# APPENDIX B SUMMARY OF LESIONS IN FEMALE p53 HAPLOINSUFFICIENT MICE IN THE 27-WEEK DERMAL STUDY OF DIISOPROPYLCARBODIIMIDE

TABLE B1 Summary of the Incidence of Neoplasms in Female p53 Haploinsufficient Mice in the 27-Week Dermal Study of Diisopropylcarbodiimide^a^

| Vehicle Control | 4.38 mg/kg | 8.75 mg/kg | 17.5 mg/kg | 35 mg/kg | 70 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Survivors
Terminal sacrifice | 15 | 15 | 15 | 15 | 15 | 15
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Hematopoietic System
Lymph node, mandibular | (15) | (15) | (15) | (14) | (15) | (15)
Hemangioma | | | | | 1 (7%)
Systems Examined with no Neoplasms Observed
Alimentary System
Cardiovascular System
Endocrine System
General Body System
Genital System
Integumentary System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System
Urinary System
Neoplasm Summary^b^
Total animals with primary neoplasms | | | | | 1
Total primary neoplasms | | | | | 1
Total animals with benign neoplasms | | | | | 1
Total benign neoplasms | | | | | 1

a Number of animals examined microscopically at site and number of animals with neoplasm

b Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE B2 Summary of the Incidence of Nonneoplastic Lesions in Female p53 Haploinsufficient Mice in the 27-Week Dermal Study of Diisopropylcarbodiimide^a^

| Vehicle Control | 4.38 mg/kg | 8.75 mg/kg | 17.5 mg/kg | 35 mg/kg | 70 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Survivors
Terminal sacrifice | 15 | 15 | 15 | 15 | 15 | 15
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15) | (15) | (15)
Infiltration cellular, focal, lymphocyte | 4 (27%) | 1 (7%) | 1 (7%) | | 2 (13%) | 5 (33%)
Infiltration cellular, lymphocyte | | | 1 (7%)
Inflammation, chronic active, focal | 1 (7%)
Hepatocyte, necrosis, focal | 1 (7%) | 1 (7%) | 3 (20%) | 8 (53%) | 4 (27%) | 3 (20%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (14) | (14) | (15)
Subcapsular, hyperplasia, focal | 12 (80%) | 7 (47%) | 10 (67%) | 12 (86%) | 12 (86%) | 15 (100%)
Zona glomerulosa, hyperplasia, focal | | | | | | 1 (7%)
Parathyroid gland | (10) | (5) | (4) | (4) | (9) | (5)
Cyst | | | | | | 1 (20%)
Thyroid gland | (15) | (14) | (14) | (15) | (15) | (15)
Ectopic thymus | 2 (13%) | | 1 (7%) | 2 (13%) | 1 (7%) | 1 (7%)
Follicular cell, hyperplasia, focal | 1 (7%)
Genital System
Uterus | (15) | (15) | (15) | (15) | (15) | (15)
Hydrometra | | | | | | 1 (7%)
Endometrium, hyperplasia, cystic | 14 (93%) | 14 (93%) | 14 (93%) | 14 (93%) | 14 (93%) | 13 (87%)
Hematopoietic System
Bone marrow | | | | | (1) | (1)
Myeloid cell, hyperplasia | | | | | | 1 (100%)
Lymph node | | | | (1)
Inguinal, hyperplasia, lymphoid | | | | 1 (100%)
Lymph node, mandibular | (15) | (15) | (15) | (14) | (15) | (15)
Hyperplasia, lymphoid | 2 (13%) | | 2 (13%) | | | 1 (7%)
Lymph node, mediastinal | (15) | (14) | (13) | (15) | (12) | (15)
Hyperplasia, lymphoid | 2 (13%)
Spleen | (15) | (15) | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | 14 (93%) | 15 (100%) | 15 (100%) | 15 (100%) | 14 (93%) | 15 (100%)
Pigmentation | 1 (7%)
Integumentary System
Skin | (15) | (15) | (15) | (15) | (15) | (15)
Dermis, fibrosis | | | | | | 1 (7%)
Dermis, infiltration cellular, mast cell | | | | | | 2 (13%)
Epidermis, control, hyperplasia, focal | 1 (7%)
Epidermis, skin, site of application, hyperplasia | | | | | | 8 (53%)
Epidermis, skin, site of application, hyperplasia, diffuse | | | | | | 1 (7%)
Epidermis, skin, site of application, hyperplasia, focal | | | | | | 1 (7%)
Sebaceous gland, hypertrophy | | | | | | 1 (7%)
Subcutaneous tissue, metaplasia, focal, osseous | | | | | | 1 (7%)
Vulva, degeneration | | | | | | 1 (7%)
Vulva, ulcer, chronic, focal | | | | | | 1 (7%)
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15) | (15)
Alveolus, hemorrhage, focal | 1 (7%) | 1 (7%)
Alveolus, inflammation, chronic active, focal | | | | 1 (7%) | 1 (7%)
Perivascular, infiltration cellular, focal, lymphocyte | | | | | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15) | (15) | (15)
Infiltration cellular, focal, lymphocyte | 1 (7%) | 2 (13%)
Pelvis, infiltration cellular, focal, lymphocyte | | | | | 1 (7%)
Renal tubule, degeneration, focal | 1 (7%)
Renal tubule, dilatation, focal | 4 (27%) | 1 (7%) | 1 (7%) | | | 3 (20%)
Renal tubule, hyperplasia | | | | | | 1 (7%)
Systems Examined with no Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion