# APPENDIX A SUMMARY OF LESIONS IN FEMALE Tg.AC HEMIZYGOUS MICE IN THE 20-WEEK DERMAL STUDY OF DIISOPROPYLCARBODIIMIDE

TABLE A1 Summary of the Incidence of Neoplasms in Female Tg.AC Hemizygous Mice in the 20-Week Dermal Study of Diisopropylcarbodiimide^a^

| Vehicle Control | 4.38 mg/kg | 8.75 mg/kg | 17.5 mg/kg | 35 mg/kg | 70 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Early deaths
Moribund | 1 | 2 | 2 | 1 | 2
Natural deaths | 1 | | | 1 | 2
Survivors
Terminal sacrifice | 8 | 8 | 8 | 8 | 6 | 10
Animals examined microscopically | 10 | 8 | 10 | 9 | 9 | 10
Alimentary System
Intestine small, jejunum | (9) | (2) | (2) | (1) | (2) | (10)
Carcinoma | 1 (11%)
Liver | (10) | (6) | (7) | (7) | (6) | (10)
Leukemia erythrocytic | 1 (10%)
Salivary glands | (10) | (2) | (10) | (10) | (10) | (10)
Duct, squamous cell carcinoma | | | | | 1 (25%)
Stomach, forestomach | (10) | (2) | (3) | (3) | (2) | (10)
Squamous cell papilloma | | | 2 (67%) | 2 (67%) | | 2 (20%)
Tooth | (3) | (4) | (4) | (6) | (3) | (7)
Odontoma | 3 (100%) | 2 (50%) | 4 (100%) | 6 (100%) | 1 (33%) | 6 (86%)
Genital System
Ovary | (10) | (2) | (2) | (2) | (4) | (10)
Teratoma benign | | | | | 2 (50%)
Yolk sac carcinoma | | | 1 (50%)
Hematopoietic System
Spleen | (9) | (5) | (3) | (3) | (6) | (10)
Leukemia erythrocytic | 1 (11%)
Integumentary System
Skin | (10) | (3) | (4) | (4) | (4) | (10)
Squamous cell papilloma | | 1 (33%) | | 1 (25%)
Squamous cell papilloma, multiple | 1 (10%) | | 1 (25%)
Dermis, skin, site of application, fibrosarcoma | | | 1 (25%)
Skin, site of application, squamous cell papilloma | | | | | | 1 (10%)
Skin, site of application, squamous cell papilloma, multiple | 1 (10%) | | 1 (25%) | 1 (25%)
Respiratory System
Nose | (10) | (5) | (1) | (2) | (4) | (10)
Respiratory epithelium, adenoma | 1 (10%)
Systemic Lesions
Multiple organs^b^ | (10) | (8) | (10) | (9) | (9) | (10)
Leukemia erythrocytic | 1 (10%)
Systems Examined with no Neoplasms Observed
Cardiovascular System
Endocrine System
General Body System
Musculoskeletal System
Nervous System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 6 | 3 | 6 | 7 | 3 | 8
Total primary neoplasms | 8 | 3 | 10 | 10 | 4 | 9
Total animals with benign neoplasms | 5 | 3 | 6 | 7 | 3 | 8
Total benign neoplasms | 6 | 3 | 8 | 10 | 3 | 9
Total animals with malignant neoplasms | 2 | | 2 | | 1
Total malignant neoplasms | 2 | | 2 | | 1

a Number of animals examined microscopically at site and number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A2 Summary of the Incidence of Nonneoplastic Lesions in Female Tg.AC Hemizygous Mice in the 20-Week Dermal Study of Diisopropylcarbodiimide^a^

| Vehicle Control | 4.38 mg/kg | 8.75 mg/kg | 17.5 mg/kg | 35 mg/kg | 70 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Early deaths
Moribund | 1 | 2 | 2 | 1 | 2
Natural deaths | 1 | | | 1 | 2
Survivors
Terminal sacrifice | 8 | 8 | 8 | 8 | 6 | 10
Animals examined microscopically | 10 | 8 | 10 | 9 | 9 | 10
Alimentary System
Intestine small, jejunum | (9) | (2) | (2) | (1) | (2) | (10)
Ulcer, chronic active | 1 (11%)
Liver | (10) | (6) | (7) | (7) | (6) | (10)
Hematopoietic cell proliferation | 1 (10%) | | 1 (14%) | | | 1 (10%)
Inflammation | | | 1 (14%)
Inflammation, focal | 7 (70%) | 4 (67%) | 3 (43%) | 7 (100%) | 2 (33%) | 8 (80%)
Necrosis | 1 (10%) | | 1 (14%)
Pancreas | (9) | (2) | (2) | (1) | (4) | (10)
Inflammation, focal | 1 (11%)
Stomach, glandular | (10) | (2) | (2) | (2) | (2) | (10)
Inflammation | | | | | | 1 (10%)
Tongue | | | | | (1)
Epithelium, hyperkeratosis | | | | | 1 (100%)
Tooth | (3) | (4) | (4) | (6) | (3) | (7)
Hyperplasia, odontogenic | | | | | 1 (33%) | 1 (14%)
Cardiovascular System
Blood vessel | (10) | (2) | (2) | (2) | (4) | (10)
Aorta, adventitia, inflammation, focal | 1 (10%)
Genital System
Clitoral gland | (7) | (2) | (1) | (1) | (2) | (8)
Atrophy | | 1 (50%) | | 1 (100%)
Uterus | (10) | (2) | (2) | (2) | (4) | (10)
Hydrometra | 1 (10%) | | | | | 2 (20%)
Bilateral, hydrometra | 2 (20%) | | | | 1 (25%) | 1 (10%)
Hematopoietic System
Bone marrow | (10) | (2) | (2) | (2) | (4) | (10)
Myeloid cell, hyperplasia | 1 (10%) | | 1 (50%)
Lymph node | | | (1) | (1)
Infiltration cellular, plasma cell | | | 1 (100%)
Infiltration cellular, histiocyte | | | 1 (100%)
Mediastinal, infiltration cellular, histiocyte | | | | 1 (100%)
Lymph node, mandibular | (10) | (2) | (2) | (1) | (4) | (10)
Infiltration cellular, plasma cell | 1 (10%) | | 1 (50%) | 1 (100%)
Infiltration cellular, polymorphonuclear | 1 (10%) | | | | | 1 (10%)
Lymph node, mesenteric | (9) | (2) | (2) | (1) | (4) | (10)
Infiltration cellular, polymorphonuclear | 1 (11%)
Infiltration cellular, histiocyte | 1 (11%) | | 1 (50%)
Inflammation | | | | | | 1 (10%)
Inflammation, focal | | | 1 (50%) | | 1 (25%)
Pigmentation | | 1 (50%)
Spleen | (9) | (5) | (3) | (3) | (6) | (10)
Fibrosis | | | | 1 (33%)
Hematopoietic cell proliferation | 7 (78%) | 5 (100%) | 2 (67%) | 1 (33%) | 5 (83%) | 9 (90%)
Lymphoid follicle, necrosis | | | | | 1 (17%)
Thymus | (9) | (2) | (2) | | (3) | (10)
Atrophy | 1 (11%) | 2 (100%) | 1 (50%)
Thymocyte, necrosis | 1 (11%) | | 1 (50%) | | 1 (33%)
Integumentary System
Skin | (10) | (3) | (4) | (4) | (4) | (10)
Dermis, atrophy | | | 1 (25%)
Dermis, skin, site of application, inflammation | | | 1 (25%) | | 1 (25%) | 1 (10%)
Epidermis, hyperplasia | | | 1 (25%)
Epidermis, skin, site of application, hyperplasia | | | 1 (25%) | | 1 (25%)
Epidermis, skin, site of application, inflammation | | | 2 (50%)
Epidermis, skin, site of application, inflammation, chronic active | | | | | | 1 (10%)
Skin, site of application, ulcer, chronic active | | | 1 (25%)
Respiratory System
Lung | (10) | (2) | (2) | (3) | (4) | (10)
Inflammation, chronic, focal | 1 (10%)
Inflammation, chronic active, focal | | | | 1 (33%) | | 1 (10%)
Inflammation, focal | 2 (20%) | | 1 (50%)
Nose | (10) | (5) | (1) | (2) | (4) | (10)
Inflammation | 2 (20%) | 3 (60%) | | | | 2 (20%)
Systems Examined with no Lesions Observed
Endocrine System
General Body System
Musculoskeletal System
Nervous System
Special Senses System
Urinary System

a Number of animals examined microscopically at the site and the number of animals with lesion