# REFERENCES

The Aldrich Library of IR Spectra (1981). 3rd. ed. (C.J. Pouchert, Ed.), Spectrum 1005H. Aldrich Chemical Company, Inc., Milwaukee.
Ashby, J., and Tennant, R.W. (1991). Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the U.S. NTP. Mutat. Res. 257, 229–306.1707500
Bailer, A.J., and Portier, C.J. (1988). Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics 44, 417–431.3390507
Bieler, G.S., and Williams, R.L. (1993). Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics 49, 793–801.8241374
Boorman, G.A., Montgomery, C.A., Jr., Eustis, S.L., Wolfe, M.J., McConnell, E.E., and Hardisty, J.F. (1985). Quality assurance in pathology for rodent carcinogenicity studies. In Handbook of Carcinogen Testing (H.A. Milman and E.K. Weisburger, Eds.), pp. 345–357. Noyes Publications, Park Ridge, NJ.
Boorman, G.A., Hickman, R.L., Davis, G.W., Rhodes, L.S., White, N.W., Griffin, T.A., Mayo, J., and Hamm, T.E., Jr. (1986). Serological titers to murine viruses in 90-day and 2-year studies. In Complications of Viral and Mycoplasmal Infections in Rodents to Toxicology Research and Testing (T.E. Hamm, Jr., Ed.), pp. 11–23. Hemisphere Publishing Corporation, Washington, DC.
Bradstock, M.K., Serdula, M.K., Marks, J.S., Barnard, R.J., Crane, N.T., Remington, P.L., and Trowbridge, F.L. (1986). Evaluation of reactions to food additives: The aspartame experience. Am. J. Clin. Nutr. 43, 464–469.3953484
Bucher, J.R. (1998). Update on National Toxicology Program (NTP) assays with genetically altered or “transgenic” mice. Environ. Health Perspect. 106, 619–621.9755135
Bucher, J.R. (2000). Doses in rodent cancer studies: Sorting fact from fiction. Drug Metab. Rev. 32, 153–163.10774772
Butchko, H.H., and Stargel, W.W. (2001). Aspartame: Scientific evaluation in the postmarketing period. Regul. Toxicol. Pharmacol. 34, 221–233.11754527
Cannon, R.E., Spalding, J.W., Trempus, C.S., Szczesniak, C.J., Virgil, K.M., Humble, M.C., and Tennant, R.W. (1997). Kinetics of wound-induced v-Ha-ras transgene expression and papilloma development in transgenic Tg.AC mice. Mol. Carcinog. 20, 108–114.9328441
Centers for Disease Control (CDC) (1984). Evaluation of consumer complaints related to aspartame use. MMWR Morb. Mortal. Wkly. Rep. 33, 605–607.6436658
Code of Federal Regulations (CFR) 21, Part 58.
Cornell, R.G., Wolfe, R.A, and Sanders, P.G. (1984). Aspartame and brain tumors: Statistical issues. In Aspartame: Physiology and Biochemistry (L.D. Stegink and L.J. Filer, Jr., Eds.), pp. 459–479. Marcel Dekker, Inc., New York.
Cox, D.R. (1972). Regression models and life-tables. J. R. Stat. Soc. B34, 187–220.
Crawford, B.D. (1985). Perspectives on the somatic mutation model of carcinogenesis. In Advances in Modern Environmental Toxicology. Mechanisms and Toxicity of Chemical Carcinogens and Mutagens (M.A. Mehlman, W.G. Flamm, and R.J. Lorentzen, Eds.), pp. 13–59. Princeton Scientific Publishing Co., Inc., Princeton, NJ.
Dews, P.B. (1987). Summary report of an international aspartame workshop. Food Chem. Toxicol. 25, 549–552.3623346
Diomede, L., Romano, M., Guiso, G., Caccia, S., Nava, S., and Salmona, M. (1991). Interspecies and interstrain studies on the increased susceptibility to metrazol-induced convulsions in animals given aspartame. Food Chem. Toxicol. 29, 101–106.2010138
Donehower, L.A., Harvey, M., Slagle, B.L., McArthur, M.J., Montogmery, C.A., Jr., Butel, J.S., and Bradley, A. (1992). Mice deficient for p53 are developmentally normal but susceptible to spontaneous tumours. Nature 356, 215–221.1552940
Dow-Edwards, D.L., Scribani, L.A., and Riley, E.P. (1989). Impaired performance on odor-aversion testing following prenatal aspartame exposure in the guinea pig. Neurotoxicol. Teratol. 11, 413–416.2796897
Dunnett, C.W. (1955). A multiple comparison procedure for comparing several treatments with a control. J. Am. Stat. Assoc. 50, 1096–1121.
Federal Register (1981a). Aspartame: Commissioner’s Final Decision. Vol. 46, No. 142, pp. 38,285–38,308. Food and Drug Administration, Rockville, MD.
Federal Register (1981b). Aspartame: Commissioner’s Final Decision; Correction. Vol. 46, No. 181, p. 46,394. Food and Drug Administration, Rockville, MD.
Federal Register (1984). Food Additives Permitted for Direct Addition to Food for Human Consumption; Aspartame; Denial of Requests for Hearing; Final Rule. Vol. 49, No. 36, pp. 6672–6682. Food and Drug Administration, Department of Health and Human Services, Rockville, MD.
Federal Register (1996). Food Additives Permitted for Direct Addition to Food for Human Consumption; Aspartame. Vol. 61, No. 126, pp. 33,654–33,656. Food and Drug Administration, Department of Health and Human Services, Rockville, MD.
Food and Drug Administration (FDA) (1994). Is aspartame safe? Excerpted from Food allergies are rare but risky. FDA Consum., May 1994 (http:www.cfsan.fda.gov/~dms/qa-adf9.html).
Freeman, G., Sobotka, T., and Hattan, D. (1990). Acute effects of aspartame on concentrations of brain amines and their metabolites in selected brain regions of Fischer 344 and Sprague-Dawley rats. Drug Chem. Toxicol. 13, 113–133.1703475
Galletti, G.C., Chiavari, G., and Bocchini, P. (1995). Thermal decomposition products of aspartame as determined by pyrolysis — gas chromatography/mass spectrometry. J. Anal. Appl. Pyrolysis 32, 137–151.
Goelz, M.F., Mahler, J., Harry, J., Myers, P., Clark, J., Thigpen, J.E., and Forsythe, D.B. (1998). Neuropathologic findings associated with seizures in FVB mice. Lab. Anim. Sci. 48, 34–37.9517887
Gurney, J.G., Pogoda, J.M., Holly, E.A., Hecht, S.S., and Preston-Martin, S. (1997). Aspartame consumption in relation to childhood brain tumor risk: Results from a case-control study. J. Natl. Cancer Inst. 89, 1072–1074.9230890
Harris, C.C. (1996a). Structure and function of the p53 tumor suppressor gene: Clues for rational cancer therapeutic strategies. J. Natl. Cancer Inst. 88, 1442–1455.8841019
Harris, C.C. (1996b). p53 Tumor suppressor gene: From the basic research laboratory to the clinic — an abridged historical perspective. Carcinogenesis 17, 1187–1198.8681432
Harris, C.C. (1996c). The 1995 Walter Hubert Lecture — molecular epidemiology of human cancer: Insights from the mutational analysis of the p53 tumour-suppressor gene. Brit. J. Cancer 73, 261–269.8562328
Hazardous Substances Data Bank (HSDB) (2003). National Institute for Occupational Safety and Health, HSDB database available through the National Library of Medicine TOXNET System.
Holder, M.D. (1989). Effects of perinatal exposure to aspartame on rat pups. Neurotoxicol. Teratol. 11, 1–6.2725436
Holder, M.D., and Yirmiya, R. (1989). Behavioral assessment of the toxicity of aspartame. Pharmacol. Biochem. Behav. 32, 17–26.2734328
Hollander, M., and Wolfe, D.A. (1973). Nonparametric Statistical Methods, pp. 120–123. John Wiley and Sons, New York.
Integrated Laboratory Systems (ILS) (1990). Micronucleus Data Management and Statistical Analysis Software, Version 1.4. ILS P.O. Box 13501, Research Triangle Park, NC.
Ishii, H. (1981). Incidence of brain tumors in rats fed aspartame. Toxicol. Lett. 7, 433–437.7245229
Ishii, H., Koshimizu, T., Usami, S., and Fujimoto, T. (1981). Toxicity of aspartame and its diketopiperazine for Wistar rats by dietary administration for 104 weeks. Toxicology 21, 91–94.7281205
Jeffrey, A.M., and Williams, G.M. (2000). Lack of DNA-damaging activity of five non-nutritive sweeteners in the rat hepatocyte/DNA repair assay. Food Chem. Toxicol. 38, 335–338.10722887
Kaplan, E.L., and Meier, P. (1958). Nonparametric estimation from incomplete observations. J. Am. Stat. Assoc. 53, 457–481.
Kim, S.K., Jung, M.Y., and Kim, S.Y. (1997). Photodecomposition of aspartame in aqueous solutions. Food Chem. 59, 272–278.
Koestner, A. (1984). Aspartame and brain tumors: Pathology issues. In Aspartame: Physiology and Biochemistry (L.D. Stegink and L.J. Filer, Jr., Eds.), pp. 447–457 Marcel Dekker, Inc., New York.
Leder, A., Kuo, A., Cardiff, R.D., Sinn, E., and Leder, P. (1990). v-Ha-ras transgene abrogates the initiation step in mouse skin tumorigenesis: Effects of phorbol esters and retinoic acid. Proc. Natl. Acad. Sci. 87, 9178–9182.2251261
Levy, P.S., and Hedeker, D. (1996). Letter to the editor. J. Neuropathol. Exp. Neurol. 55, 1280.8957453
Liggett, W.H., Jr., and Sidransky, D. (1998). Role of the p16 tumor suppressor gene in cancer. J. Clin. Oncol. 16, 1197–1206.9508208
McAnulty, P.A., Collier, M.J., Enticott, J., Tesh, J.M., Mayhew, D.A., Comer, C.P., Hjelle, J.J., and Kotsonis, F.N. (1989). Absence of developmental effects in CF-1 mice exposed to aspartame in utero. Fundam. Appl. Toxicol. 13, 296–302.2792596
MacGregor, J.T., Wehr, C.M., Henika, P.R., and Shelby, M.D. (1990). The in vivo erythrocyte micronucleus test: Measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam. Appl. Toxicol. 14, 513–522.2111256
McIntyre, B.S., Barlow, N.J., and Foster, P.M.D. (2002). Male rats exposed to linuron in utero exhibit perminant changes in anogenital distance, nipple retention, and epididymal malformations that result in subsequent testicular atrophy. Toxicol Sci. 65, 62–70.11752686
Mahler, J.F., Stokes, W., Mann, P.C., Takaoka, M., and Maronpot, R.R. (1996). Spontaneous lesions in aging FVB/N mice. Toxicol. Pathol. 24, 710–716.8994298
Mahler, J.F., Flagler, N.D., Malarkey, D.E., Mann, P.C., Haseman, J.K., and Eastin, W. (1998). Spontaneous and chemically induced proliferative lesions in Tg.AC transgenic and p53-heterozygous mice. Toxicol. Pathol. 26, 501–511.9715509
Maronpot, R.R., and Boorman, G.A. (1982). Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol. Pathol. 10, 71–80.28094716
Miller, J.A., and Miller, E.C. (1977). Ultimate chemical carcinogens as reactive mutagenic electrophiles. In Origins of Human Cancer (H.H. Hiatt, J.D. Watson, and J.A. Winsten, Eds.), pp. 605–627. Cold Spring Harbor Laboratory, Cold Spring Harbor, NY.
Molinary, S.V. (1984). Preclinical studies of aspartame in nonprimate animals. In Aspartame: Physiology and Biochemistry (L.D. Stegink and L.J. Filer, Jr., Eds.), pp. 289–306. Marcel Dekker, Inc., New York.
Mukhopadhyay, M., Mukherjee, A., and Chakrabarti, J. (2000). In vivo cytogenetic studies on blends of aspartame and acesulfame-K. Food Chem. Toxicol. 38, 75–77.10685017
National Toxicology Program (NTP) (2003). NTP Workshop. Genetically Modified Rodent Models for Cancer Hazard Indentification: Selecting Substances for Study and Interpreting and Communicating Results (http://ntp-server.niehs.nih.gov/Meetings/2003/2003FebTgWkshop.html).
National Toxicology Program (NTP) (2005). Toxicology Studies of Acesulfame Potassium (CAS No. 55589-62-3) in FVB Tg.AC Hemizygous Mice and Carcinogenicity Studies of Acesulfame Potassium in B6/129 (N5) p53 Haploinsufficient Mice (Feed Studies). Technical Report Series No. 524. NIH Publication No. 06-4460. U.S. Department of Health and Human Services, Public Health Service, National Insititutes of Health, Research Triangle Park, NC (in press).
Nguyen, U.N., Dumoulin, G., Henriet, M.-T., and Regnard, J. (1998). Aspartame ingestion increases urinary calcium, but not oxalate excretion, in healthy subjects. J. Clin. Endocrinol. Metab. 83, 165–168.9435435
Olney, J.W., Farber, N.B., Spitznagel, E., and Robins, L.N. (1996). Increasing brain tumor rates: Is there a link to aspartame? J. Neuropathol. Exp. Neurol. 55, 1115–1123.8939194
Piegorsch, W.W., and Bailer, A.J. (1997). Statistics for Environmental Biology and Toxicology, Section 6.3.2. Chapman and Hall, London.
Pomerantz, J., Schreiber-Agus, N., Liégeois, N.J., Silverman, A., Alland, L., Chin, L., Potes, J., Chen, K., Orlow, I., Lee, H.-W., Cordon-Cardo, C., and DePinho, R.A. (1998). The Ink4a tumor suppressor gene product, p19^Arf^, interacts with MDM2 and neutralizes MDM2’s inhibition of p53. Cell 92, 713–723.9529248
Portier, C.J., and Bailer, A.J. (1989). Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam. Appl. Toxicol. 12, 731–737.2744275
Portier, C.J., Hedges, J.C., and Hoel, D.G. (1986). Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 46, 4372–4378.3731095
Pritchard, J.B., French, J.E., Davis, B.J., and Haseman, J.K. (2003). The role of transgenic mouse models in carcinogen identification. Environ. Health Perspect. 111, 444–454.12676597
Ranney, R.E., and Oppermann, J.A. (1979). A review of the metabolism of the aspartyl moiety of aspartame in experimental animals and man. J. Environ. Pathol. Toxicol. 2, 979–985.376770
Ranney, R.E., Mares, S.E., Schroeder, R.E., Hutsell, T.C., and Radzialowski, F.M. (1975). The phenylalanine and tyrosine content of maternal and fetal body fluids from rabbits fed aspartame. Toxicol. Appl. Pharmacol. 32, 339–346.1154399
Ranney, R.E., Oppermann, J.A., Muldoon, E., and McMahon, F.G. (1976). Comparative metabolism of aspartame in experimental animals and humans. J. Toxicol. Environ. Health 2, 441–451.827618
Rao, G.N., Haseman, J.K., and Edmondson, J. (1989a). Influence of viral infections on body weight, survival, and tumor prevalence in Fischer 344/NCr rats on two-year studies. Lab. Anim. Sci. 39, 389–393.2554057
Rao, G.N., Piegorsch, W.W., Crawford, D.D., Edmondson, J., and Haseman, J.K. (1989b). Influence of viral infections on body weight, survival, and tumor prevalence of B6C3F_1_ (C57BL/6N × C3H/HeN) mice in carcinogenicity studies. Fundam. Appl. Toxicol. 13, 156–164.2767355
Reed, A.L., Califano, J., Cairns, P., Westra, W.H., Jones, M., Koch, W., Ahrendt, S., Eby, Y., Sewell, D., Nawroz, H., Bartek, J., and Sidransky, D. (1996). High frequency of p16 (CDKN2/MTS-1/INK4A) inactivation in head and neck squamous cell carcinoma. Cancer Res. 56, 3630–3633.8705996
Registry of Toxic Effects of Chemical Substances (RTECS) [database online] (2002). Bethesda (MD): National Institute for Occupational Safety and Health; 1971 to present. Updated quarterly. Available from the National Library of Medicine, Bethesda, MD.
Reynolds, W.A., Stegink, L.D., Filer, L.J., Jr., and Renn, E. (1980). Aspartame administration to the infant monkey: Hypothalamic morphology and plasma amino acid levels. Anat. Rec. 198, 73–85.7457932
Reynolds, W.A., Bauman, A.F., Stegink, L.D., and Filer, L.J., Jr. (1984). Developmental assessment of infant macaques receiving dietary aspartame or phenylalanine. In Aspartame: Physiology and Biochemistry (L.D. Stegink and L.J. Filer, Jr., Eds.), pp. 405–423. Marcel Dekker, Inc., New York.
Rowan, A.J., Shaywitz, B.A., Tuchman, L., French, J.A., Luciano, D., and Sullivan, C.M. (1995). Aspartame and seizure susceptibility: Results of a clinical study in reportedly sensitive individuals. Epilepsia 36, 270–275.7614911
Serrano, M., Hannon, G.J., and Beach, D. (1993). A new regulatory motif in cell-cycle control causing specific inhibition of cyclin D/CDK4. Nature 366, 704–707.8259215
Serrano, M., Lee, H.-W., Chin, L., Cordon-Cardo, C., Beach, D., and DePinho, R.A. (1996). Role of the INK4a locus in tumor suppression and cell mortality. Cell 85, 27–37.8620534
Shelby, M.D. (1988). The genetic toxicity of human carcinogens and its implications. Mutat. Res. 204, 3–15.3277048
Shelby, M.D., and Witt, K.L. (1995). Comparison of results from mouse bone marrow chromosome aberration and micronucleus tests. Environ. Mol. Mutagen. 25, 302–313.7607185
Shelby, M.D., and Zeiger, E. (1990). Activity of human carcinogens in the Salmonella and rodent bone-marrow cytogenetics tests. Mutat. Res. 234, 257–261.2366790
Shelby, M.D., Erexson, G.L., Hook, G.J., and Tice, R.R. (1993). Evaluation of a three-exposure mouse bone marrow micronucleus protocol: Results with 49 chemicals. Environ. Mol. Mutagen. 21, 160–179.8444144
Shephard, S.E., Wakabayashi, K., and Nagao, M. (1993). Mutagenic activity of peptides and the artificial sweetener aspartame after nitrosation. Food Chem. Toxicol. 31, 323–329.8505016
Smith, M.A., Freidlin, B., Ries, L.A., and Simon, R. (1998). Trends in reported incidence of primary malignant brain tumors in children in the United States. J. Natl. Cancer Inst. 90, 1269–1277.9731733
Spalding, J.W., Momma, J., Elwell, M.R., and Tennant, R.W. (1993). Chemically induced skin carcinogenesis in a transgenic mouse line (TG•AC) carrying a v-Ha-ras gene. Carcinogenesis 14, 1335–1341.8330346
Spalding, J.W., French, J.E., Tice, R.R., Furedi-Machacek, M., Haseman, J.K., and Tennant, R.W. (1999). Development of a transgenic mouse model for carcinogenesis bioassays: Evaluation of chemically induced skin tumors in Tg.AC mice. Toxicol. Sci. 49, 241–254.10416269
Speirs, P.A., Sabounjian, L., Reiner, A., Myers, D.K., Wurtman, J., Schomer, D.L. (1998). Aspartame: Neuropsychologic and nuerophysiologic evaluation of acute and chronic effects. Am. J. Clin. Nutr. 68, 531–537.9734727
Stegink, L.D. (1987). The aspartame story: A model for the clinical testing of a food additive. Am. J. Clin. Nutr. 46, 204–215.3300262
Stegink, L.D., and Filer, L.J., Jr., Eds. (1984). Aspartame: Physiology and Biochemistry. Marcel Dekker, Inc., New York.
Stegink, L.D., Filer, L.J., Jr., Baker, G.L., and McDonnell, J.E. (1980). Effect of an abuse dose of aspartame upon plasma and erythrocyte levels of amino acids in phenylketonuric heterozygous and normal adults. J. Nutr. 110, 2216–2224.7431122
Straus, D.S. (1981). Somatic mutation, cellular differentiation, and cancer causation. JNCI 67, 233–241.7021938
Suomi, S.J. (1984). Effects of aspartame on the learning test performance of young stump-tail macaques. In Aspartame: Physiology and Biochemistry (L.D. Stegink and L.J. Filer, Jr., Eds.). Marcel Dekker, Inc., New York.
Tarone, R.E. (1975). Tests for trend in life table analysis. Biometrika 62, 679–682.
Tennant, R.W., Margolin, B.H., Shelby, M.D., Zeiger, E., Haseman, J.K., Spalding, J., Caspary, W., Resnick, M., Stasiewicz, S., Anderson, B., and Minor, R. (1987). Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science 236, 933–941.3554512
Tennant, R.W., French, J.E., and Spalding, J.W. (1995). Identifying chemical carcinogens and assessing potential risk in short-term bioassays using transgenic mouse models. Environ. Health Perspect. 103, 942–950.8529591
Tennant, R.W., Spalding, J., and French, J.E. (1996). Evaluation of transgenic mouse bioassays for identifying carcinogens and noncarcinogens. Mutat. Res. 365, 119–127.8898993
Tennant, R.W., Stasiewicz, S., Mennear, J., French, J.E., and Spalding, J.W. (1999). Genetically altered mouse models for identifying carcinogens. IARC Sci. Publ. 146, 123–150.
Tennant, R.W., Stasiewicz, S., Eastin, W.C., Mennear, H., and Spalding, J.W. (2001). The Tg.AC (v-Ha-ras) transgenic mouse: Nature of the model. Toxicol. Pathol. 29, 51–59.11695562
Tilson, H.A., Thai, L., Zhao, D., Sobotka, T.J., and Hong, J.S. (1989). Oral administration of aspartame is not proconvulsant in rats. Neurotoxicology 10, 229–238.2616065
Tilson, H.A., Hong, J.S., and Sobotka, T.J. (1991). High doses of aspartame have no effects on sensorimotor function or learning and memory in rats. Neurotoxicol. Teratol. 43, 27–35.
Tollefson, L. (1988). Monitoring adverse reactions to food additives in the U.S. Food and Drug Administration. Regul. Toxicol. Pharmacol. 8, 438–446.3222485
Tollefson, L., and Barnard, R.J. (1992). An analysis of FDA passive surveillance reports of seizures associated with consumption of aspartame. J. Am. Diet. Assoc. 92, 598–601.1573143
Tomatis, L., Huff, J., Hertz-Picciotto, I., Sandler, D.P., Bucher, J., Boffetta, P., Axelson, O., Blair, A., Taylor, J., Stayner, L., and Barrett, J.C. (1997). Avoided and avoidable risks of cancer. Carcinogenesis 18, 97–105.9054595
Trempus, C.S., Mahler, J.F., Ananthaswamy, H.N., Loughlin, S.M., French, J.E., and Tennant, R.W. (1998). Photocarcinogenesis and susceptibility to UV radiation in the v-Ha-ras transgenic Tg.AC mouse. J. Invest. Dermatol. 111, 445–451.9740239
Trocho, C., Pardo, R., Rafecas, I., Virgili, J., Remesar, X., Fernández-López, J.A., and Alemany, M. (1998). Formaldehyde derived from dietary aspartame binds to tissue components in vivo. Life Sci. 63, 337–349.9714421
Van Den Eeden, S.K., Koepsell, T.D., Longstreth, W.T., Jr., van Belle, G., Daling, J.R., and McKnight, B. (1994). Aspartame ingestion and headaches: A randomized crossover trial. Neurology 44, 1787–1793.7936222
Williams, D.A. (1971). A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics 27, 103–117.5547548
Williams, D.A. (1972). The comparison of several dose levels with a zero dose control. Biometrics 28, 519–531.5037867
Witt, K.L., Knapton, A., Wehr, C.M., Hook, G.J., Mirsalis, J., Shelby, M.D., and MacGregor, J.T. (2000). Micronucleated erythrocyte frequency in peripheral blood of B6C3F_1_ mice from short-term, prechronic, and chronic studies of the NTP Carcinogenesis Bioassay Program. Environ. Mol. Mutagen. 36, 163–194.11044899
Wolraich, M.L., Lindgren, S.D., Stumbo, P.J., Stegink, L.D., Appelbaum, M.I., and Kiritsy, M.C. (1994). Effects of diets high in sucrose or aspartame on the behavior and cognitive performance of children. N. Engl. J. Med. 330, 301–307.8277950
Wright, J.T., Hansen, L., Mahler, J., Szczesniak, C., and Spalding, J.W. (1995). Odontogenic tumours in the v-Ha-ras (TG•AC) transgenic mouse. Arch. Oral Biol. 40, 631–638.7575235
Zeiger, E., Haseman, J.K., Shelby, M.D., Margolin, B.H., and Tennant, R.W. (1990). Evaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: Confirmation of earlier results with 41 additional chemicals. Environ. Mol. Mutagen. 16 (Suppl. 18), 1–14.
Zeiger, E., Anderson, B., Haworth, S., Lawlor, T., and Mortelmans, K. (1992). Salmonella mutagenicity tests: V Results from the testing of 311 chemicals. Environ. Mol. Mutagen. 19 (Suppl. 21), 2–141.1541260