# DISCUSSION AND CONCLUSIONS

Although the National Toxicology Program (NTP) has not conducted standard 2-year rodent bioassays with aspartame, a number of chronic rodent cancer studies have been performed and are outlined in the Introduction to this report. These studies have been interpreted as showing no consistent carcinogenic response that would raise concerns about the safety of this widely consumed artificial sweetener. The one lingering concern has focused on the observation of a low number of brain tumors in studies carried out prior to the registration of the product. Nonetheless, aspartame has been selected for use in the NTP’s program for development of alternative carcinogenicity bioassays as a presumed noncarcinogen.

These studies were designed at a time when a number of questions were being raised concerning the adequacy of the existing protocols to provide the maximum sensitivity to detect a positive or carcinogenic response in the genetically modified mouse models employed. These included (1) the belief that the Tg.AC mouse line, while touted as a dermal papilloma model, might also prove to be useful for chemicals administered orally with the “reporter phenotype” (Tennant et al., 2001) being papilloma development in the forestomach; (2) the suggestion that studies could be extended to 9 months to increase the opportunity for expression of a positive response in the absence of a significant number of tumors developing in control animals; and (3) the concern that the models in use, i.e. the Tg.AC hemizygous and the p53 haploinsufficient had “blind spots” with regard to the detection of tumors in certain organs such as the brain, prostate gland, liver, and kidney (Bucher, 1998). As a consequence, the current studies were designed to administer aspartame in feed to Tg.AC hemizygous and p53 haploinsufficient mice for 9 months, and similar studies were performed using the Cdkn2a deficient mouse, an entirely uncharacterized model that was believed to hold some promise for detecting cancers of the brain.

There were no prechronic studies performed with these models because prior reports in the literature had shown conclusively that aspartame was well-tolerated by experimental animals given doses of up to 6 to 8 g aspartame/kg body weight per day (Molinary, 1984). In the current studies, the highest dietary concentration of 50,000 ppm was estimated to provide doses of between 6 and 10 g aspartame/kg body weight per day throughout the studies with all three mouse models. There were no specific clinical signs or consistent effects on body weight gains or survival in any of the studies. These findings, coupled with the absence of significant lesions associated with aspartame administration in any of the mouse models studied, suggested that higher doses could have been tolerated by the animals. However, 50,000 ppm has been adopted by the NTP as the maximum exposure concentration in rodent cancer studies with nontoxic substances administered in feed (Bucher, 2000).

In the Tg.AC hemizygous mouse there were a number of neoplasms and nonneoplastic lesions that occurred with slightly different incidences in exposed and control groups. In exposed Tg.AC hemizygous mice, alveolar/bronchiolar adenomas were observed only in males; however, the incidences (up to 2/14 or 14%) were not related to exposure concentration, and these tumors have historically occurred in 4.3% of male control Tg.AC hemizygous mice in 6-month dermal studies (Mahler et al., 1998). For these reasons, the alveolar/bronchiolar adenomas were not considered related to aspartame administration. Similarly, there were sporadic incidences of salivary gland carcinomas in exposed groups of male and female Tg.AC hemizygous mice, but again no relation to exposure concentration was apparent. These tumors have also been reported to occur in control Tg.AC mice in 6-month dermal studies, with a higher incidence in homozygous than in hemizygous mice (Tennant et al., 2001).

Concerning the typical sites of papilloma formation in Tg.AC hemizygous mice, there were no apparent increases in the incidences of skin or forestomach papillomas in exposed groups compared to the control groups in this study. The rather high incidences of both single and multiple forestomach papillomas in control Tg.AC hemizygous mice suggest that this model may not be appropriate for use in an extended-duration study of this type, if the chemical is administered orally. The high background papilloma incidence in controls would limit the ability to detect a weak response that lacked a dramatic increase in tumor multiplicity. The lack of a forestomach papilloma response to aspartame was consistent with the expected outcome.

Pritchard et al. (2003) reported as part of a global review of transgenic cancer model findings that the Tg.AC model had an overall accuracy of 74% in correctly predicting chemicals that are listed by the International Agency for Research on Cancer and/or the NTP in their respective listings of chemicals as known or suspected human carcinogens. Chemicals studied in the Tg.AC line and found negative also contributed to this accuracy score if the chemicals were considered to be noncarcinogens by virtue of not appearing in these listings. The vast majority of the Tg.AC studies examined by Pritchard et al. (2003) used the dermal route of exposure and skin papillomas as the reporter phenotype. The pattern of incorrect assignments included both “false positives” and “false negatives.” This level of accuracy is not significantly different from that achieved by the p53 haploinsufficient model or the Hras2 model in the Pritchard analysis. However, based on discussions at a recent NTP workshop (NTP, 2003) there is a lack of acceptance within the scientific/regulatory community that a positive result in the Tg.AC model represents a true cancer response. Therefore, the confidence in this model to identify carcinogens appears to be less than that in either the p53 haploinsufficient or Hras2 model.

The results of the evaluation of aspartame in the p53 haploinsufficient model were also unremarkable in that no treatment-related neoplasms or nonneoplastic lesions were identified in these mice. The p53 haploinsufficient mouse on the C57BL/6 background has a number of characteristic lesions that typically occur including inflammatory infiltrate in the salivary gland, atrophy of the adrenal cortex, and adrenal subcapsular hyperplasia. These lesions, while usually mild, did occur in this study, but at incidences not affected by aspartame. Although no tumors occurred in control males, 4 of the 15 female control animals developed a neoplasm, a rate higher than in any of the exposed groups. However, no more than one tumor of any particular type occurred in controls, suggesting that the p53 haploinsufficient line maintains sufficiently low background tumor rates to be an effective model if used in a 9-month protocol rather than the typical 6-month study.

The review and analysis of the performance of the p53 haploinsufficient model by Pritchard et al. (2003) included data and conclusions as reported by the authors of studies published up to mid-2002. They compared the responses in the p53 haploinsufficient mouse model to a group of 12 known human carcinogens, 19 suspected human carcinogens, and 28 probable human noncarcinogens. In this analysis, the p53 haploinsufficient model had an overall accuracy of 81%. The high accuracy was in large part due to the lack of “false positives” (positive outcomes for probable human noncarcinogens). They concluded that the p53 haploinsufficient model correctly identified 10 of 12 (83%) known human carcinogens, 11 of 19 (58%) suspected carcinogens, and was correctly negative for 27 of 28 (96%) putative noncarcinogens under the conditions of these short-term cancer bioassays. Thus, two known and eight suspected human carcinogens were not detected by the p53 haploinsufficient model. These authors also acknowledged that a number of procedural decisions may have increased the apparent accuracy scores for the mouse models studied. These included such things as accepting a single positive study in a given model as representing a positive response even if other studies of the same chemical were negative or gave equivocal findings in that model.

Clearly, the strength of the p53 haploinsufficient model is in its specificity for correctly identifying known or suspected carcinogens, but its sensitivity to detect carcinogens is a weakness. Because this model either did not identify or only equivocally identified a significant number of known or suspected human carcinogens, negative findings with this model as shown in the current study are of uncertain value.

The p53 haploinsufficient mouse model has been extensively evaluated as an alternative or adjunct assay to the traditional 2-year rodent bioassay (Pritchard et al., 2003). In contrast, the Cdkn2a deficient model has seen extremely limited use in this regard, and its ultimate utility as a general chemical cancer screen is uncertain. Inactivation of the p16 gene is seen in a high percentage of human cases of glioma, head and neck squamous cell carcinoma, melanoma, and other cancers (Reed et al., 1996; Liggett and Sidransky, 1998). The p16 gene encodes a cell cycle protein that inhibits CDK4 kinases 4 and 6, which in turn prevent phosphorylation of the Rb protein. This provides a normal control to cell cycle progression from G_1_ to S phase. Like the p53 haploinsufficient model, mutations to the p16 gene lead to dysregulation of cell proliferation and should make the mice susceptible to rapid tumor development when exposed to carcinogens. Aspartame had no effect on incidences of neoplasms in this model, but seemed to slightly increase the incidence of mild nephropathy in 50,000 ppm males. Whether this can be ascribed to aspartame or to biological variation is uncertain. The model demonstrated a fairly high background tumor rate for histiocytic sarcoma (2/15 in males and 5/15 in females). Studies of two known rodent carcinogens, phenolphthalein and glycidol, and of the known human carcinogen benzene are underway with the Cdkn2a deficient model, and the results should afford a better comparison of the relative cancer responses of the Cdkn2a deficient and p53 haploinsufficient models.

In summary, there was no evidence of a positive response for papilloma formation in the forestomach or for tumors at other sites in male or female Tg.AC hemizygous mice or for tumors at any site in male or female p53 haploinsufficient mice administered aspartame in feed at concentrations up to 50,000 ppm for 9 months. There was also no evidence of enhanced tumor formation in male or female Cdkn2a deficient mice; this model is currently uncharacterized in terms of its expected response to known rodent and/or human carcinogens and noncarcinogens.

Although there were no increases in neoplasm incidences in any of the mouse models used in these studies, there was a significant increase in the frequency of micronucleated normochromatic erythrocytes at the end of the exposure period in female p53 haploinsufficient mice that received a diet containing 50,000 ppm aspartame. The increase was statistically significant, but the response was small, approximately only one additional micronuclei per 1,000 cells. There was no significant increase in micronucleated erythrocytes in male p53 haploinsufficient mice or in Tg.AC hemizygous or Cdkn2a deficient mice of either sex. In a review of the results of NTP prechronic and chronic studies in which peripheral blood micronuclei had been evaluated in B6C3F_1_ mice, Witt et al. (2000) considered a small increase in magnitude and response and/or a response in only one sex as a weak response, and concluded that weak responses were not well correlated with rodent carcinogenicity and were of uncertain biological significance. By contrast, clearly positive results (determined by the magnitude of the increase in micronucleus frequency and observation of response in both sexes) were associated with high predictivity for rodent carcinogenicity. Because the peripheral blood micronucleus tests are incorporated into the subchronic toxicity assays, they are not repeated and therefore, confirmatory data are not available.

## Conclusions

Under the conditions of this 9-month feed study, there was no evidence of carcinogenic activity^*^ of aspartame in male or female p53 haploinsufficient mice exposed to 3,125, 6,250, 12,500, 25,000, or 50,000 ppm. Because this is a new model, there is uncertainty whether the study possessed sufficient sensitivity to detect a carcinogenic effect.

* Explanation of Levels of Evidence of Carcinogenic Activity is on page 9. A summary of the Technical Report Review Subcommittee comments and public discussion on this report appears on page 11.