# RESULTS

## 9-Month Study in Tg.AC Hemizygous Mice

### Positive Control Tg.AC Hemizygous Mice

12-O-Tetradecanoylphorbol-13-acetate (TPA) (1.25 µg) was dermally administered to groups of 15 males and 15 females three times weekly for up to 29 weeks. Ninety-three percent of males and females developed more than 20 skin papillomas each by week 16 (data not shown). This is consistent with historical rates found in other studies (Tennant et al., 2001).

### Survival

Estimates of 9-month survival probabilities for male and female mice are shown in Table 2 and in the Kaplan-Meier survival curves (Figure 3). Survival of all exposed groups was similar to that of the control groups.

TABLE 2 Survival of Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Male
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Moribund | 3 | 3 | 4 | 2 | 3 | 4
Natural deaths | 3 | 0 | 3 | 1 | 1 | 1
Animals surviving to study termination | 9 | 12 | 8 | 12 | 11 | 10
Percent probability of survival at end of study^a^ | 60 | 80 | 53 | 80 | 73 | 67
Mean survival (days)^b^ | 249 | 269 | 224 | 264 | 250 | 248
Survival analysis^c^ | P=1.000N | P=0.362N | P=0.768 | P=0.399N | P=0.771N | P=1.000N
Female
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Moribund | 3 | 2 | 3 | 4 | 3 | 2
Natural deaths | 1 | 3 | 3 | 2 | 1 | 5
Animals surviving to study termination | 11 | 10 | 9 | 9 | 11 | 8
Percent probability of survival at end of study | 73 | 67 | 60 | 60 | 73 | 53
Mean survival (days) | 256 | 247 | 218 | 233 | 257 | 219
Survival analysis | P=0.454 | P=0.916 | P=0.541 | P=0.596 | P=1.000N | P=0.329

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice).

c The result of the life table trend test (Tarone, 1975) is in the control column, and the results of the life table pairwise comparisons (Cox, 1972) with the controls are in the exposed group columns. A negative trend or lower mortality in an exposed group is indicated by N.

FIGURE 3 Kaplan-Meier Survival Curves for Male and Female Tg.AC Hemizygous Mice Exposed to Aspartame in Feed for 9 Months

### Body Weights, Feed and Compound Consumption, and Clinical Findings

Mean body weights of all exposed groups of males and of 3,125, 6,250, 12,500, and 25,000 ppm females were generally similar to those of the control groups throughout the study; mean body weights of 50,000 ppm females were greater than those of the controls after week 15 (Tables 3 and 4, and Figure 4). Feed consumption by the exposed groups was similar to that by the control groups (Tables J1 and J2). Dietary concentrations of 3,125, 6,250, 12,500, 25,000 and 50,000 ppm delivered average daily doses of approximately 490, 980, 1,960, 3,960 and 7,660 mg aspartame/kg body weight to males and 550, 1,100, 2,260, 4,420, and 8,180 mg/kg to females. Clinical findings included jaw masses, malocclusions, and cutaneous papillomas, but these findings were not considered related to aspartame exposure.

### Organ Weights and Organ-Weight-to-Body-Weight Ratios

There was a significant increase in the absolute brain weight of 50,000 ppm males, and a significant increase in the relative brain weight of 25,000 ppm males (Table H1). Relative kidney weights were increased in 25,000 and 50,000 ppm males. Relative heart weights were also increased in some exposure groups but no exposure concentration-related response was apparent.

TABLE 3 Mean Body Weights and Survival of Male Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame

Weeks on Study | 0 ppm | | 3,125 ppm | | | 6,250 ppm | | | 12,500 ppm | | | 25,000 ppm | | | 50,000 ppm
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 19.1 | 15 | 19.2 | 101 | 15 | 19.1 | 100 | 15 | 17.8 | 93 | 15 | 19.1 | 100 | 15 | 18.6 | 97 | 15
2 | 21.5 | 15 | 21.3 | 99 | 15 | 20.1 | 94 | 15 | 20.3 | 94 | 15 | 21.7 | 101 | 15 | 20.8 | 97 | 15
3 | 21.9 | 15 | 22.0 | 101 | 15 | 21.8 | 100 | 15 | 21.2 | 97 | 15 | 22.1 | 101 | 15 | 22.0 | 101 | 15
4 | 22.6 | 15 | 23.2 | 103 | 15 | 22.7 | 100 | 15 | 22.3 | 99 | 15 | 23.3 | 103 | 15 | 22.7 | 100 | 15
5 | 23.8 | 15 | 23.7 | 100 | 15 | 23.6 | 99 | 15 | 23.1 | 97 | 15 | 23.9 | 100 | 15 | 23.6 | 99 | 15
6 | 24.6 | 15 | 23.2 | 94 | 15 | 24.6 | 100 | 15 | 23.5 | 96 | 15 | 25.0 | 102 | 15 | 23.8 | 97 | 15
7 | 25.2 | 15 | 24.8 | 98 | 15 | 25.7 | 102 | 15 | 23.9 | 95 | 15 | 25.4 | 101 | 15 | 24.9 | 99 | 15
8 | 26.0 | 15 | 25.0 | 96 | 15 | 25.8 | 99 | 15 | 24.8 | 95 | 15 | 25.9 | 100 | 15 | 24.6 | 95 | 15
9 | 26.3 | 15 | 25.9 | 99 | 15 | 26.8 | 102 | 15 | 25.6 | 97 | 15 | 26.1 | 99 | 15 | 25.5 | 97 | 15
10 | 27.4 | 15 | 26.4 | 96 | 15 | 26.7 | 97 | 15 | 26.1 | 95 | 15 | 26.4 | 96 | 15 | 26.2 | 96 | 15
11 | 28.2 | 15 | 26.7 | 95 | 15 | 27.5 | 98 | 15 | 26.8 | 95 | 15 | 27.5 | 98 | 15 | 26.8 | 95 | 15
12 | 28.5 | 14 | 26.2 | 92 | 15 | 28.0 | 98 | 14 | 26.6 | 93 | 15 | 26.7 | 94 | 15 | 27.0 | 95 | 15
13 | 28.8 | 14 | 27.4 | 95 | 15 | 28.3 | 98 | 14 | 27.0 | 94 | 15 | 27.9 | 97 | 15 | 27.4 | 95 | 15
14 | 29.0 | 14 | 27.1 | 93 | 15 | 27.8 | 96 | 14 | 27.2 | 94 | 15 | 28.1 | 97 | 15 | 27.6 | 95 | 15
15 | 29.5 | 14 | 28.5 | 97 | 15 | 29.2 | 99 | 14 | 28.0 | 95 | 15 | 28.5 | 97 | 14 | 28.1 | 95 | 15
16 | 29.5 | 14 | 27.8 | 94 | 15 | 28.8 | 98 | 14 | 27.9 | 95 | 15 | 28.4 | 96 | 14 | 27.8 | 94 | 15
17 | 29.2 | 14 | 27.9 | 96 | 15 | 29.1 | 100 | 14 | 28.3 | 97 | 15 | 29.0 | 99 | 14 | 28.6 | 98 | 15
18 | 29.5 | 14 | 28.6 | 97 | 15 | 29.2 | 99 | 14 | 28.3 | 96 | 15 | 28.8 | 98 | 14 | 28.6 | 97 | 15
19 | 29.1 | 14 | 29.4 | 101 | 15 | 29.7 | 102 | 14 | 28.2 | 97 | 15 | 29.3 | 101 | 14 | 28.4 | 98 | 15
20 | 29.7 | 14 | 29.0 | 98 | 15 | 29.9 | 101 | 13 | 28.6 | 96 | 15 | 29.9 | 101 | 14 | 28.9 | 97 | 15
21 | 30.2 | 14 | 29.6 | 98 | 15 | 30.3 | 100 | 12 | 29.0 | 96 | 15 | 29.6 | 98 | 13 | 29.4 | 97 | 14
22 | 30.4 | 14 | 29.1 | 96 | 15 | 29.7 | 98 | 12 | 29.0 | 95 | 15 | 29.4 | 97 | 13 | 28.5 | 94 | 14
23 | 30.8 | 14 | 29.1 | 95 | 15 | 29.9 | 97 | 11 | 29.2 | 95 | 15 | 29.7 | 96 | 13 | 28.4 | 92 | 14
24 | 30.7 | 14 | 28.8 | 94 | 15 | 30.1 | 98 | 11 | 29.9 | 97 | 15 | 30.0 | 98 | 13 | 27.9 | 91 | 14
25 | 31.1 | 14 | 29.1 | 94 | 15 | 30.5 | 98 | 11 | 30.0 | 97 | 15 | 29.6 | 95 | 13 | 28.0 | 90 | 14
26 | 30.8 | 14 | 29.4 | 96 | 15 | 30.7 | 100 | 11 | 30.0 | 97 | 15 | 30.3 | 98 | 13 | 27.2 | 88 | 14
27 | 31.3 | 13 | 29.4 | 94 | 15 | 30.7 | 98 | 11 | 29.7 | 95 | 15 | 30.5 | 97 | 13 | 29.0 | 93 | 12
28 | 31.5 | 13 | 29.3 | 93 | 15 | 30.5 | 97 | 11 | 29.7 | 94 | 15 | 30.7 | 98 | 13 | 29.7 | 94 | 12
29 | 31.4 | 12 | 28.8 | 92 | 15 | 30.0 | 96 | 10 | 30.1 | 96 | 15 | 30.9 | 98 | 13 | 30.0 | 96 | 12
30 | 31.8 | 12 | 30.2 | 95 | 14 | 30.0 | 94 | 10 | 30.7 | 97 | 14 | 31.1 | 98 | 13 | 30.9 | 97 | 11
31 | 31.5 | 12 | 30.4 | 97 | 14 | 30.6 | 97 | 9 | 30.5 | 97 | 13 | 31.0 | 98 | 13 | 30.9 | 98 | 11
32 | 31.1 | 12 | 30.6 | 98 | 14 | 30.9 | 99 | 9 | 30.1 | 97 | 13 | 31.3 | 101 | 13 | 31.0 | 100 | 11
33 | 31.1 | 12 | 30.6 | 98 | 14 | 30.8 | 99 | 9 | 30.0 | 97 | 13 | 31.1 | 100 | 13 | 31.2 | 100 | 11
34 | 31.3 | 12 | 30.5 | 97 | 14 | 31.2 | 100 | 9 | 30.3 | 97 | 13 | 30.8 | 98 | 13 | 30.5 | 97 | 11
35 | 31.6 | 12 | 30.6 | 97 | 14 | 30.7 | 97 | 9 | 30.8 | 98 | 13 | 30.3 | 96 | 13 | 31.1 | 98 | 11
36 | 32.0 | 12 | 30.6 | 96 | 14 | 31.7 | 99 | 9 | 31.3 | 98 | 13 | 29.8 | 93 | 12 | 31.6 | 99 | 11
37 | 32.0 | 12 | 30.1 | 94 | 14 | 31.9 | 100 | 9 | 30.9 | 97 | 13 | 29.7 | 93 | 12 | 31.2 | 98 | 11
38 | 31.7 | 12 | 30.9 | 98 | 14 | 31.6 | 100 | 9 | 31.2 | 98 | 13 | 30.3 | 96 | 12 | 31.3 | 99 | 11
39 | 31.8 | 12 | 31.1 | 98 | 14 | 31.8 | 100 | 9 | 31.3 | 98 | 13 | 31.7 | 100 | 11 | 31.2 | 98 | 11
40 | 32.8 | 9 | 31.3 | 95 | 12 | 32.1 | 98 | 8 | 31.2 | 95 | 12 | 31.2 | 95 | 11 | 31.7 | 97 | 10
Mean for weeks
1–13 | 24.9 | | 24.2 | 97 | | 24.7 | 99 | | 23.8 | 96 | | 24.7 | 99 | | 24.1 | 97
14–40 | 30.8 | | 29.5 | 96 | | 30.3 | 98 | | 29.7 | 96 | | 30.0 | 97 | | 29.6 | 96

TABLE 4 Mean Body Weights and Survival of Female Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame

Weeks on Study | 0 ppm | | 3,125 ppm | | | 6,250 ppm | | | 12,500 ppm | | | 25,000 ppm | | | 50,000 ppm
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 16.6 | 15 | 16.6 | 100 | 15 | 15.8 | 95 | 15 | 15.5 | 93 | 15 | 16.4 | 99 | 15 | 16.6 | 100 | 15
2 | 18.1 | 15 | 18.0 | 99 | 15 | 17.7 | 98 | 15 | 17.4 | 96 | 15 | 18.1 | 100 | 15 | 17.8 | 98 | 15
3 | 18.5 | 15 | 18.9 | 102 | 15 | 18.3 | 99 | 15 | 17.8 | 96 | 15 | 17.6 | 95 | 15 | 17.9 | 97 | 15
4 | 19.5 | 15 | 19.7 | 101 | 15 | 19.5 | 100 | 15 | 18.8 | 96 | 15 | 19.6 | 101 | 15 | 19.6 | 101 | 15
5 | 19.5 | 15 | 20.1 | 103 | 15 | 19.7 | 101 | 15 | 19.7 | 101 | 15 | 20.1 | 103 | 14 | 20.3 | 104 | 15
6 | 19.7 | 15 | 20.3 | 103 | 15 | 20.4 | 104 | 15 | 19.3 | 98 | 15 | 20.2 | 103 | 14 | 20.2 | 103 | 15
7 | 20.1 | 15 | 21.4 | 107 | 15 | 21.3 | 106 | 15 | 20.7 | 103 | 15 | 20.8 | 104 | 14 | 21.3 | 106 | 15
8 | 20.5 | 15 | 20.9 | 102 | 15 | 20.6 | 101 | 15 | 20.6 | 101 | 15 | 21.1 | 103 | 14 | 20.7 | 101 | 15
9 | 21.1 | 15 | 21.9 | 104 | 15 | 21.5 | 102 | 15 | 21.3 | 101 | 15 | 21.6 | 102 | 14 | 21.8 | 103 | 15
10 | 21.6 | 15 | 22.2 | 103 | 15 | 21.5 | 100 | 14 | 21.9 | 101 | 15 | 21.9 | 101 | 14 | 22.4 | 104 | 15
11 | 21.7 | 15 | 22.4 | 103 | 15 | 22.5 | 104 | 13 | 21.9 | 101 | 15 | 22.5 | 104 | 14 | 22.7 | 105 | 15
12 | 22.4 | 15 | 22.6 | 101 | 15 | 21.9 | 98 | 13 | 21.9 | 98 | 15 | 21.7 | 97 | 14 | 23.2 | 104 | 15
13 | 22.5 | 15 | 22.6 | 100 | 14 | 22.0 | 98 | 13 | 22.3 | 99 | 15 | 23.2 | 103 | 14 | 23.1 | 103 | 14
14 | 22.4 | 15 | 22.9 | 102 | 14 | 23.0 | 103 | 13 | 22.5 | 100 | 15 | 22.9 | 102 | 14 | 23.1 | 103 | 12
15 | 22.3 | 15 | 22.5 | 101 | 14 | 23.3 | 105 | 13 | 22.4 | 100 | 14 | 23.6 | 106 | 14 | 23.5 | 105 | 12
16 | 22.6 | 15 | 23.3 | 103 | 14 | 23.4 | 104 | 13 | 22.5 | 100 | 14 | 23.4 | 104 | 14 | 24.5 | 108 | 12
17 | 22.6 | 14 | 23.1 | 102 | 14 | 23.2 | 103 | 12 | 22.5 | 100 | 14 | 23.8 | 105 | 14 | 24.4 | 108 | 12
18 | 22.6 | 14 | 23.3 | 103 | 14 | 23.4 | 104 | 12 | 22.9 | 101 | 14 | 23.7 | 105 | 14 | 24.5 | 108 | 12
19 | 23.0 | 14 | 23.3 | 101 | 14 | 23.8 | 104 | 12 | 23.4 | 102 | 14 | 23.6 | 103 | 14 | 24.9 | 108 | 12
20 | 23.1 | 14 | 23.1 | 100 | 14 | 23.7 | 103 | 12 | 23.0 | 100 | 13 | 23.7 | 103 | 14 | 25.9 | 112 | 12
21 | 23.9 | 14 | 24.2 | 101 | 14 | 24.7 | 103 | 12 | 23.3 | 98 | 13 | 24.1 | 101 | 14 | 26.0 | 109 | 12
22 | 23.7 | 14 | 24.3 | 103 | 14 | 24.6 | 104 | 11 | 22.9 | 97 | 13 | 24.2 | 102 | 14 | 25.7 | 108 | 12
23 | 24.4 | 14 | 24.6 | 101 | 14 | 24.6 | 101 | 11 | 23.1 | 95 | 13 | 23.9 | 98 | 14 | 25.7 | 105 | 11
24 | 24.4 | 14 | 24.1 | 99 | 14 | 24.8 | 102 | 11 | 23.1 | 95 | 13 | 24.3 | 100 | 14 | 26.1 | 107 | 11
25 | 24.4 | 14 | 25.2 | 103 | 14 | 25.0 | 103 | 11 | 24.0 | 98 | 11 | 24.4 | 100 | 14 | 26.2 | 107 | 11
26 | 24.9 | 14 | 25.6 | 103 | 14 | 25.0 | 100 | 11 | 23.9 | 96 | 11 | 24.7 | 99 | 14 | 26.1 | 105 | 11
27 | 25.1 | 14 | 25.6 | 102 | 14 | 24.9 | 99 | 11 | 23.5 | 94 | 11 | 24.9 | 99 | 14 | 26.3 | 105 | 11
28 | 25.3 | 14 | 25.2 | 100 | 14 | 25.1 | 99 | 11 | 25.0 | 99 | 10 | 25.1 | 99 | 14 | 27.3 | 108 | 10
29 | 25.3 | 14 | 25.4 | 100 | 13 | 24.9 | 98 | 11 | 24.9 | 98 | 10 | 25.0 | 99 | 14 | 27.5 | 109 | 10
30 | 26.0 | 13 | 25.0 | 96 | 12 | 25.6 | 99 | 10 | 25.4 | 98 | 10 | 24.8 | 95 | 14 | 27.2 | 105 | 10
31 | 25.8 | 13 | 25.1 | 97 | 11 | 26.3 | 102 | 9 | 25.1 | 97 | 10 | 24.4 | 95 | 14 | 27.9 | 108 | 10
32 | 25.1 | 13 | 25.1 | 100 | 11 | 26.1 | 104 | 9 | 25.3 | 101 | 10 | 24.3 | 97 | 14 | 28.0 | 112 | 9
33 | 25.6 | 13 | 25.1 | 98 | 11 | 26.4 | 103 | 9 | 25.0 | 98 | 10 | 24.6 | 96 | 14 | 27.8 | 109 | 9
34 | 25.6 | 13 | 25.1 | 98 | 11 | 26.6 | 104 | 9 | 25.4 | 99 | 10 | 24.7 | 97 | 14 | 27.9 | 109 | 9
35 | 25.4 | 13 | 26.0 | 102 | 11 | 26.9 | 106 | 9 | 26.1 | 103 | 10 | 25.3 | 100 | 14 | 27.7 | 109 | 9
36 | 26.1 | 12 | 25.7 | 99 | 11 | 27.8 | 107 | 9 | 26.3 | 101 | 10 | 25.0 | 96 | 14 | 27.8 | 107 | 9
37 | 25.9 | 12 | 25.4 | 98 | 11 | 27.6 | 107 | 9 | 25.8 | 100 | 10 | 24.7 | 95 | 14 | 27.2 | 105 | 9
38 | 26.2 | 12 | 26.2 | 100 | 11 | 27.0 | 103 | 9 | 26.0 | 99 | 10 | 24.6 | 94 | 14 | 28.1 | 107 | 9
39 | 26.5 | 12 | 26.4 | 100 | 11 | 27.6 | 104 | 9 | 26.4 | 100 | 10 | 24.8 | 94 | 14 | 28.0 | 106 | 9
40 | 26.7 | 11 | 25.4 | 95 | 10 | 26.9 | 101 | 9 | 26.5 | 99 | 9 | 26.5 | 99 | 11 | 28.3 | 106 | 8
Mean for weeks
1–13 | 20.1 | | 20.6 | 102 | | 20.2 | 100 | | 19.9 | 99 | | 20.4 | 101 | | 20.6 | 102
14–40 | 24.6 | | 24.7 | 100 | | 25.3 | 103 | | 24.3 | 99 | | 24.4 | 98 | | 26.4 | 107

FIGURE 4 Growth Curves for Male and Female Tg.AC Hemizygous Mice Exposed to Aspartame in Feed for 9 Months

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the lung, salivary gland, testis and epididymis, brain, and adrenal gland. Summaries of the incidences of neoplasms and nonneoplastic lesions, individual animal tumor diagnoses, and statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group are presented in Appendix A for males and Appendix B for females.

Lung: Alveolar/bronchiolar adenomas were seen in a few 6,250, 12,500, 25,000, and 50,000 ppm males (0 ppm, 0/14; 3,125 ppm, 0/15; 6,250 ppm, 2/14; 12,500 ppm, 1/15; 25,000 ppm, 2/14; 50,000 ppm, 2/14; Table A3).

Salivary Gland: Carcinomas were seen in a few 6,250, 25,000, and 50,000 ppm males (0/15, 0/15, 2/15, 0/15, 1/15, 1/15), and in 12,500 and 50,000 ppm females (0/15, 0/15, 0/15, 1/15, 0/15, and 1/15; Tables A3 and B3). No adenomas were observed in these studies.

Testis and Epididymis: The occurrence of germ cell degeneration of the testis was increased in all exposed groups of males (Tables 5 and A4). The lesion was predominantly unilateral, diffusely affecting the testis with mild to moderate severity, and often accompanied by dilated seminiferous tubules, cystic rete testes, aspermia of the epididymis, and occasional granulomas in the epididymis. The germ cell degeneration was consistent with obstruction atrophy of the testes as described by McIntyre et al., (2002). The spermatic outflow tract obstruction can be anywhere downstream of the testes, and there is subsequent pressure atrophy of the testis leading to degeneration and aspermia. The lack of exposure concentration-related response, the predominant finding of unilateral rather than bilateral lesions, and the fact that the findings were limited to the Tg.AC hemizygous strain argue against a relationship to aspartame exposure.

Brain: There were four incidences of nonneoplastic focal lesions: a brain abscess in one 25,000 ppm female, focal cortical neuronal necrosis in one 6,250 ppm female, and focal cortical degeneration in one 50,000 ppm male and one 50,000 ppm female (Tables 5, A4, and B4). The lesions are considered incidental and unrelated to exposure. They may be related to a condition described in the parent FVB/N strain in which mice are susceptible to spontaneous seizures and exhibit secondary neuronal necrosis microscopically (Goelz et al., 1998).

Adrenal Gland: The incidences of focal subcapsular adrenocortical hyperplasia were decreased in all exposed groups of females, and the decreases in 12,500 and 25,000 ppm females were significant (Tables 5 and B4). The incidences of focal hypertrophy of the adrenal cortex were decreased in all exposed groups of males (Tables 5 and A4). The incidences of adrenal cortex atrophy tended to decrease at higher exposure concentrations in males; however, in females the incidences at the higher exposure concentrations were slightly increased when compared with controls. The differences in these lesion incidences were not considered related to aspartame exposure.

TABLE 5 Incidences of Selected Nonneoplastic Lesions in Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Male
Adrenal Cortex^a^ | 13 | 15 | 13 | 14 | 15 | 13
Atrophy^b^ | 10 (2.1)^c^ | 12 (1.6) | 8 (1.4) | 9 (1.2) | 8 (1.5) | 6 (1.2)
Hypertrophy, Focal | 9 (1.0) | 5^*^ (1.0) | 5 (1.0) | 6 (1.0) | 7 (1.0) | 5 (1.0)
Brain | 15 | 15 | 13 | 14 | 14 | 15
Cortex, Cerebrum, Degeneration, Focal | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Epididymis | 15 | 15 | 15 | 15 | 15 | 15
Aspermia, Bilateral | 0 | 1 | 0 | 0 | 0 | 0
Aspermia (includes bilateral) | 1 | 4 | 4 | 2 | 3 | 2
Testes | 15 | 15 | 15 | 14 | 15 | 15
Germinal Epithelium Degeneration, Bilateral | 0 | 2 (3.0) | 0 | 1 (1.0) | 0 | 1 (2.0)
Germinal Epithelium, Degeneration (includes bilateral) | 1 (3.0) | 4 (3.0) | 4 (2.5) | 3 (2.0) | 3 (2.3) | 4 (2.5)
Female
Adrenal Cortex | 15 | 12 | 13 | 13 | 14 | 15
Atrophy | 3 (2.0) | 2 (2.0) | 1 (1.0) | 4 (1.0) | 5 (1.6) | 5 (1.4)
Subcapsular, Hyperplasia, Focal | 12 (1.0) | 6 (1.0) | 6 (1.0) | 5^*^ (1.0) | 6^*^ (1.0) | 6 (1.0)
Brain | 15 | 12 | 13 | 13 | 14 | 11
Abscess, Focal | 0 | 0 | 0 | 0 | 1 (3.0) | 0
Cortex, Cerebrum, Degeneration, Focal | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Cortex, Cerebrum, Neuron, Necrosis | 0 | 0 | 1 (1.0) | 0 | 0 | 0

* Significantly different (P≤0.05) from the control group by the Poly-3 test

a Number of animals with tissue examined microscopically

b Number of animals with lesion

c Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

## 9-Month Study in p53 Haploinsufficient Mice

### Survival

Estimates of 9-month survival probabilities for male and female mice are shown in Table 6. Survival of all exposed groups was similar to that of the control groups.

### Body Weights, Feed and Compound Consumption, and Clinical Findings

Mean body weights of exposed males were generally similar to those of controls through week 28. Mean body weights of 6,250, 12,500, 25,000, and 50,000 ppm males were less than those of the controls for several weeks near the end of the study (Figure 5 and Table 7). Mean body weights of all exposed groups of females were similar to those of the control groups (Figure 5 and Table 8). Feed consumption by the exposed groups was similar to that by the control groups (Tables J3 and J4). Dietary concentrations of 3,125, 6,250, 12,500, 25,000, and 50,000 ppm aspartame delivered average daily doses of approximately 490, 970, 1,860, 3,800, and 7,280 mg/kg to males and 630, 1,210, 2,490, 5,020, and 9,620 mg/kg to females. There were no clinical findings related to aspartame exposure.

### Organ Weights and Organ-Weight-to-Body-Weight Ratios

There were no chemical-related differences in absolute or relative organ weights in males or females (Table H2).

### Pathology and Statistical Analyses

There were no neoplasms or nonneoplastic lesions in p53 haploinsufficient mice that were attributed to exposure to aspartame. Summaries of the incidences of neoplasms and nonneoplastic lesions, individual animal tumor diagnoses, and statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group are presented in Appendix C for males and Appendix D for females.

TABLE 6 Survival of p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Male
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Moribund | 0 | 0 | 1 | 0 | 0 | 1
Natural deaths | 1 | 0 | 1 | 0 | 1 | 0
Animals surviving to study termination | 14 | 15 | 13 | 15 | 14 | 14
Percent probability of survival at end of study^a^ | 93 | 100 | 87 | 100 | 93 | 93
Mean survival (days)^b^ | 263 | 274 | 259 | 274 | 259 | 261
Survival analysis^c^ | P=1.000 | P=1.000N | P=1.000 | P=1.000N | P=1.000 | P=1.000
Female
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Moribund | 1 | 0 | 1 | 0 | 0 | 0
Natural deaths | 0 | 1 | 0 | 0 | 0 | 0
Animals surviving to study termination | 14 | 14 | 14 | 15 | 15 | 15
Percent probability of survival at end of study | 93 | 93 | 93 | 100 | 100 | 100
Mean survival (days) | 259 | 263 | 268 | 275 | 275 | 275
Survival analysis | P=0.363N | P=1.000N | P=1.000N | P=1.000N | P=1.000N | P=1.000N

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice).

c The result of the life table trend test (Tarone, 1975) is in the control column, and the results of the life table pairwise comparisons (Cox, 1972) with the controls are in the exposed group columns. A negative trend or lower mortality in an exposed group is indicated by N.

FIGURE 5 Growth Curves for Male and Female p53 Haploinsufficient Mice Exposed to Aspartame in Feed for 9 Months

TABLE 7 Mean Body Weights and Survival of Male p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame

Weeks on Study | 0 ppm | | 3,125 ppm | | | 6,250 ppm | | | 12,500 ppm | | | 25,000 ppm | | | 50,000 ppm
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 20.9 | 15 | 20.3 | 97 | 15 | 20.1 | 96 | 15 | 20.1 | 96 | 15 | 20.2 | 97 | 15 | 20.2 | 97 | 15
2 | 22.0 | 15 | 21.8 | 99 | 15 | 21.4 | 97 | 15 | 20.9 | 95 | 15 | 21.5 | 98 | 15 | 21.4 | 97 | 15
3 | 22.6 | 15 | 22.3 | 99 | 15 | 22.2 | 98 | 15 | 21.6 | 96 | 15 | 21.8 | 97 | 15 | 21.6 | 96 | 15
4 | 22.8 | 15 | 23.0 | 101 | 15 | 22.4 | 98 | 15 | 22.5 | 99 | 15 | 22.8 | 100 | 15 | 22.5 | 99 | 15
5 | 23.5 | 15 | 23.6 | 100 | 15 | 22.9 | 97 | 15 | 22.9 | 97 | 15 | 23.3 | 99 | 15 | 23.0 | 98 | 15
6 | 24.0 | 15 | 24.1 | 100 | 15 | 23.7 | 99 | 15 | 23.4 | 98 | 15 | 23.9 | 100 | 15 | 23.3 | 97 | 15
7 | 24.8 | 15 | 24.7 | 100 | 15 | 24.2 | 98 | 15 | 23.9 | 96 | 15 | 24.6 | 99 | 15 | 24.1 | 97 | 15
8 | 25.7 | 15 | 25.5 | 99 | 15 | 24.5 | 95 | 15 | 24.6 | 96 | 15 | 24.7 | 96 | 14 | 24.5 | 95 | 15
9 | 26.1 | 15 | 25.9 | 99 | 15 | 24.9 | 95 | 15 | 24.9 | 95 | 15 | 25.4 | 97 | 14 | 24.8 | 95 | 15
10 | 26.6 | 15 | 26.2 | 99 | 15 | 25.3 | 95 | 15 | 25.6 | 96 | 15 | 26.1 | 98 | 14 | 25.5 | 96 | 15
11 | 27.0 | 15 | 26.7 | 99 | 15 | 25.5 | 94 | 15 | 26.0 | 96 | 15 | 26.6 | 99 | 14 | 25.8 | 96 | 14
12 | 27.1 | 15 | 27.2 | 100 | 15 | 25.9 | 96 | 15 | 26.5 | 98 | 15 | 27.3 | 101 | 14 | 26.5 | 98 | 14
13 | 27.6 | 15 | 27.6 | 100 | 15 | 26.8 | 97 | 15 | 26.8 | 97 | 15 | 27.3 | 99 | 14 | 27.0 | 98 | 14
14 | 28.0 | 15 | 27.8 | 99 | 15 | 27.3 | 98 | 15 | 27.3 | 98 | 15 | 28.1 | 100 | 14 | 27.5 | 98 | 14
15 | 28.3 | 15 | 28.2 | 100 | 15 | 27.4 | 97 | 15 | 27.5 | 97 | 15 | 28.1 | 99 | 14 | 27.5 | 97 | 14
16 | 28.6 | 14 | 28.4 | 99 | 15 | 27.0 | 94 | 15 | 28.1 | 98 | 15 | 28.4 | 99 | 14 | 27.8 | 97 | 14
17 | 29.1 | 14 | 28.8 | 99 | 15 | 27.8 | 96 | 15 | 28.2 | 97 | 15 | 29.0 | 100 | 14 | 28.1 | 97 | 14
18 | 29.4 | 14 | 29.2 | 99 | 15 | 28.7 | 98 | 14 | 28.9 | 98 | 15 | 29.3 | 100 | 14 | 28.7 | 98 | 14
19 | 29.8 | 14 | 29.4 | 99 | 15 | 29.0 | 97 | 14 | 28.9 | 97 | 15 | 29.4 | 99 | 14 | 29.2 | 98 | 14
20 | 30.1 | 14 | 29.3 | 97 | 15 | 29.1 | 97 | 14 | 28.8 | 96 | 15 | 30.2 | 100 | 14 | 29.5 | 98 | 14
21 | 30.3 | 14 | 29.6 | 98 | 15 | 29.7 | 98 | 14 | 29.3 | 97 | 15 | 30.4 | 100 | 14 | 29.5 | 97 | 14
22 | 30.0 | 14 | 29.5 | 98 | 15 | 29.5 | 98 | 14 | 29.6 | 99 | 15 | 30.0 | 100 | 14 | 29.0 | 97 | 14
23 | 30.8 | 14 | 29.0 | 94 | 15 | 29.8 | 97 | 14 | 29.0 | 94 | 15 | 29.9 | 97 | 14 | 29.1 | 95 | 14
24 | 30.6 | 14 | 29.6 | 97 | 15 | 29.8 | 97 | 14 | 29.0 | 95 | 15 | 29.7 | 97 | 14 | 29.1 | 95 | 14
25 | 30.4 | 14 | 29.6 | 97 | 15 | 29.8 | 98 | 14 | 29.2 | 96 | 15 | 29.2 | 96 | 14 | 29.1 | 96 | 14
26 | 30.9 | 14 | 30.0 | 97 | 15 | 29.7 | 96 | 14 | 29.5 | 96 | 15 | 29.5 | 96 | 14 | 29.3 | 95 | 14
27 | 30.8 | 14 | 29.8 | 97 | 15 | 30.0 | 97 | 14 | 29.6 | 96 | 15 | 29.6 | 96 | 14 | 29.4 | 96 | 14
28 | 31.0 | 14 | 29.9 | 97 | 15 | 29.9 | 97 | 14 | 29.7 | 96 | 15 | 28.8 | 93 | 14 | 29.7 | 96 | 14
29 | 31.2 | 14 | 30.2 | 97 | 15 | 29.9 | 96 | 14 | 29.8 | 96 | 15 | 29.0 | 93 | 14 | 29.7 | 95 | 14
30 | 31.8 | 14 | 30.6 | 96 | 15 | 29.8 | 94 | 14 | 30.2 | 95 | 15 | 29.3 | 92 | 14 | 29.7 | 93 | 14
31 | 32.3 | 14 | 31.0 | 96 | 15 | 30.3 | 94 | 13 | 30.0 | 93 | 15 | 29.4 | 91 | 14 | 30.2 | 94 | 14
32 | 32.6 | 14 | 31.0 | 95 | 15 | 30.6 | 94 | 13 | 29.9 | 92 | 15 | 29.5 | 91 | 14 | 30.3 | 93 | 14
33 | 32.4 | 14 | 30.9 | 95 | 15 | 30.3 | 94 | 13 | 29.8 | 92 | 15 | 29.7 | 92 | 14 | 30.5 | 94 | 14
34 | 32.3 | 14 | 30.6 | 95 | 15 | 30.5 | 94 | 13 | 29.9 | 93 | 15 | 30.3 | 94 | 14 | 30.2 | 94 | 14
35 | 32.2 | 14 | 30.7 | 95 | 15 | 30.2 | 94 | 13 | 29.7 | 92 | 15 | 30.1 | 94 | 14 | 30.2 | 94 | 14
36 | 32.4 | 14 | 30.9 | 95 | 15 | 30.1 | 93 | 13 | 29.9 | 92 | 15 | 30.1 | 93 | 14 | 30.1 | 93 | 14
37 | 31.6 | 14 | 30.6 | 97 | 15 | 30.1 | 95 | 13 | 29.7 | 94 | 15 | 29.7 | 94 | 14 | 30.1 | 95 | 14
38 | 31.9 | 14 | 30.9 | 97 | 15 | 30.1 | 94 | 13 | 29.3 | 92 | 15 | 29.9 | 94 | 14 | 30.0 | 94 | 14
39 | 31.9 | 14 | 30.4 | 95 | 15 | 29.6 | 93 | 13 | 29.4 | 92 | 15 | 30.1 | 94 | 14 | 29.9 | 94 | 14
40 | 31.3 | 14 | 30.3 | 97 | 15 | 29.7 | 95 | 13 | 29.8 | 95 | 15 | 30.1 | 96 | 14 | 29.9 | 96 | 14
Mean for weeks
1–13 | 24.7 | | 24.5 | 99 | | 23.8 | 96 | | 23.8 | 96 | | 24.3 | 98 | | 23.9 | 97
14–40 | 30.8 | | 29.9 | 97 | | 29.5 | 96 | | 29.3 | 95 | | 29.5 | 96 | | 29.4 | 95

TABLE 8 Mean Body Weights and Survival of Female p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame

Weeks on Study | 0 ppm | | 3,125 ppm | | | 6,250 ppm | | | 12,500 ppm | | | 25,000 ppm | | | 50,000 ppm
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 16.9 | 15 | 16.4 | 97 | 15 | 16.8 | 99 | 15 | 16.3 | 96 | 15 | 16.4 | 97 | 15 | 16.1 | 95 | 15
2 | 18.5 | 15 | 18.1 | 98 | 15 | 18.2 | 98 | 15 | 18.1 | 98 | 15 | 18.2 | 98 | 15 | 17.7 | 96 | 15
3 | 19.6 | 15 | 19.2 | 98 | 15 | 18.9 | 96 | 15 | 18.7 | 95 | 15 | 19.0 | 97 | 15 | 18.6 | 95 | 15
4 | 20.0 | 15 | 20.2 | 101 | 15 | 19.9 | 100 | 15 | 19.9 | 100 | 15 | 20.1 | 101 | 15 | 19.3 | 97 | 15
5 | 20.8 | 15 | 20.5 | 99 | 15 | 20.5 | 99 | 15 | 20.3 | 98 | 15 | 20.1 | 97 | 15 | 19.9 | 96 | 15
6 | 21.0 | 15 | 20.5 | 98 | 15 | 21.2 | 101 | 15 | 20.6 | 98 | 15 | 20.6 | 98 | 15 | 20.3 | 97 | 15
7 | 20.7 | 14 | 20.7 | 100 | 15 | 20.5 | 99 | 15 | 20.6 | 100 | 15 | 20.8 | 101 | 15 | 19.9 | 96 | 15
8 | 21.5 | 14 | 20.9 | 97 | 15 | 21.4 | 100 | 15 | 21.3 | 99 | 15 | 21.0 | 98 | 15 | 21.3 | 99 | 15
9 | 21.7 | 14 | 21.5 | 99 | 15 | 22.0 | 101 | 15 | 21.4 | 99 | 15 | 21.7 | 100 | 15 | 21.3 | 98 | 15
10 | 22.1 | 14 | 21.8 | 99 | 15 | 22.0 | 100 | 15 | 22.2 | 101 | 15 | 21.7 | 98 | 15 | 21.9 | 99 | 15
11 | 22.1 | 14 | 22.0 | 100 | 15 | 22.4 | 101 | 15 | 22.3 | 101 | 15 | 22.2 | 101 | 15 | 21.8 | 99 | 15
12 | 22.0 | 14 | 22.0 | 100 | 15 | 22.6 | 103 | 15 | 22.5 | 102 | 15 | 22.3 | 101 | 15 | 21.9 | 100 | 15
13 | 22.2 | 14 | 22.6 | 102 | 15 | 23.4 | 105 | 15 | 22.5 | 101 | 15 | 22.5 | 101 | 15 | 22.3 | 101 | 15
14 | 22.6 | 14 | 23.0 | 102 | 15 | 23.5 | 104 | 15 | 22.9 | 101 | 15 | 22.9 | 101 | 15 | 22.6 | 100 | 15
15 | 22.9 | 14 | 23.2 | 101 | 14 | 23.9 | 104 | 15 | 22.9 | 100 | 15 | 23.6 | 103 | 15 | 22.9 | 100 | 15
16 | 22.7 | 14 | 23.3 | 103 | 14 | 24.0 | 106 | 15 | 23.3 | 103 | 15 | 23.4 | 103 | 15 | 23.1 | 102 | 15
17 | 23.1 | 14 | 23.4 | 101 | 14 | 24.0 | 104 | 15 | 23.6 | 102 | 15 | 22.9 | 99 | 15 | 23.0 | 100 | 15
18 | 23.3 | 14 | 23.4 | 100 | 14 | 24.4 | 105 | 15 | 24.4 | 105 | 15 | 23.3 | 100 | 15 | 23.5 | 101 | 15
19 | 23.6 | 14 | 23.5 | 100 | 14 | 24.8 | 105 | 15 | 24.6 | 104 | 15 | 23.6 | 100 | 15 | 23.6 | 100 | 15
20 | 23.7 | 14 | 23.8 | 100 | 14 | 24.8 | 105 | 15 | 25.1 | 106 | 15 | 23.8 | 100 | 15 | 24.1 | 102 | 15
21 | 23.7 | 14 | 23.5 | 99 | 14 | 25.1 | 106 | 15 | 25.1 | 106 | 15 | 24.0 | 101 | 15 | 24.3 | 103 | 15
22 | 24.1 | 14 | 23.7 | 98 | 14 | 25.0 | 104 | 15 | 25.1 | 104 | 15 | 23.7 | 98 | 15 | 24.0 | 100 | 15
23 | 24.0 | 14 | 23.4 | 98 | 14 | 25.3 | 105 | 15 | 24.9 | 104 | 15 | 23.7 | 99 | 15 | 23.6 | 98 | 15
24 | 24.2 | 14 | 23.8 | 98 | 14 | 25.5 | 105 | 15 | 24.7 | 102 | 15 | 23.8 | 98 | 15 | 24.2 | 100 | 15
25 | 24.2 | 14 | 23.6 | 98 | 14 | 25.4 | 105 | 14 | 24.7 | 102 | 15 | 23.5 | 97 | 15 | 24.1 | 100 | 15
26 | 24.3 | 14 | 23.7 | 98 | 14 | 25.7 | 106 | 14 | 25.1 | 103 | 15 | 24.3 | 100 | 15 | 24.4 | 100 | 15
27 | 23.9 | 14 | 23.4 | 98 | 14 | 25.7 | 108 | 14 | 25.1 | 105 | 15 | 24.0 | 100 | 15 | 24.2 | 101 | 15
28 | 24.5 | 14 | 23.4 | 96 | 14 | 25.8 | 105 | 14 | 25.1 | 102 | 15 | 23.9 | 98 | 15 | 24.3 | 99 | 15
29 | 24.2 | 14 | 23.4 | 97 | 14 | 25.8 | 107 | 14 | 25.1 | 104 | 15 | 24.0 | 99 | 15 | 24.4 | 101 | 15
30 | 25.0 | 14 | 24.1 | 96 | 14 | 25.5 | 102 | 14 | 25.8 | 103 | 15 | 24.2 | 97 | 15 | 24.3 | 97 | 15
31 | 25.2 | 14 | 24.1 | 96 | 14 | 25.7 | 102 | 14 | 26.0 | 103 | 15 | 24.5 | 97 | 15 | 24.7 | 98 | 15
32 | 25.3 | 14 | 24.4 | 96 | 14 | 25.8 | 102 | 14 | 25.8 | 102 | 15 | 24.3 | 96 | 15 | 24.6 | 97 | 15
33 | 24.9 | 14 | 24.0 | 96 | 14 | 25.8 | 104 | 14 | 25.9 | 104 | 15 | 24.5 | 98 | 15 | 25.0 | 100 | 15
34 | 25.2 | 14 | 24.5 | 97 | 14 | 25.9 | 103 | 14 | 25.9 | 103 | 15 | 24.9 | 99 | 15 | 24.6 | 98 | 15
35 | 25.2 | 14 | 24.7 | 98 | 14 | 25.8 | 102 | 14 | 25.8 | 102 | 15 | 24.9 | 99 | 15 | 24.5 | 97 | 15
36 | 25.4 | 14 | 24.7 | 97 | 14 | 26.4 | 104 | 14 | 26.0 | 102 | 15 | 25.1 | 99 | 15 | 24.9 | 98 | 15
37 | 25.3 | 14 | 24.6 | 97 | 14 | 26.3 | 104 | 14 | 26.0 | 103 | 15 | 25.0 | 99 | 15 | 24.8 | 98 | 15
38 | 25.7 | 14 | 24.4 | 95 | 14 | 26.6 | 104 | 14 | 26.0 | 101 | 15 | 25.4 | 99 | 15 | 25.1 | 98 | 15
39 | 25.7 | 14 | 24.4 | 95 | 14 | 26.5 | 103 | 14 | 25.8 | 100 | 15 | 25.4 | 99 | 15 | 25.0 | 97 | 15
40 | 26.1 | 14 | 24.3 | 93 | 14 | 26.2 | 100 | 14 | 25.4 | 97 | 15 | 25.3 | 97 | 15 | 25.1 | 96 | 15
Mean for weeks
1–13 | 20.7 | | 20.5 | 99 | | 20.8 | 100 | | 20.5 | 99 | | 20.5 | 99 | | 20.2 | 98
14–40 | 24.4 | | 23.8 | 98 | | 25.4 | 104 | | 25.0 | 102 | | 24.1 | 99 | | 24.2 | 99

## 9-Month Study in Cdkn2a deficient mice

Estimates of 9-month survival probabilities for male and female mice are shown in Table 9. Survival of all exposed groups was similar to that of the control groups.

### Body Weights, Feed and Compound Consumption, and Clinical Findings

Mean body weights of 3,125 ppm males after week 29 and of 6,250 ppm males after week 16 were less than those of the controls (Figure 6 and Table 10). Mean body weights of female mice were similar to those of the controls throughout the study (Figure 6 and Table 11). Feed consumption by exposed groups was similar to that by the control groups (Tables J5 and J6). Dietary concentrations of 3,125, 6,250, 12,500, 25,000, and 50,000 ppm aspartame delivered average daily doses of approximately 490, 960, 1,900, 3,700, and 7,400 mg/kg to males and 610, 1,200, 2,300, 4,850, and 9,560 mg/kg to females. There were no clinical findings related to aspartame exposure.

### Organ Weights and Organ-Weight-to-Body-Weight Ratios

No statistical differences were found in absolute organ weights, but relative lung weights of 6,250 and 25,000 ppm female mice were significantly decreased (Table H3).

TABLE 9 Survival of Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Male
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Natural deaths | 1 | 1 | 0 | 1 | 1 | 0
Animals surviving to study termination | 14 | 14 | 15 | 14 | 14 | 15
Percent probability of survival at end of study^a^ | 93 | 93 | 100 | 93 | 93 | 100
Mean survival (days)^b^ | 260 | 271 | 274 | 259 | 257 | 274
Survival analysis^c^ | P=0.741N | P=1.000N | P=1.000N | P=1.000 | P=1.000 | P=1.000N
Female
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Moribund | 0 | 0 | 0 | 0 | 0 | 1
Natural deaths | 2 | 0 | 2 | 0 | 0 | 0
Animals surviving to study termination | 13 | 15 | 13 | 15 | 15 | 14
Percent probability of survival at end of study | 87 | 100 | 87 | 100 | 100 | 93
Mean survival (days) | 254 | 275 | 260 | 275 | 275 | 275
Survival analysis | P=0.851N | P=0.464N | P=1.000 | P=0.464N | P=0.464N | P=0.951N

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice).

c The result of the life table trend test (Tarone, 1975) is in the control column, and the results of the life table pairwise comparisons (Cox 1972) with the controls are in the exposed group columns. A negative trend or lower mortality in an exposed group is indicated by N.

FIGURE 6 Growth Curves for Male and Female Cdkn2a Deficient Mice Exposed to Aspartame in Feed for 9 Months

TABLE 10 Mean Body Weights and Survival of Male Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame

Weeks on Study | 0 ppm | | 3,125 ppm | | | 6,250 ppm | | | 12,500 ppm | | | 25,000 ppm | | | 50,000 ppm
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 22.2 | 15 | 22.1 | 100 | 15 | 22.2 | 100 | 15 | 22.0 | 99 | 15 | 21.8 | 98 | 15 | 21.9 | 99 | 15
2 | 22.4 | 15 | 22.2 | 99 | 15 | 22.4 | 100 | 15 | 22.1 | 99 | 15 | 22.0 | 98 | 15 | 22.3 | 100 | 15
3 | 23.1 | 15 | 23.2 | 100 | 15 | 23.0 | 100 | 15 | 22.9 | 99 | 15 | 22.7 | 98 | 15 | 23.0 | 100 | 15
4 | 23.6 | 15 | 23.8 | 101 | 15 | 23.4 | 99 | 15 | 23.8 | 101 | 15 | 23.0 | 98 | 14 | 23.6 | 100 | 15
5 | 25.0 | 15 | 24.9 | 100 | 15 | 24.6 | 98 | 15 | 24.8 | 99 | 15 | 24.7 | 99 | 14 | 24.9 | 100 | 15
6 | 25.6 | 15 | 25.5 | 100 | 15 | 25.1 | 98 | 15 | 25.2 | 98 | 15 | 25.0 | 98 | 14 | 25.1 | 98 | 15
7 | 26.1 | 15 | 26.5 | 102 | 15 | 26.2 | 100 | 15 | 25.6 | 98 | 15 | 26.1 | 100 | 14 | 26.4 | 101 | 15
8 | 26.7 | 15 | 26.7 | 100 | 15 | 26.3 | 99 | 15 | 26.7 | 100 | 14 | 26.6 | 100 | 14 | 26.5 | 99 | 15
9 | 27.4 | 15 | 27.7 | 101 | 15 | 26.5 | 97 | 15 | 27.2 | 99 | 14 | 27.1 | 99 | 14 | 26.9 | 98 | 15
10 | 28.6 | 14 | 27.9 | 98 | 15 | 27.1 | 95 | 15 | 27.6 | 97 | 14 | 27.7 | 97 | 14 | 27.3 | 96 | 15
11 | 28.9 | 14 | 27.9 | 97 | 15 | 27.9 | 97 | 15 | 28.2 | 98 | 14 | 28.0 | 97 | 14 | 28.1 | 97 | 15
12 | 29.4 | 14 | 28.4 | 97 | 15 | 28.2 | 96 | 15 | 28.3 | 96 | 14 | 28.2 | 96 | 14 | 28.9 | 98 | 15
13 | 30.0 | 14 | 28.8 | 96 | 15 | 28.3 | 94 | 15 | 29.0 | 97 | 14 | 29.1 | 97 | 14 | 29.2 | 97 | 15
14 | 30.1 | 14 | 29.1 | 97 | 15 | 28.7 | 95 | 15 | 29.6 | 98 | 14 | 29.1 | 97 | 14 | 29.4 | 98 | 15
15 | 30.8 | 14 | 29.4 | 96 | 15 | 29.8 | 97 | 15 | 29.9 | 97 | 14 | 29.5 | 96 | 14 | 29.9 | 97 | 15
16 | 30.6 | 14 | 29.8 | 97 | 15 | 29.8 | 97 | 15 | 30.7 | 100 | 14 | 29.8 | 97 | 14 | 30.4 | 99 | 15
17 | 31.6 | 14 | 30.7 | 97 | 15 | 30.8 | 98 | 15 | 31.7 | 100 | 14 | 30.5 | 97 | 14 | 31.4 | 99 | 15
18 | 32.4 | 14 | 31.1 | 96 | 15 | 30.5 | 94 | 15 | 32.1 | 99 | 14 | 31.6 | 98 | 14 | 31.6 | 98 | 15
19 | 32.8 | 14 | 31.5 | 96 | 15 | 30.1 | 92 | 15 | 32.4 | 99 | 14 | 32.0 | 98 | 14 | 32.1 | 98 | 15
20 | 33.3 | 14 | 32.1 | 96 | 15 | 30.9 | 93 | 15 | 32.8 | 99 | 14 | 32.2 | 97 | 14 | 32.7 | 98 | 15
21 | 34.0 | 14 | 32.6 | 96 | 15 | 31.9 | 94 | 15 | 33.1 | 97 | 14 | 33.0 | 97 | 14 | 32.8 | 97 | 15
22 | 34.2 | 14 | 32.7 | 96 | 15 | 32.2 | 94 | 15 | 32.7 | 96 | 14 | 33.1 | 97 | 14 | 33.1 | 97 | 15
23 | 34.4 | 14 | 32.7 | 95 | 15 | 32.2 | 94 | 15 | 33.0 | 96 | 14 | 33.0 | 96 | 14 | 33.0 | 96 | 15
24 | 34.5 | 14 | 32.7 | 95 | 15 | 32.2 | 93 | 15 | 33.3 | 97 | 14 | 33.0 | 96 | 14 | 33.4 | 97 | 15
25 | 34.6 | 14 | 32.8 | 95 | 15 | 32.2 | 93 | 15 | 33.2 | 96 | 14 | 32.9 | 95 | 14 | 33.3 | 96 | 15
26 | 34.6 | 14 | 32.7 | 95 | 15 | 32.2 | 93 | 15 | 33.6 | 97 | 14 | 33.1 | 96 | 14 | 33.5 | 97 | 15
27 | 34.6 | 14 | 32.7 | 95 | 15 | 32.6 | 94 | 15 | 33.8 | 98 | 14 | 33.3 | 96 | 14 | 33.7 | 97 | 15
28 | 35.1 | 14 | 33.4 | 95 | 15 | 32.9 | 94 | 15 | 34.3 | 98 | 14 | 33.9 | 97 | 14 | 33.8 | 96 | 15
29 | 35.6 | 14 | 33.9 | 95 | 15 | 33.3 | 94 | 15 | 34.6 | 97 | 14 | 34.3 | 96 | 14 | 33.9 | 95 | 15
30 | 35.9 | 14 | 33.8 | 94 | 15 | 33.8 | 94 | 15 | 35.0 | 98 | 14 | 34.6 | 96 | 14 | 34.3 | 96 | 15
31 | 35.8 | 14 | 33.4 | 93 | 15 | 33.9 | 95 | 15 | 34.8 | 97 | 14 | 34.5 | 96 | 14 | 34.4 | 96 | 15
32 | 36.1 | 14 | 33.5 | 93 | 15 | 33.7 | 93 | 15 | 34.8 | 96 | 14 | 34.6 | 96 | 14 | 34.0 | 94 | 15
33 | 35.6 | 14 | 33.5 | 94 | 15 | 34.0 | 96 | 15 | 34.3 | 96 | 14 | 34.6 | 97 | 14 | 33.9 | 95 | 15
34 | 36.1 | 14 | 33.1 | 92 | 15 | 34.2 | 95 | 15 | 34.9 | 97 | 14 | 35.1 | 97 | 14 | 34.4 | 95 | 15
35 | 35.4 | 14 | 33.0 | 93 | 14 | 33.9 | 96 | 15 | 35.3 | 100 | 14 | 34.8 | 98 | 14 | 34.3 | 97 | 15
36 | 35.6 | 14 | 33.6 | 94 | 14 | 34.3 | 96 | 15 | 35.5 | 100 | 14 | 35.3 | 99 | 14 | 34.3 | 96 | 15
37 | 35.6 | 14 | 33.1 | 93 | 14 | 34.1 | 96 | 15 | 35.1 | 99 | 14 | 34.9 | 98 | 14 | 33.9 | 95 | 15
38 | 35.9 | 14 | 32.6 | 91 | 14 | 34.0 | 95 | 15 | 35.2 | 98 | 14 | 35.0 | 98 | 14 | 34.1 | 95 | 15
39 | 35.6 | 14 | 32.4 | 91 | 14 | 33.9 | 95 | 15 | 34.9 | 98 | 14 | 35.4 | 99 | 14 | 34.4 | 97 | 15
40 | 35.7 | 14 | 33.1 | 93 | 14 | 33.7 | 94 | 15 | 35.0 | 98 | 14 | 35.6 | 100 | 14 | 34.2 | 96 | 15
Mean for weeks
1–13 | 26.1 | | 25.8 | 99 | | 25.5 | 98 | | 25.6 | 98 | | 25.5 | 98 | | 25.7 | 98
14–40 | 34.3 | | 32.4 | 94 | | 32.4 | 94 | | 33.5 | 98 | | 33.3 | 97 | | 33.1 | 97

TABLE 11 Mean Body Weights and Survival of Female Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame

Weeks on Study | 0 ppm | | 3,125 ppm | | | 6,250 ppm | | | 12,500 ppm | | | 25,000 ppm | | | 50,000 ppm
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 17.9 | 15 | 18.4 | 103 | 15 | 18.3 | 102 | 15 | 18.2 | 102 | 15 | 17.9 | 100 | 15 | 18.2 | 102 | 15
2 | 18.7 | 15 | 19.0 | 102 | 15 | 18.4 | 98 | 15 | 18.6 | 100 | 15 | 18.6 | 100 | 15 | 18.8 | 101 | 15
3 | 19.8 | 14 | 20.3 | 103 | 15 | 19.8 | 100 | 15 | 20.0 | 101 | 15 | 19.6 | 99 | 15 | 20.0 | 101 | 15
4 | 20.7 | 14 | 21.0 | 101 | 15 | 20.6 | 100 | 15 | 20.8 | 101 | 15 | 20.3 | 98 | 15 | 20.7 | 100 | 15
5 | 21.2 | 14 | 21.6 | 102 | 15 | 21.9 | 103 | 15 | 21.4 | 101 | 15 | 20.9 | 99 | 15 | 21.9 | 103 | 15
6 | 22.1 | 14 | 22.3 | 101 | 15 | 22.4 | 101 | 15 | 22.3 | 101 | 15 | 21.8 | 99 | 15 | 22.5 | 102 | 15
7 | 22.5 | 14 | 23.0 | 102 | 15 | 22.6 | 100 | 15 | 22.8 | 101 | 15 | 22.3 | 99 | 15 | 22.6 | 100 | 15
8 | 21.8 | 14 | 22.3 | 102 | 15 | 22.6 | 104 | 15 | 22.9 | 105 | 15 | 22.0 | 101 | 15 | 22.5 | 103 | 15
9 | 22.7 | 14 | 23.1 | 102 | 15 | 23.0 | 101 | 15 | 23.0 | 101 | 15 | 22.1 | 97 | 15 | 22.8 | 100 | 15
10 | 23.1 | 14 | 23.4 | 101 | 15 | 22.8 | 99 | 15 | 23.7 | 103 | 15 | 22.8 | 99 | 15 | 23.1 | 100 | 15
11 | 23.0 | 14 | 23.6 | 103 | 15 | 23.7 | 103 | 15 | 23.9 | 104 | 15 | 22.9 | 100 | 15 | 23.6 | 103 | 15
12 | 23.3 | 14 | 24.1 | 103 | 15 | 24.0 | 103 | 15 | 24.7 | 106 | 15 | 23.1 | 99 | 15 | 23.9 | 103 | 15
13 | 23.5 | 14 | 24.5 | 104 | 15 | 23.8 | 101 | 15 | 25.0 | 106 | 15 | 23.8 | 101 | 15 | 23.9 | 102 | 15
14 | 23.3 | 14 | 24.2 | 104 | 15 | 24.0 | 103 | 15 | 24.6 | 106 | 15 | 23.3 | 100 | 15 | 24.2 | 104 | 15
15 | 24.3 | 14 | 25.0 | 103 | 15 | 25.1 | 103 | 15 | 25.1 | 103 | 15 | 23.8 | 98 | 15 | 24.8 | 102 | 15
16 | 24.3 | 14 | 24.9 | 103 | 15 | 25.1 | 103 | 15 | 25.3 | 104 | 15 | 23.7 | 98 | 15 | 24.5 | 101 | 15
17 | 24.4 | 14 | 25.7 | 105 | 15 | 26.1 | 107 | 14 | 25.8 | 106 | 15 | 24.2 | 99 | 15 | 25.6 | 105 | 15
18 | 24.8 | 14 | 25.8 | 104 | 15 | 26.1 | 105 | 14 | 25.8 | 104 | 15 | 24.9 | 100 | 15 | 25.7 | 104 | 15
19 | 25.1 | 14 | 26.3 | 105 | 15 | 26.1 | 104 | 14 | 26.2 | 104 | 15 | 25.1 | 100 | 15 | 25.8 | 103 | 15
20 | 25.3 | 14 | 26.7 | 106 | 15 | 25.5 | 101 | 14 | 26.3 | 104 | 15 | 25.1 | 99 | 15 | 26.0 | 103 | 15
21 | 25.7 | 14 | 27.2 | 106 | 15 | 26.1 | 102 | 14 | 26.9 | 105 | 15 | 25.6 | 100 | 15 | 26.5 | 103 | 15
22 | 25.4 | 14 | 27.0 | 106 | 15 | 26.7 | 105 | 14 | 26.8 | 106 | 15 | 25.4 | 100 | 15 | 26.5 | 104 | 15
23 | 25.3 | 14 | 26.8 | 106 | 15 | 26.7 | 106 | 14 | 26.6 | 105 | 15 | 25.7 | 102 | 15 | 26.7 | 106 | 15
24 | 25.7 | 14 | 27.2 | 106 | 15 | 26.9 | 105 | 14 | 26.5 | 103 | 15 | 25.4 | 99 | 15 | 26.6 | 104 | 15
25 | 25.9 | 14 | 27.4 | 106 | 15 | 26.4 | 102 | 14 | 26.7 | 103 | 15 | 25.3 | 98 | 15 | 26.2 | 101 | 15
26 | 26.2 | 14 | 27.3 | 104 | 15 | 26.7 | 102 | 14 | 26.8 | 102 | 15 | 25.4 | 97 | 15 | 26.2 | 100 | 15
27 | 25.6 | 14 | 26.9 | 105 | 15 | 26.5 | 104 | 14 | 27.0 | 106 | 15 | 25.6 | 100 | 15 | 26.7 | 104 | 15
28 | 26.2 | 14 | 27.9 | 107 | 15 | 27.4 | 105 | 14 | 27.4 | 105 | 15 | 25.9 | 99 | 15 | 26.9 | 103 | 15
29 | 26.8 | 14 | 28.1 | 105 | 15 | 27.0 | 101 | 14 | 27.6 | 103 | 15 | 26.1 | 97 | 15 | 26.7 | 100 | 15
30 | 26.4 | 14 | 28.5 | 108 | 15 | 27.2 | 103 | 14 | 27.8 | 105 | 15 | 26.4 | 100 | 15 | 27.1 | 103 | 15
31 | 25.6 | 14 | 28.2 | 110 | 15 | 28.3 | 111 | 14 | 27.7 | 108 | 15 | 26.3 | 103 | 15 | 27.5 | 107 | 15
32 | 26.2 | 14 | 28.1 | 107 | 15 | 27.8 | 106 | 13 | 27.7 | 106 | 15 | 26.7 | 102 | 15 | 27.4 | 105 | 15
33 | 26.8 | 13 | 28.0 | 105 | 15 | 28.1 | 105 | 13 | 27.5 | 103 | 15 | 26.5 | 99 | 15 | 27.6 | 103 | 15
34 | 27.1 | 13 | 28.4 | 105 | 15 | 28.3 | 104 | 13 | 27.7 | 102 | 15 | 26.9 | 99 | 15 | 28.1 | 104 | 15
35 | 27.0 | 13 | 28.0 | 104 | 15 | 27.9 | 103 | 13 | 28.0 | 104 | 15 | 26.9 | 100 | 15 | 27.8 | 103 | 15
36 | 27.0 | 13 | 28.1 | 104 | 15 | 28.1 | 104 | 13 | 28.0 | 104 | 15 | 26.4 | 98 | 15 | 28.0 | 104 | 15
37 | 26.8 | 13 | 27.6 | 103 | 15 | 27.7 | 103 | 13 | 27.8 | 104 | 15 | 26.8 | 100 | 15 | 27.7 | 103 | 15
38 | 26.9 | 13 | 27.7 | 103 | 15 | 28.0 | 104 | 13 | 27.8 | 103 | 15 | 26.6 | 99 | 15 | 27.7 | 103 | 15
39 | 26.7 | 13 | 27.6 | 103 | 15 | 28.3 | 106 | 13 | 28.2 | 106 | 15 | 27.1 | 102 | 15 | 27.8 | 104 | 15
40 | 27.4 | 13 | 27.9 | 102 | 15 | 28.8 | 105 | 13 | 28.6 | 104 | 15 | 26.9 | 98 | 15 | 28.3 | 103 | 14
Mean for weeks
1–13 | 21.6 | | 22.0 | 102 | | 21.8 | 101 | | 22.1 | 102 | | 21.4 | 99 | | 21.9 | 102
14–40 | 25.9 | | 27.1 | 105 | | 26.9 | 104 | | 27.0 | 104 | | 25.7 | 100 | | 26.7 | 103

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of nonneoplastic lesions of the liver and kidney. Summaries of the incidences of neoplasms and nonneoplastic lesions, individual animal tumor diagnoses, and statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group are presented in Appendix E for males and Appendix F for females.

Liver: Minimal to mild cytoplasmic vacuolization of periportal hepatocytes was found in control and exposed male mice (Tables 12 and E4). Compared to the control group, the incidences of periportal vacuolization were significantly greater in males exposed to 6,250, 25,000, or 50,000 ppm aspartame. Severity grades were increased in exposed mice. The prominence of the periportal hepatocellular vacuolization is accentuated by the concurrent loss of vacuolization in the centrilobular hepatocytes (probable glycogenolysis), rather than primarily being due to an accumulation of excessive vacuoles (presumed glycogen) in periportal cells. The biologic significance is uncertain, but this is likely a phenomenon with biological variability reflecting metabolic demands for glycogen and may be related to the amount of time without direct access to food prior to sacrifice rather than to treatment.

Kidney: The incidence of minimal nephropathy in male mice exposed to 50,000 ppm was increased; however, this increase was not significant (Tables 12 and E4). This change consisted of occasional cortical tubules with slight to moderate cytoplasmic basophilia and mild cytomegaly sometimes associated with interstitial inflammatory cell infiltrates, thickening of tubule basement membranes, and proteinaceous tubular casts. Minimal to mild nephropathy can be a common background lesion of uncertain etiology in mice and the biological significance of this marginal increase was not determined.

TABLE 12 Incidences of Selected Nonneoplastic Lesions in Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame

| 0 ppm | 3,250 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Male
Liver^a^ | 15 | 15 | 15 | 14 | 15 | 15
Hepatocyte, Periportal, Vacuolization Cytoplasmic^b^ | 6 (1.0)^c^ | 11 (1.5) | 14^**^ (1.2) | 8 (1.1) | 13^**^ (1.1) | 13^*^ (1.5)
Kidney | 15 | 15 | 15 | 14 | 15 | 15
Nephropathy | 2 (1.0) | 0 | 0 | 0 | 0 | 7 (1.0)
Female
Liver | 15 | 15 | 15 | 15 | 15 | 15
Hepatocyte, Periportal, Vacuolization Cytoplasmic | 0 | 0 | 0 | 0 | 0 | 2 (1.0)
Kidney | 15 | 15 | 13 | 15 | 15 | 15
Nephropathy | 1 (1.0) | 0 | 0 | 0 | 0 | 1 (1.0)

* Significantly different (P≤0.05) from the vehicle control group by the Poly-3 test

** P≤0.01

a Number of animals with tissue examined microscopically

b Number of animals with lesion

c Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

## Genetic Toxicology

Aspartame (100 to 10,000 µg/plate) was tested for induction of gene mutations in Salmonella typhimurium with and without induced rat or hamster liver S9 metabolic activation enzymes (Table G1). No mutagenicity was detected in strains TA98, TA100, or TA1535 with or without S9. In addition, a single test in TA1537 with 30% rat liver S9 gave negative results. In TA97 with 30% rat liver S9, however, a reproducible small increase in mutant colonies was observed, and this response was judged to be equivocal. No mutagenicity was detected in TA97 without S9 or with hamster liver S9.

No increase in micronucleated polychromatic erythrocytes (PCEs) was observed in bone marrow of male F344/N rats administered aspartame by gavage over a dose range of 500 to 2,000 mg/kg (Table G2). However, a slight decrease in percent PCEs occurred in the 1,000 mg/kg group, and in the positive controls the percent of PCEs was dramatically lowered, an indication of marked toxicity.

Peripheral blood micronucleus tests were conducted in Tg.AC hemizygous, p53 haploinsufficient, and Cdkn2a deficient mice after 9 months exposure to 3,125 to 50,000 ppm aspartame in feed. Negative results were obtained in male and female Tg.AC hemizygous and Cdkn2a deficient mice (Tables G3 and G4). Negative results were also obtained in male p53 haploinsufficient mice (Table G5); in female p53 haploinsufficient mice, the results of the micronucleus test were judged to be positive based on a significant trend test and the increased frequency of micronucleated erythrocytes seen in the 50,000 ppm group. For all three strains of mice, the percent PCEs was not significantly altered by treatment with aspartame.