# INTRODUCTION

ASPARTAME

CAS No. 22839-47-0

Chemical Formula: C_14_H_18_N_2_O_5_ Molecular Weight: 294.3

Synonyms: N-L-α-Aspartyl-L-phenylalanine 1-methyl ester; 3-amino-N-(α-carboxyphenethyl)succinamic acid N-methyl ester; APM; SC-18862

Trade names: Canderel, Equal, NutraSweet, Sanecta, Tri-Sweet

## Chemical and Physical Properties

Aspartame (the methyl ester of the dipeptide L-aspartyl-L-phenylalanine) is an odorless off-white crystalline powder with a melting point of approximately 246.5° C. A 0.8% solution in water has a pH of 5.3. The solubility of aspartame in water at 25° C is approximately 18.2 mg/mL. Aspartame is more soluble in acidic solutions and hot water and is only slightly soluble in alcohol and chloroform. The dipeptide ester is about 160 times sweeter than sucrose in aqueous solutions. In the presence of moisture, aspartame will hydrolyze to form aspartylphenylalanine and a diketopiperazine derivative, resulting in the loss of sweetness (HSDB, 2003). Photodecomposition of aspartame may occur in aqueous solutions (Kim et al., 1997), and aspartame may also decompose at high temperatures (Galletti et al., 1995).

## Production, Use, and Human Exposure

In 1974, the Food and Drug Administration (FDA) approved the use of aspartame as a sweetener in dry sugar substitutes in free-flowing and tablet form, cold cereals, chewing gum, and a dry base for beverages, instant coffees and teas, puddings and gelatins, and a dairy analogue topping (Fed. Regist., 1981a,b). The FDA Commissioner issued a final decision on the safety of aspartame for use in these food products in 1981 (Fed. Regist., 1981a,b). In 1983, the FDA also approved the use of aspartame as a sweetener in carbonated beverages and carbonated beverage syrup bases (Fed. Regist., 1984). In 1996, the FDA amended the food additive regulations to provide for the safe use of aspartame as a general purpose sweetener; the acceptable daily intake is up to 50 mg aspartame/kg body weight per day (Fed. Regist., 1996).

Aspartame is produced by the NutraSweet Company. In large-scale production of aspartame, L-aspartic acid anhydride is condensed with L-phenylalanine methyl ester to form a mixture of β-L-aspartyl-L-phenylalanine methyl ester and α-L-aspartyl-L-phenylalanine methyl ester. On acidification with hydrochloric acid, α-L-aspartyl-L-phenylalanine methyl ester precipitates, and the precipitate is neutralized to form aspartame (HSDB, 2003). It is estimated that 8,040 tons of aspartame are consumed in the United States each year (HSDB, 2003).

Aspartame is present in many food items such as beverages (180 mg/12 oz), yogurt (125 mg/8 oz), gelatin dessert (95 mg/4 oz), hot chocolate (50 mg/6 oz), table-top sweetener (35 mg/1 packet), pudding desert (25 mg/4 oz), and breath mints (1.5 mg/mint), and the upper end (90th percentile) of the daily average intake of aspartame may be 3 to 5 mg/kg body weight (Butchko and Stargel, 2001).

## Absorption, Distribution, and Excretion

Studies in a number of animal species indicate that aspartame is rapidly and extensively metabolized to its constituent amino acids and methanol (Figure 1). The hydrolysis occurs during the absorption process (Ranney et al., 1976; Ranney and Oppermann, 1979; Stegink and Filer, 1984; Stegink, 1987; Diomede et al., 1991) (Figure 2). Aspartame (N-L-α-aspartyl-L-phenylalanine 1-methyl ester) is the methyl ester of a dipeptide, aspartylphenylalanine. The ester bond is rapidly hydrolyzed in the gastrointestinal tract in mice, rats, rabbits, dogs, monkeys, and humans to give methanol, aspartic acid, and phenylalanine (Ranney et al., 1976). Methanol may be oxidized to formaldehyde and formic acid in the body (Trocho et al., 1998).

When aspartame is administered with carbohydrate, which promotes insulin secretion, plasma levels of other large neutral amino acids that compete with phenylalanine and tyrosine for brain uptake are lowered, and the brain levels of phenylalanine may increase (Dews, 1987). In the fetus and in young children, very high plasma levels of phenylalanine may interfere with the development of the nervous system. This condition is also seen in phenylketonuria because of a lower level of phenylalanine hydroxylase activity (Dews, 1987).

Complete absorption and toxicokinetic data are not available to compare the disposition of aspartame in humans and animals over the same dose range. However, the available data suggest that animals clear aspartame and/or metabolites more rapidly than humans (Reynolds et al., 1980).

Phenylalanine in plasma has been used as a marker for aspartame oral absorption in some studies. In humans, a normal plasma level of phenylalanine is 60 µM. Uncontrolled phenylketonurics have phenylalanine plasma levels of up to 1,200 µM. In humans, after a bolus dose of 34 mg aspartame/kg body weight, plasma phenylalanine levels rise to a peak of 110 µM (approximately 11 µmol/dL plasma) (Dews, 1987; Stegink, 1987). An aspartame dose of 100 mg/kg in normal subjects increased fasting levels of phenylalanine from 54 µM to 202 µM (Stegink et al., 1980).

The aspartame plasma level of phenylalanine in infant monkeys 1 hour after an oral dose of 2 g aspartame/kg body weight was approximately 82 µmol/dL plasma (Reynolds et al., 1980). Mean plasma levels of phenylalanine 1 hour after an oral dose of 0.5, 0.75, or 1 g/kg were 162, 241, or 442 nmol/mL plasma, respectively, in Sprague-Dawley rats and 192, 147, or 312 nmol/mL plasma in CD-1^®^ mice (Diomede et al., 1991).

## Toxicity

### Experimental Animals

Aspartame is reported to have low toxicity in experimental model systems. The oral LD_50_ of aspartame in rats and mice is reported to be more than 10 g/kg per day (RTECS, 2002).

In a 90-day oral gavage study in F344/N rats, doses up to 1,000 mg aspartame/kg body weight were not proconvulsant (Tilson et al., 1989). Aspartame at 1,000 mg/kg had no effect on learning and memory in F344/N rats (Tilson et al., 1991). Aspartame at doses up to 1,000 mg/kg given orally to male Sprague-Dawley and F344/N rats also did not alter levels of norepinephrine, dopamine, or serotonin in the brain at intervals up to 240 minutes after administration (Freeman et al., 1990). Other studies have also revealed that oral administration of aspartame at doses up to 704 mg/kg did not affect the behavior of Sprague-Dawley rats when evaluated by spontaneous activity or “wheel running” (Holder and Yirmiya, 1989).

The toxicity of aspartame was evaluated in male and female Wistar rats fed diets that delivered approximately 0, 1, 2, or 4 g aspartame/kg body weight daily from 6 weeks of age up to 104 weeks of age (Ishii et al., 1981). Each group contained 60 animals, with additional animals added for interim sacrifice at 26 or 52 weeks. Dose-dependent decreases in body weight gain and dose-related increases in urinary calcium occurred in the 2 and 4 g/kg groups. Clinical chemistry and hematologic endpoints were measured at the interim and terminal sacrifices, and no treatment-related changes were noted except for a decrease in total cholesterol in the 4 g/kg group at terminal sacrifice. The study indicated that portions of major organs and gross lesions were examined microscopically, although complete details of this evaluation were not given.

FIGURE 1 Chemical Structure of Aspartame with its Components Indicated by the Dotted Lines (Stegink, 1987)

FIGURE 2 Hydrolysis of Aspartame (Stegink, 1987)

### Humans

There have been no large-scale, controlled studies to evaluate whether aspartame causes toxic effects in humans; however, the FDA has a passive surveillance system for reporting side effects from aspartame use (CDC, 1984; Bradstock et al., 1986; Tollefson, 1988; Tollefson and Barnard, 1992). Generally, passive surveillance systems receive reports from consumers, and the types of side effects reported are anecdotal in nature and usually are conditions that occur immediately after consumption of a product (CDC, 1984).

The FDA has collected information on adverse health effects reported by individuals through its Adverse Reaction Monitoring system (ARMS). In 1988, the FDA presented an analyses of the aspartame adverse reports (Tollefson, 1988). As of 1988, the FDA received approximately 4,000 consumer complaints, and the most common adverse reactions were headaches (19%), dizziness/balance problems (8%), change in mood (7%), and vomiting and nausea (7%); a variety of other symptoms were also reported. Based on this information, it is not possible to determine the incidence or severity of the reported effect, and it is not possible to determine if the reaction is truly associated with the intake of aspartame (Tollefson, 1988). In 1992, the FDA reported that it received 251 reports of seizures after aspartame ingestion, but it concluded that the information did not support the claim that the seizures were related to aspartame consumption (Tollefson and Barnard, 1992).

The Centers for Disease Control (CDC) published an evaluation of reactions to aspartame and noted that neurological/behavioral symptoms were most frequently (67%) reported; however, the CDC concluded that it could not make a clear association between aspartame consumption and adverse effects (Bradstock et al., 1986). The NutraSweet Company also collected post-marketing information on aspartame and reported that no evidence of a relationship between aspartame and adverse health effects was found (Butchko and Stargel, 2001).

Several studies in the literature have evaluated a small number of people in an attempt to gain some additional information on side effects from aspartame intake. Sixteen adults and two children, who reported to the FDA that they had seizures associated with aspartame consumption, were subsequently evaluated in a clinical study (Rowan et al., 1995). In this evaluation, aspartame (50 mg/kg) or placebo was randomly administered to two groups in divided doses on days 2 and 4. No clinical seizures or other adverse effects were observed; however, plasma phenylalanine concentrations increased after aspartame ingestion (83.6 µM) compared to placebo (52.3 µM).

A double-blind controlled trial divided a group of 25 normal preschool children and a group of 23 children described as being sensitive to sugar into three groups that received one of three diets daily for 3 weeks: a diet that contained 5,600 mg sucrose/kg body weight and no artificial sweeteners; a diet low in sucrose and containing 38 mg aspartame/kg body weight; or a diet low in sucrose and containing 12 mg saccharin/kg body weight (Wolraich et al., 1994). None of the diets affected the children’s behavior or cognitive function.

Thirty-two subjects received approximately 30 mg aspartame/kg body weight per day or placebo for 7 days in a two-treatment, four period crossover design (Van en Eeden et al., 1994). Thirty-three percent of the subjects that received aspartame reported headaches versus 24% in the placebo group. The authors concluded that some people were susceptible to headaches after aspartame consumption. Another study with 48 volunteers who received aspartame (up to 48 mg/kg per day for 20 days) or placebo found no neuropsychologic, neurophysiologic, or behavior effects in the aspartame group (Spiers et al., 1998).

A variety of other studies have explored the effects of aspartame. One study reported that injection of 250 mg aspartame into healthy human subjects could lead to increased levels of urinary calcium but had no effect on plasma insulin or glucose levels (Nguyen et al., 1998).

After a review of the data, the FDA concluded that there were no consistent patterns of symptoms attributed to the use of aspartame in humans. The FDA pointed out that people with phenylketonuria do not have the ability to metabolize the amino acid, phenylalanine, and should not use aspartame (FDA, 1994).

## Reproductive and Developmental Toxicity

### Experimental Animals

A series of studies were conducted to evaluate the reproductive and developmental toxicity of aspartame in animals, and none found any evidence of these toxicities. Aspartame (500, 1,000, 2,000, or 4,000 mg/kg) was administered to CF-l mice on days 15 to 18 of gestation by oral gavage, and no adverse effects on maternal body weight, gestation length, reproductive indices, or litter size were noted (McAnulty et al., 1989). In the pups, body weights, negative geotaxis, and righting reflexes were not altered, and there were no changes in time of eye opening or reflex pupil closure.

Searle & Company (Searle) conducted two-generation reproductive, perinatal, and postnatal toxicity studies in rats given up to 4,000 mg/kg aspartame, and there were no delays in the onset of developmental milestones in the dams (Molinary, 1984). However, no data from the study were presented in the review article, and there was no information on levels of aspartame metabolites in the dams or pups.

When adult female Sprague-Dawley rats were administered aspartame in the drinking water at concentrations up to 0.9% from 12 days prior to conception until pups were 38 days old, no effects on perinatal development were detected in the pups (Holder, 1989). This included two measures of morphologic development (latencies to pinnae detachment and eye opening) and two tests of development (latencies for surface righting at 7 days of age and negative geotaxis at 8 days of age). The estimated dose was up to 1,614 mg/kg per day in the dams and up to 3,566 mg/kg per day in the pups.

A 6% aspartame concentration given to pregnant rabbits in the diet from day 6 to day 16 or 20 had no effect on fetal weight or litter size (Ranney et al., 1975). When pregnant guinea pigs were administered 500 mg/kg aspartame daily by oral gavage from day of conception to parturition, there were no effects on maternal weight gain, litter size, or pup birth weight (Dow-Edwards et al., 1989); however, there was some effect on odor-associative learning in 15-day-old pups.

Up to 3,000 mg/kg aspartame given to infant macaque monkeys in the diet had no effect on growth rate, development milestones, or learning or sensory discrimination (Reynolds et al., 1984). There were also no effects on long-term behavior in these primates (Suomi, 1984).

### Humans

No reproductive or developmental toxicity studies of aspartame in humans were found in the literature.

## Carcinogenicity

### Experimental Animals

The FDA approved the use of aspartame in 1981 after reviewing studies submitted by Searle (Fed. Regist., 1981a,b); the FDA commissioner’s decision on the use of aspartame contains information on Searle’s studies to determine any carcinogenic potential of aspartame, however, the experimental details of the studies were not published.

The FDA summary notes that prior to the approval, it established a Public Board of Inquiry to answer questions on aspartame including whether the ingestion of aspartame contributed to mental retardation, brain damage, or undesirable effects on neuroendocrine regulatory systems and whether the ingestion of aspartame might induce brain neoplasms in rats. The Board of Inquiry found that aspartame consumption would not pose an increased risk of adverse neurological effects. However, the Board did find that the available data were not conclusive to rule out an effect on the incidence of brain tumors in laboratory rats (Fed. Regist., 1981a,b). In its final ruling, the FDA concluded that aspartame was safe for its proposed uses.

The FDA summarized a Searle 104-week study in Sprague-Dawley rats (Fed. Regist., 1981a,b). In this study, 1, 2, 4, or 6 to 8 g/kg aspartame were given to groups of 40 male and 40 female rats in the diet; dosing began after weaning. Groups of 60 male and 60 female rats served as controls. Further details on this study were also reported in an aspartame monograph (Molinary, 1984); there were reductions in mean body weight and mean feed consumption in the 6 to 8 mg/kg groups, 2-year survival was poor (attributed to spontaneous disease), and no treatment-related hematologic or clinical chemistry findings were reported. The Board of Inquiry was concerned that there was an occurrence of gliomas at a relatively early age in some of the exposed groups. A total of seven brain tumors occurred in exposed males (1 g/kg, 2/40; 2 g/kg, 1/40; 4 g/kg, 4/40; 6 to 8 g/kg, 0/40), and a total of five occurred in exposed females (2/40, 0/40, 1/40, 2/40; Cornell et al., 1984). In an initial review, no brain tumors were observed in controls, but in subsequent review one occurred in a control male. There were brain tumor diagnosis inconsistencies among the various groups that reviewed these lesions (Koestner, 1984).

The FDA also reported on a two-generation study in Sprague-Dawley rats given 0, 2, or 4 g aspartame/kg body weight in the diet in utero, during lactation, and then for 104 weeks. Brain tumors occurred in three control males and one control female, in two males and one female in the 2 g/kg groups, and in one male and one female in the 4 g/kg groups. There were increased incidences of hyperplastic nodules of the liver in treated females; however, there were no treatment-related differences in neoplasm rates between control and treated groups (Fed. Regist., 1981a,b; Molinary, 1984).

A principal product of aspartame decomposition is diketopiperizine. The FDA summarized a 115-week study of diketopiperizine in Sprague-Dawley rats exposed to 0, 0.75, 1.5, or 3.0 g aspartame/kg body weight; exposure began after weaning. There was no treatment-related carcinogenicity in that study, and there was none in a similar study in mice (Fed. Regist., 1981a,b; Molinary, 1984).

The FDA also reported that a chronic aspartame mouse study did not show any treatment-related carcinogenic effects (Fed. Regist., 1981a,b). Further details on this study were reported by Molinary (1984). Groups of 36 male and 36 female mice were fed 1, 2, or 4 g/kg aspartame for up to 110 weeks. Mean body weights of treated animals were similar to those of the controls, although feed consumption decreased with increasing aspartame concentration. There were no treatment-related effects on survival or behavior, there were no statistically significant differences in hematologic or clinical chemistry endpoints, and there were no treatment-related gross or microscopic findings.

An aspartame carcinogenesis study was also conducted in Japan (Ishii, 1981; Ishii et al., 1981). In this study, 1, 2, or 4 g/kg aspartame or a 3:1 ratio of 4 g/kg aspartame:diketopiperazine metabolite (5-benzyl-3,6-dioxo-2-piperazine acetic acid) in the diet were administered to male and female Wistar rats. One atypical astrocytoma was found in a control rat, and two astrocytomas, two oligodendrogliomas and one ependymoma were found in the exposed groups. The authors concluded that there were no significant differences in the incidences of brain tumors between the control and treated groups. Complete experimental details of this study were not published.

In a 106-week study, dogs were fed 0, 1, 2, or 4 g/kg aspartame daily in the diet. Aspartame caused no treatment-related carcinogenic effects, although no experimental data were presented in the review article (Molinary, 1984).

### Humans

There have been no large-scale epidemiology studies to evaluate the relationship between aspartame intake and cancer development in humans.

One study reported that the incidence of brain tumors in the United States increased between 1970 and 1980, and suggested that while the cause of the increase remains unknown, environmental factors, including aspartame use might have contributed to this increase (Olney et al., 1996). Others have concluded that diagnostic advances or other factors could better account for these findings (Levy and Hedeker, 1996; Gurney et al., 1997; Smith et al., 1998).

## Genetic Toxicity

There are few published mutagenicity data for aspartame. Aspartame was reported to be negative in a Salmonella mutagenicity test using strains TA100 and TA98, but following nitrosation (40 mM nitrite under acidic pH at 37° C), mutagenic activity was demonstrated by the resulting product (aspartame concentration of 8 mM in the reaction product) in TA100, TA104, and TA98 in the absence of S9 metabolic activation enzymes (Shephard et al., 1993); addition of 10% S9 reduced the magnitude of the mutagenic response in TA100, but did not eliminate it. No mutagenicity was detected in TA98 with aspartame in the presence of S9. The nitrosated product was also tested in TA102 without S9, but no mutagenic activity was detected. The authors concluded from kinetic studies that nitrosation of the primary amine produced the mutagenic product, and they suggested that under naturally occurring conditions in the stomach, side chain nitrosation would be the primary pathway of activity. Thus, the mutagenic products produced through this experimental nitrosation procedure would not likely be produced through normal digestive reactions in vivo. Results of an assay to measure induction of unscheduled DNA synthesis in rat hepatocytes treated with aspartame in vitro were negative, indicating the absence of induced DNA damage by aspartame (Jeffrey and Williams, 2000). In vivo, a mixture of aspartame (up to 350 mg/kg) and a second sweetener, acesulfame potassium (up to 150 mg/kg), was reported to be negative in a test for induction of chromosomal aberrations in bone marrow cells of male Swiss mice when administered by gavage (Mukhopadhyay et al., 2000). A dose-related increase in the percentage of cells with chromosomal aberrations was noted with increasing doses of the two sweeteners, but the increase was not statistically significant.

## Background on Genetically Altered Mice

Mutation and/or deletions of tumor suppressor genes or activation of protooncogenes can disrupt cell function and predispose an animal to cancer. In the current studies, three genetically altered mouse models with either a loss of heterozygosity in a critical cancer gene (Trp53 or Cdkn2a) or a gain of oncogene function (Ha-ras) were used to determine how these animals would response to aspartame exposure. Two of these mouse models have been shown to be susceptible to the rapid development of cancer. The Tg.AC hemizygous and p53 haploinsufficient mice are being evaluated by the National Institute of Environmental Health Sciences (NIEHS) as models for identifying chemical toxicity and/or chemical carcinogenic processes (Tennant et al., 1996).

### FVB/N-TgN(v-Ha-ras)Led (Tg.AC) Hemizygous Mouse Model

The Tg.AC mouse (on an FVB/N background) was developed by Leder et al. (1990) by introduction via pronuclear injection of a tripartite transgene composed of the promotor of the mouse embryonic zeta-globin gene, through the v-Ha-ras coding sequence, with point mutation in codons 12 and 59, and an SV40 polyadenylation sequence.

The Tg.AC transgenic mouse model has been evaluated as a reporter phenotype (skin papillomas) in response to either genotoxic or nongenotoxic carcinogens, including tumor promoters (Spalding et al., 1993, 1999; Tennant et al., 1999). Tg.AC mice are hemizygous for a mutant v-Ha-ras transgene. The model was developed by Leder et al. (1990) with an inducible zeta-globin promoter driving the expression of a mutated v-Ha-ras oncogene and is regarded as a genetically initiated model. With the exception of bone marrow, constitutive expression of the transgene cannot be detected in adult tissues. The trans-gene is usually transcriptionally silent until activated by certain treatments including full-thickness wounding, ultraviolet irradiation, or exposure to some chemicals (Cannon et al., 1997; Trempus et al., 1998). The Tg.AC hemizygous mouse develops a high incidence of skin papillomas in response to topical application of 12-O-tetradecanoyl-phorbol-13-acetate (TPA), and TPA has been used as a positive control in NIEHS Tg.AC mouse studies (Spalding et al., 1993). Point mutations in the Ha-ras gene are believed to be early events in the induction of skin papillomas and malignancies. Topical application of carcinogens to the shaved dorsal surface of Tg.AC mice induces epidermal squamous cell papillomas or carcinomas, a reporter phenotype that defines the activity of the chemical. The oral route of administration can also generate tumor responses in the skin of Tg.AC mice and lead to squamous cell papillomas and/or carcinomas of the forestomach. To date, the appearance of either spontaneous or induced tumors has been shown to require activation of transgene expression. However, the mechanism of response by the Tg.AC model to chemical carcinogens is not yet understood.

In NIEHS studies, mice are exposed beginning at 2 months of age for a total of 6 to 9 months. Incidences of cutaneous papillomas at various sites have been reported at 3.7% and 3.8% in 26-week-old control male and female Tg.AC mice, respectively (Mahler et al., 1998). Cutaneous papillomas occurring at sites such as the lip, pinnae, prepuce, and vulva suggest a possible relationship to grooming and chronic irritation. Up to 32% of Tg.AC homozygous and heterozygous male or female mice can develop odontogenic tumors as early as 26 weeks (Wright et al., 1995; Mahler et al., 1998). A number of different tumor types occur in untreated Tg.AC hemizygous mice at incidences greater than 3% including odontogenic tumors, forestomach papillomas, cutaneous papillomas, alveolar/bronchiolar adenomas, salivary gland duct carcinomas, and erythroleukemia (Mahler et al., 1998). In the FVB mouse (the background strain for the Tg.AC hemizygous mouse), alveolar/bronchiolar neoplasms occur at 14 months of age (Mahler et al., 1996).

The Tg.AC hemizygous mouse model was used in the current Report for the studies of aspartame and in a companion Report for the studies of acesulfame potassium (NTP, 2005) because this model has been reported to detect both nongenotoxic and genotoxic carcinogens (Spalding et al., 1993; Tennant et al., 1995, 1996; Pritchard, 2003).

### B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient Mouse Model

The heterozygous B6.129-Trp53 (N12)^tmlBrd(+/–)^ mouse (on a B6.129S7 background) was developed by Donehower et al. (1992). A null mutation was introduced into one p53 allele by homologous recombination in murine embryonic stem cells. Insertion of a neo cassette resulted in deletion of a 450-base pair gene fragment containing 106 nucleotides of exon 5 and approximately 350 nucleotides of intron 4.

Trp53, a nuclear protein, plays an essential role in the regulation of the cell cycle, specifically in the transition from G_0_ to G_1_, as well as G_2_ to M, and the spindle apparatus. The p53 protein has a short half-life and exists at a very low concentration under normal cell physiological conditions. However, in DNA damaged cells that are able to replicate, p53 is expressed in high amounts with a significant increase in half-life due to post-translational modification (phosphorylation or acetylation). Mutations in p53 may also increase the protein half-life and alter functions that may contribute to transformation and development of the malignant phenotype. p53 is a DNA-binding protein containing DNA-binding, oligomerization, and transcription activation domains. Many amino acid residues in different p53 domains may be phosphorylated or acetylated, which may determine specific p53 functions. It is postulated to bind as a tetramer to a p53-binding site and activate expression of downstream genes that inhibit growth and/or invasion or promote apoptosis, functioning as a tumor suppressor. This protein is critical to tumor suppression in humans and rodents. Mutants of p53 that fail to bind the consensus DNA binding site, and hence are unable to function as tumor suppressors, frequently occur in human cancers. Alterations of the Tp53 gene occur not only as somatic mutations in human malignancies, but also as germline mutations in some cancer-prone families with Li-Fraumeni syndrome.

The mouse heterozygous for a p53 null allele (+/–) has only a single functional wild-type p53 allele which provides a target for mutagens. The p53 tumor suppressor gene is one of the most common sites for mutations and gene alterations in human cancer (Harris, 1996a,b,c).

Heterozygous p53^(+/–)^ transgenic mice develop normally, and like humans and other mammals, develop cancer (primarily lymphomas or sarcomas) with age, but often with decreased latency and increased susceptibility.

### B6.129-Cdkn2a^tm1Rdp^ (N2) Deficient Mouse Model

A transgenic model with a targeted deletion in the Cdkn2a locus (Cdkn2a deletion), and thus disruption in p16^Ink4a^ and p19^Arf^ function, was developed by Serrano et al. (1996). The genetic background of this mouse is derived from parental strains C57BL/6 and 129WW6 (75%), 129/Sv (20%), and 129SJL (5%).

The Cdkn2a gene generates several different transcript variants using different first exons and alternate polyadenylation sites. The p16^Ink4a^ variants encode structurally related protein isoforms that function to inhibit CDK4 kinase. The p19^Arf^ transcript includes an alternate first exon located upstream of the remainder of the gene. This alternate open reading frame (ARF) specifies a protein which is structurally unrelated to the other variants. The p19^Arf^ product functions to stabilize the tumor suppressor protein, p53. The p19^Arf^ binds Mdm2, a protein that targets degradation of p53 through ubiquination. Both the p16^Ink4a^ CDK4 inhibitors and the p19^Arf^ protein encoded by the Cdkn2a gene play a critical role in G_1_/S progression of the cell cycle.

Transition from G_1_ to S phase in the mammalian cell cycle is under complex regulatory control, and one G_1_/S regulatory pathway involves p16 protein (encoded by the Cdkn2a gene). p16 inhibits the CDK4/cyclin D1 complex, preventing CDK4 from phosphorylating pRb, ensuring that pRb maintains G_1_ arrest. Disruption of this pathway by p16 gene mutations perturbs the cell cycle (Reed et al., 1996), and in the case of the Cdkn2a knockout mice, allows more cell proliferation to occur.

This gene is frequently mutated or deleted in a wide variety of tumors and is known to be an important tumor suppressor gene. Genetic alterations in the Cdkn2a gene play an important role in human cancers, particularly with brain tumor carcinogens (Liggett and Sidransky, 1998). The Cdkn2a gene encodes two distinct proteins, the p16^Ink4a^ protein, which is a component of the retinoblastoma (Rb) gene pathway, and the p19^Arf^ protein (or in humans, the p14^Arf^ protein), which interacts with Mdm2 and neutralizes Mdm2 inhibition of p53 (Pomerantz et al., 1998).

Homozygous null Cdkn2a^(–/–)^ (i.e., p16^Ink4a(–/–)^ and p19^Arf(–/–)^) are viable and fertile. On inspection, these mice appear normal until approximately 2 months of age, but histologic analysis of the spleen shows a mild proliferative expansion of the white pulp and the presence of numerous megakaryocytes and lymphoblasts in the red pulp. The mice homozygous for Cdkn2a null alleles (–/–) develop tumors at an average age of 29 weeks, and most mice die by 36 weeks. Lymphomas and fibrosarcomas are two common types of tumors seen in these mice. In contrast, the Cdkn2a^(+/–)^ mouse does not usually develop obvious tumors or display compromised health until after 36 weeks of age (Serrano et al., 1993)

At this time, the NIEHS and the NTP do not have enough information on the characteristics of Cdkn2a deficient mice to predict how this model might respond to different types of carcinogens.

## Study Rationale

Aspartame has been evaluated in conventional rodent cancer studies (non-NTP studies) and is considered negative for carcinogenicity. It has been argued that those studies showed a slight increase in brain tumors. Because of these uncertainties, aspartame was selected by the NIEHS for evaluation of its toxicologic and carcinogenic potential.

The conventional rodent bioassay has been used for over three decades and is credible in identifying carcinogens thought to pose risks to humans (Tomatis et al., 1997), although only two chemicals in rats and one in mice of over 500 chemicals studied by the NTP have shown unequivocal increases in brain tumors. An ongoing goal of the NIEHS and the NTP is to seek other model systems for toxicology and carcinogenesis studies, especially those that can provide mechanistic information that will assist in understanding an agent’s mode of action. The use of genetically altered models holds promise for improving the accuracy and efficacy of experimental assessment of the carcinogenic potential of chemicals. Genetically altered mouse models carry activated oncogenes or inactivated tumor suppressor genes known to be involved in neoplastic processes in humans and rodents. This trait may allow them to respond to carcinogens more quickly than conventional rodent strains. In addition, the neoplastic effects of agents can be observed in genetically altered models within a time frame in which few, if any, spontaneous tumors would arise. The high incidences of spontaneous or background tumors, which occur most often late in the 2-year rodent studies, can hinder interpretation of the findings and their implications for human health. The use of target or reporter genes allows for direct molecular and cellular analysis of a chemical’s effects in genetically modified mouse models and can provide additional mechanistic information about the mode of action.

For the past few years, the NIEHS and the NTP have been actively evaluating genetically altered strains in toxicologic testing strategies. Based on completed evaluations, three models, the Tg.AC hemizygous (v-Ha-ras) and p53-deficient (p53 haploinsufficient), and the ras H2 (cHa-ras-transgene) mice have shown potential usefulness in identifying carcinogens (Pritchard et al., 2003). Aspartame was one of the test agents selected for the continued evaluation of the genetically modified Tg.AC hemizygous and p53 haploinsufficient strains and for initial evaluations of the Cdkn2a deficient mouse model. The vast majority of studies utilizing genetically modified mice for cancer hazard identification have employed a dosing duration of 6 months, after which mice are examined for tumor development. Although this may be adequate to identify relatively potent carcinogens, there is uncertainty over the adequacy of this dosing duration to produce a tumor response with weaker carcinogens. To partially address this question, the current studies were carried out for 9 months rather than 6 months.