# APPENDIX J FEED AND COMPOUND CONSUMPTION IN THE 9-MONTH FEED STUDIES OF ASPARTAME

TABLE J1 Feed and Compound Consumption by Male Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame

Week | 0 ppm | | 3,125 ppm | | | 6,250 ppm | | | 12,500 ppm | | | 25,000 ppm | | | 50,000 ppm
Week | Feed (g)^a^ | Body Weight (g) | Feed (g) | Body Weight (g) | Dose (mg/kg)^b^ | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg)
2 | 4.5 | 21.5 | 4.2 | 21.3 | 615 | 4.2 | 20.1 | 1,304 | 4.3 | 20.3 | 2,631 | 4.3 | 21.7 | 5,005 | 4.1 | 20.8 | 9,871
3 | 4.1 | 21.9 | 4.0 | 22.0 | 572 | 4.4 | 21.8 | 1,267 | 4.3 | 21.2 | 2,510 | 4.4 | 22.1 | 4,998 | 4.2 | 22.0 | 9,590
4 | 4.5 | 22.6 | 4.5 | 23.2 | 601 | 4.4 | 22.7 | 1,204 | 4.3 | 22.3 | 2,432 | 4.5 | 23.3 | 4,808 | 4.3 | 22.7 | 9,448
5 | 4.5 | 23.8 | 4.3 | 23.7 | 570 | 4.5 | 23.6 | 1,190 | 4.3 | 23.1 | 2,312 | 4.4 | 23.9 | 4,642 | 4.3 | 23.6 | 9,028
6 | 4.2 | 24.6 | 4.1 | 23.2 | 552 | 4.4 | 24.6 | 1,129 | 4.2 | 23.5 | 2,244 | 4.5 | 25.0 | 4,540 | 4.1 | 23.8 | 8,695
7 | 4.5 | 25.2 | 4.2 | 24.8 | 531 | 4.4 | 25.7 | 1,081 | 4.0 | 23.9 | 2,075 | 4.4 | 25.4 | 4,375 | 4.2 | 24.9 | 8,394
8 | 4.5 | 26.0 | 4.2 | 25.0 | 523 | 4.3 | 25.8 | 1,031 | 4.2 | 24.8 | 2,125 | 4.5 | 25.9 | 4,332 | 4.1 | 24.6 | 8,247
9 | 4.4 | 26.3 | 4.3 | 25.9 | 516 | 4.4 | 26.8 | 1,019 | 4.4 | 25.6 | 2,125 | 4.3 | 26.1 | 4,168 | 4.3 | 25.5 | 8,340
10 | 4.3 | 27.4 | 4.3 | 26.4 | 513 | 4.3 | 26.7 | 1,007 | 4.3 | 26.1 | 2,059 | 4.3 | 26.4 | 4,027 | 4.3 | 26.2 | 8,210
11 | 4.3 | 28.2 | 4.4 | 26.7 | 513 | 4.5 | 27.5 | 1,032 | 4.6 | 26.8 | 2,125 | 4.5 | 27.5 | 4,056 | 4.4 | 26.8 | 8,178
12 | 4.4 | 28.5 | 4.1 | 26.2 | 487 | 4.5 | 28.0 | 1,015 | 4.3 | 26.6 | 2,001 | 4.2 | 26.7 | 3,968 | 4.3 | 27.0 | 8,059
13 | 4.3 | 28.8 | 4.4 | 27.4 | 496 | 4.5 | 28.3 | 1,006 | 4.2 | 27.0 | 1,923 | 4.7 | 27.9 | 4,170 | 4.4 | 27.4 | 7,993
14 | 4.2 | 29.0 | 4.2 | 27.1 | 479 | 4.2 | 27.8 | 949 | 4.2 | 27.2 | 1,933 | 4.5 | 28.1 | 3,985 | 4.4 | 27.6 | 7,958
15 | 4.2 | 29.5 | 4.5 | 28.5 | 490 | 4.5 | 29.2 | 966 | 4.2 | 28.0 | 1,872 | 4.4 | 28.5 | 3,876 | 4.2 | 28.1 | 7,465
16 | 4.2 | 29.5 | 4.1 | 27.8 | 460 | 4.3 | 28.8 | 928 | 4.3 | 27.9 | 1,923 | 4.4 | 28.4 | 3,841 | 4.1 | 27.8 | 7,396
17 | 4.2 | 29.2 | 4.3 | 27.9 | 486 | 4.3 | 29.1 | 930 | 4.2 | 28.3 | 1,876 | 4.5 | 29.0 | 3,879 | 4.2 | 28.6 | 7,348
18 | 4.1 | 29.5 | 4.4 | 28.6 | 478 | 4.3 | 29.2 | 928 | 4.3 | 28.3 | 1,881 | 4.4 | 28.8 | 3,779 | 4.2 | 28.6 | 7,423
19 | 4.1 | 29.1 | 4.4 | 29.4 | 471 | 4.4 | 29.7 | 926 | 4.2 | 28.2 | 1,845 | 4.5 | 29.3 | 3,840 | 4.3 | 28.4 | 7,611
20 | 4.4 | 29.7 | 4.1 | 29.0 | 446 | 4.1 | 29.9 | 864 | 4.2 | 28.6 | 1,851 | 4.2 | 29.9 | 3,479 | 4.1 | 28.9 | 7,128
21 | 4.3 | 30.2 | 4.4 | 29.6 | 469 | 4.5 | 30.3 | 921 | 4.3 | 29.0 | 1,874 | 4.2 | 29.6 | 3,584 | 4.2 | 29.4 | 7,092
22 | 4.2 | 30.4 | 4.2 | 29.1 | 447 | 4.0 | 29.7 | 847 | 4.3 | 29.0 | 1,873 | 4.4 | 29.4 | 3,724 | 3.9 | 28.5 | 6,829
23 | 4.3 | 30.8 | 4.2 | 29.1 | 450 | 4.5 | 29.9 | 948 | 4.4 | 29.2 | 1,892 | 4.5 | 29.7 | 3,766 | 4.2 | 28.4 | 7,373
24 | 4.2 | 30.7 | 4.2 | 28.8 | 451 | 4.2 | 30.1 | 877 | 4.3 | 29.9 | 1,780 | 4.4 | 30.0 | 3,635 | 4.4 | 27.9 | 7,866
25 | 4.4 | 31.1 | 4.3 | 29.1 | 461 | 4.3 | 30.5 | 890 | 4.5 | 30.0 | 1,856 | 4.5 | 29.6 | 3,820 | 4.0 | 28.0 | 7,176
26 | 4.0 | 30.8 | 4.3 | 29.4 | 460 | 4.4 | 30.7 | 902 | 4.2 | 30.0 | 1,758 | 4.5 | 30.3 | 3,724 | 4.0 | 27.2 | 7,385
27 | 4.3 | 31.3 | 4.4 | 29.4 | 466 | 4.2 | 30.7 | 861 | 4.1 | 29.7 | 1,738 | 4.5 | 30.5 | 3,668 | 4.1 | 29.0 | 7,075
28 | 4.1 | 31.5 | 4.3 | 29.3 | 458 | 4.2 | 30.5 | 869 | 4.2 | 29.7 | 1,785 | 4.6 | 30.7 | 3,713 | 4.2 | 29.7 | 7,085
29 | 4.2 | 31.4 | 4.2 | 28.8 | 460 | 4.0 | 30.0 | 840 | 4.1 | 30.1 | 1,719 | 4.5 | 30.9 | 3,622 | 4.1 | 30.0 | 6,796
30 | 4.4 | 31.8 | 4.6 | 30.2 | 472 | 4.5 | 30.0 | 931 | 4.4 | 30.7 | 1,779 | 4.6 | 31.1 | 3,669 | 4.3 | 30.9 | 6,998
31 | 4.5 | 31.5 | 4.6 | 30.4 | 471 | 4.7 | 30.6 | 968 | 4.6 | 30.5 | 1,869 | 4.8 | 31.0 | 3,854 | 4.6 | 30.9 | 7,479
32 | 4.3 | 31.1 | 4.6 | 30.6 | 470 | 4.8 | 30.9 | 961 | 4.4 | 30.1 | 1,830 | 4.7 | 31.3 | 3,756 | 4.3 | 31.0 | 6,938
33 | 4.4 | 31.1 | 4.8 | 30.6 | 494 | 4.7 | 30.8 | 960 | 4.6 | 30.0 | 1,918 | 4.5 | 31.1 | 3,591 | 4.5 | 31.2 | 7,174
34 | 4.5 | 31.3 | 4.7 | 30.5 | 482 | 4.6 | 31.2 | 925 | 4.8 | 30.3 | 1,965 | 4.8 | 30.8 | 3,862 | 4.3 | 30.5 | 7,085
35 | 4.5 | 31.6 | 4.6 | 30.6 | 470 | 4.6 | 30.7 | 928 | 4.7 | 30.8 | 1,914 | 4.4 | 30.3 | 3,603 | 4.3 | 31.1 | 6,951
36 | 4.6 | 32.0 | 4.6 | 30.6 | 467 | 4.8 | 31.7 | 952 | 4.8 | 31.3 | 1,896 | 4.4 | 29.8 | 3,704 | 4.5 | 31.6 | 7,044
37 | 4.4 | 32.0 | 4.5 | 30.1 | 464 | 4.7 | 31.9 | 918 | 4.5 | 30.9 | 1,832 | 4.2 | 29.7 | 3,536 | 4.2 | 31.2 | 6,662
38 | 4.3 | 31.7 | 4.7 | 30.9 | 475 | 4.4 | 31.6 | 878 | 4.3 | 31.2 | 1,739 | 4.7 | 30.3 | 3,881 | 4.2 | 31.3 | 6,790
39 | 4.2 | 31.8 | 4.6 | 31.1 | 461 | 4.6 | 31.8 | 898 | 4.5 | 31.3 | 1,796 | 4.8 | 31.7 | 3,817 | 4.1 | 31.2 | 6,564
40 | 4.4 | 32.8 | 4.3 | 31.3 | 428 | 4.7 | 32.1 | 907 | 4.5 | 31.2 | 1,802 | 4.6 | 31.2 | 3,667 | 4.5 | 31.7 | 7,023
Mean for weeks
2–13 | 4.4 | 25.4 | 4.2 | 24.7 | 541 | 4.4 | 25.1 | 1,107 | 4.3 | 24.3 | 2,214 | 4.4 | 25.2 | 4,424 | 4.2 | 24.6 | 8,671
14–40 | 4.3 | 30.8 | 4.4 | 29.5 | 466 | 4.4 | 30.3 | 914 | 4.4 | 29.7 | 1,844 | 4.5 | 30.0 | 3,736 | 4.2 | 29.6 | 7,175

a Grams of feed consumed per animal per day

b Milligrams of aspartame consumed per kilogram body weight per day

TABLE J2 Feed and Compound Consumption by Female Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame

Week | 0 ppm | | 3,125 ppm | | | 6,250 ppm | | | 12,500 ppm | | | 25,000 ppm | | | 50,000 ppm
Week | Feed (g)^a^ | Body Weight (g) | Feed (g) | Body Weight (g) | Dose (mg/kg)^b^ | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg)
2 | 4.2 | 18.1 | 4.2 | 18.0 | 724 | 4.1 | 17.7 | 1,432 | 4.1 | 17.4 | 2,918 | 4.2 | 18.1 | 5,774 | 3.9 | 17.8 | 10,879
3 | 4.0 | 18.5 | 4.1 | 18.9 | 682 | 3.8 | 18.3 | 1,285 | 3.8 | 17.8 | 2,649 | 3.8 | 17.6 | 5,388 | 3.8 | 17.9 | 10,617
4 | 4.5 | 19.5 | 4.2 | 19.7 | 669 | 4.1 | 19.5 | 1,306 | 4.0 | 18.8 | 2,643 | 4.1 | 19.6 | 5,255 | 4.0 | 19.6 | 10,200
5 | 4.1 | 19.5 | 4.0 | 20.1 | 618 | 3.8 | 19.7 | 1,206 | 3.9 | 19.7 | 2,488 | 3.9 | 20.1 | 4,804 | 3.8 | 20.3 | 9,293
6 | 4.2 | 19.7 | 4.1 | 20.3 | 634 | 4.1 | 20.4 | 1,269 | 4.1 | 19.3 | 2,658 | 3.6 | 20.2 | 4,408 | 3.8 | 20.2 | 9,351
7 | 4.1 | 20.1 | 4.0 | 21.4 | 581 | 3.9 | 21.3 | 1,155 | 4.1 | 20.7 | 2,458 | 4.1 | 20.8 | 4,911 | 3.8 | 21.3 | 9,017
8 | 4.1 | 20.5 | 3.8 | 20.9 | 566 | 3.7 | 20.6 | 1,118 | 4.0 | 20.6 | 2,404 | 4.1 | 21.1 | 4,848 | 3.6 | 20.7 | 8,771
9 | 4.2 | 21.1 | 4.0 | 21.9 | 570 | 3.9 | 21.5 | 1,134 | 4.1 | 21.3 | 2,397 | 4.0 | 21.6 | 4,578 | 4.0 | 21.8 | 9,301
10 | 4.0 | 21.6 | 4.1 | 22.2 | 574 | 4.0 | 21.5 | 1,156 | 4.1 | 21.9 | 2,327 | 3.9 | 21.9 | 4,461 | 3.9 | 22.4 | 8,760
11 | 3.8 | 21.7 | 4.0 | 22.4 | 559 | 4.2 | 22.5 | 1,165 | 4.0 | 21.9 | 2,308 | 3.8 | 22.5 | 4,271 | 3.8 | 22.7 | 8,466
12 | 4.1 | 22.4 | 4.1 | 22.6 | 561 | 4.1 | 21.9 | 1,166 | 4.1 | 21.9 | 2,326 | 3.8 | 21.7 | 4,424 | 3.9 | 23.2 | 8,460
13 | 4.1 | 22.5 | 4.1 | 22.6 | 568 | 3.9 | 22.0 | 1,117 | 4.2 | 22.3 | 2,372 | 4.4 | 23.2 | 4,737 | 4.0 | 23.1 | 8,756
14 | 4.0 | 22.4 | 4.1 | 22.9 | 564 | 4.3 | 23.0 | 1,158 | 4.1 | 22.5 | 2,257 | 4.4 | 22.9 | 4,768 | 4.1 | 23.1 | 8,832
15 | 3.7 | 22.3 | 3.6 | 22.5 | 494 | 3.9 | 23.3 | 1,057 | 4.1 | 22.4 | 2,283 | 4.2 | 23.6 | 4,495 | 3.8 | 23.5 | 8,133
16 | 3.8 | 22.6 | 4.2 | 23.3 | 567 | 4.0 | 23.4 | 1,056 | 4.0 | 22.5 | 2,224 | 3.9 | 23.4 | 4,183 | 4.2 | 24.5 | 8,461
17 | 4.0 | 22.6 | 3.9 | 23.1 | 528 | 3.8 | 23.2 | 1,027 | 4.1 | 22.5 | 2,263 | 4.1 | 23.8 | 4,262 | 3.9 | 24.4 | 7,892
18 | 4.0 | 22.6 | 4.1 | 23.3 | 544 | 4.2 | 23.4 | 1,112 | 4.1 | 22.9 | 2,228 | 4.1 | 23.7 | 4,273 | 3.9 | 24.5 | 8,036
19 | 3.8 | 23.0 | 4.0 | 23.3 | 537 | 4.2 | 23.8 | 1,110 | 4.1 | 23.4 | 2,188 | 4.1 | 23.6 | 4,320 | 4.2 | 24.9 | 8,436
20 | 4.0 | 23.1 | 3.9 | 23.1 | 523 | 3.9 | 23.7 | 1,024 | 3.8 | 23.0 | 2,090 | 4.1 | 23.7 | 4,302 | 4.0 | 25.9 | 7,669
21 | 4.1 | 23.9 | 4.1 | 24.2 | 535 | 4.3 | 24.7 | 1,084 | 3.9 | 23.3 | 2,065 | 4.0 | 24.1 | 4,152 | 3.9 | 26.0 | 7,512
22 | 4.1 | 23.7 | 4.1 | 24.3 | 527 | 4.3 | 24.6 | 1,088 | 3.9 | 22.9 | 2,147 | 4.2 | 24.2 | 4,328 | 3.8 | 25.7 | 7,319
23 | 4.6 | 24.4 | 4.0 | 24.6 | 513 | 4.2 | 24.6 | 1,068 | 4.1 | 23.1 | 2,222 | 4.1 | 23.9 | 4,301 | 4.1 | 25.7 | 7,991
24 | 4.3 | 24.4 | 4.0 | 24.1 | 515 | 4.1 | 24.8 | 1,044 | 3.8 | 23.1 | 2,033 | 4.1 | 24.3 | 4,212 | 4.3 | 26.1 | 8,163
25 | 4.0 | 24.4 | 4.2 | 25.2 | 525 | 4.2 | 25.0 | 1,037 | 4.0 | 24.0 | 2,071 | 4.1 | 24.4 | 4,190 | 3.9 | 26.2 | 7,483
26 | 4.3 | 24.9 | 4.0 | 25.6 | 492 | 4.2 | 25.0 | 1,053 | 4.4 | 23.9 | 2,281 | 4.4 | 24.7 | 4,439 | 3.8 | 26.1 | 7,339
27 | 4.2 | 25.1 | 4.1 | 25.6 | 498 | 3.9 | 24.9 | 969 | 4.0 | 23.5 | 2,126 | 4.1 | 24.9 | 4,145 | 3.8 | 26.3 | 7,318
28 | 4.0 | 25.3 | 3.8 | 25.2 | 475 | 4.3 | 25.1 | 1,061 | 4.2 | 25.0 | 2,107 | 4.2 | 25.1 | 4,151 | 3.9 | 27.3 | 7,214
29 | 4.2 | 25.3 | 3.9 | 25.4 | 479 | 3.8 | 24.9 | 955 | 3.8 | 24.9 | 1,928 | 4.1 | 25.0 | 4,140 | 3.9 | 27.5 | 7,156
30 | 4.6 | 26.0 | 3.8 | 25.0 | 481 | 4.3 | 25.6 | 1,039 | 4.5 | 25.4 | 2,209 | 4.1 | 24.8 | 4,119 | 3.9 | 27.2 | 7,180
31 | 4.5 | 25.8 | 4.2 | 25.1 | 526 | 4.5 | 26.3 | 1,065 | 4.3 | 25.1 | 2,139 | 4.1 | 24.4 | 4,220 | 4.2 | 27.9 | 7,521
32 | 4.4 | 25.1 | 4.4 | 25.1 | 544 | 4.3 | 26.1 | 1,036 | 4.6 | 25.3 | 2,246 | 4.2 | 24.3 | 4,370 | 4.1 | 28.0 | 7,251
33 | 4.3 | 25.6 | 4.4 | 25.1 | 554 | 4.6 | 26.4 | 1,091 | 4.4 | 25.0 | 2,219 | 4.2 | 24.6 | 4,282 | 4.3 | 27.8 | 7,671
34 | 4.3 | 25.6 | 4.6 | 25.1 | 573 | 4.8 | 26.6 | 1,132 | 4.5 | 25.4 | 2,202 | 4.2 | 24.7 | 4,243 | 4.1 | 27.9 | 7,433
35 | 4.1 | 25.4 | 4.5 | 26.0 | 540 | 4.3 | 26.9 | 1,007 | 4.4 | 26.1 | 2,115 | 4.4 | 25.3 | 4,292 | 4.1 | 27.7 | 7,364
36 | 4.6 | 26.1 | 4.2 | 25.7 | 512 | 4.4 | 27.8 | 998 | 4.3 | 26.3 | 2,026 | 3.8 | 25.0 | 3,827 | 3.9 | 27.8 | 7,086
37 | 4.4 | 25.9 | 3.8 | 25.4 | 472 | 4.3 | 27.6 | 982 | 4.3 | 25.8 | 2,064 | 3.8 | 24.7 | 3,866 | 4.1 | 27.2 | 7,545
38 | 4.5 | 26.2 | 4.3 | 26.2 | 507 | 4.1 | 27.0 | 945 | 4.2 | 26.0 | 2,000 | 3.9 | 24.6 | 3,959 | 4.2 | 28.1 | 7,425
39 | 4.3 | 26.5 | 4.0 | 26.4 | 474 | 4.1 | 27.6 | 932 | 4.3 | 26.4 | 2,025 | 4.0 | 24.8 | 4,042 | 4.0 | 28.0 | 7,132
40 | 4.3 | 26.7 | 4.1 | 25.4 | 500 | 4.3 | 26.9 | 1,000 | 4.4 | 26.5 | 2,055 | 4.4 | 26.5 | 4,195 | 4.2 | 28.3 | 7,456
Mean for weeks
2–13 | 4.1 | 20.4 | 4.1 | 20.9 | 609 | 4.0 | 20.6 | 1,209 | 4.0 | 20.3 | 2,496 | 4.0 | 20.7 | 4,822 | 3.9 | 20.9 | 9,323
14–40 | 4.2 | 24.6 | 4.1 | 24.7 | 518 | 4.2 | 25.3 | 1,042 | 4.2 | 24.3 | 2,141 | 4.1 | 24.4 | 4,225 | 4.0 | 26.4 | 7,630

a Grams of feed consumed per animal per day

b Milligrams of aspartame consumed per kilogram body weight per day

TABLE J3 Feed and Compound Consumption by Male p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame

Week | 0 ppm | | 3,125 ppm | | | 6,250 ppm | | | 12,500 ppm | | | 25,000 ppm | | | 50,000 ppm
Week | Feed (g)^a^ | Body Weight (g) | Feed (g) | Body Weight (g) | Dose (mg/kg)^b^ | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg)
2 | 4.1 | 22.0 | 4.5 | 21.8 | 639 | 4.3 | 21.4 | 1,242 | 4.0 | 20.9 | 2,395 | 4.2 | 21.5 | 4,832 | 3.9 | 21.4 | 9,070
3 | 4.2 | 22.6 | 4.1 | 22.3 | 581 | 4.2 | 22.2 | 1,195 | 4.0 | 21.6 | 2,318 | 4.1 | 21.8 | 4,696 | 3.7 | 21.6 | 8,475
4 | 4.1 | 22.8 | 4.3 | 23.0 | 588 | 4.4 | 22.4 | 1,218 | 4.1 | 22.5 | 2,296 | 4.2 | 22.8 | 4,655 | 3.8 | 22.5 | 8,556
5 | 4.3 | 23.5 | 4.3 | 23.6 | 568 | 4.2 | 22.9 | 1,151 | 4.1 | 22.9 | 2,254 | 4.3 | 23.3 | 4,593 | 4.0 | 23.0 | 8,662
6 | 4.2 | 24.0 | 4.3 | 24.1 | 563 | 4.3 | 23.7 | 1,130 | 3.9 | 23.4 | 2,106 | 4.1 | 23.9 | 4,241 | 4.0 | 23.3 | 8,474
7 | 4.3 | 24.8 | 4.3 | 24.7 | 549 | 4.2 | 24.2 | 1,074 | 4.0 | 23.9 | 2,085 | 4.1 | 24.6 | 4,187 | 4.0 | 24.1 | 8,223
8 | 4.3 | 25.7 | 4.3 | 25.5 | 528 | 4.1 | 24.5 | 1,045 | 4.1 | 24.6 | 2,104 | 4.1 | 24.7 | 4,120 | 4.1 | 24.5 | 8,320
9 | 4.1 | 26.1 | 4.3 | 25.9 | 522 | 4.0 | 24.9 | 1,013 | 3.9 | 24.9 | 1,946 | 4.2 | 25.4 | 4,160 | 3.8 | 24.8 | 7,634
10 | 4.2 | 26.6 | 4.5 | 26.2 | 537 | 4.5 | 25.3 | 1,120 | 3.9 | 25.6 | 1,912 | 4.4 | 26.1 | 4,268 | 4.0 | 25.5 | 7,810
11 | 4.0 | 27.0 | 4.6 | 26.7 | 533 | 4.5 | 25.5 | 1,110 | 4.1 | 26.0 | 1,950 | 4.1 | 26.6 | 3,859 | 4.0 | 25.8 | 7,796
12 | 4.1 | 27.1 | 4.6 | 27.2 | 532 | 4.2 | 25.9 | 1,014 | 4.3 | 26.5 | 2,027 | 4.7 | 27.3 | 4,266 | 4.5 | 26.5 | 8,551
13 | 4.1 | 27.6 | 4.4 | 27.6 | 496 | 4.3 | 26.8 | 1,010 | 4.0 | 26.8 | 1,866 | 4.3 | 27.3 | 3,914 | 4.1 | 27.0 | 7,562
14 | 4.3 | 28.0 | 4.2 | 27.8 | 471 | 4.3 | 27.3 | 992 | 4.1 | 27.3 | 1,864 | 4.3 | 28.1 | 3,865 | 4.1 | 27.5 | 7,453
15 | 4.2 | 28.3 | 4.4 | 28.2 | 492 | 4.5 | 27.4 | 1,026 | 4.0 | 27.5 | 1,814 | 4.1 | 28.1 | 3,652 | 3.9 | 27.5 | 7,061
16 | 4.4 | 28.6 | 4.4 | 28.4 | 480 | 4.0 | 27.0 | 931 | 4.1 | 28.1 | 1,839 | 4.4 | 28.4 | 3,887 | 4.2 | 27.8 | 7,460
17 | 4.4 | 29.1 | 4.5 | 28.8 | 493 | 4.4 | 27.8 | 983 | 4.2 | 28.2 | 1,869 | 4.5 | 29.0 | 3,842 | 4.1 | 28.1 | 7,288
18 | 4.3 | 29.4 | 4.5 | 29.2 | 480 | 4.2 | 28.7 | 924 | 4.4 | 28.9 | 1,892 | 4.4 | 29.3 | 3,713 | 4.3 | 28.7 | 7,453
19 | 4.3 | 29.8 | 4.3 | 29.4 | 452 | 4.1 | 29.0 | 884 | 3.9 | 28.9 | 1,692 | 4.1 | 29.4 | 3,460 | 4.1 | 29.2 | 6,937
20 | 4.2 | 30.1 | 4.1 | 29.3 | 441 | 4.1 | 29.1 | 875 | 3.8 | 28.8 | 1,647 | 4.3 | 30.2 | 3,559 | 3.9 | 29.5 | 6,627
21 | 4.1 | 30.3 | 4.2 | 29.6 | 449 | 4.2 | 29.7 | 885 | 3.9 | 29.3 | 1,671 | 4.2 | 30.4 | 3,441 | 3.8 | 29.5 | 6,350
22 | 4.0 | 30.0 | 4.3 | 29.5 | 455 | 4.1 | 29.5 | 861 | 4.1 | 29.6 | 1,731 | 3.9 | 30.0 | 3,240 | 3.8 | 29.0 | 6,538
23 | 4.1 | 30.8 | 4.3 | 29.0 | 459 | 4.2 | 29.8 | 876 | 3.7 | 29.0 | 1,596 | 3.9 | 29.9 | 3,272 | 3.8 | 29.1 | 6,500
24 | 4.1 | 30.6 | 4.3 | 29.6 | 451 | 4.2 | 29.8 | 883 | 3.7 | 29.0 | 1,578 | 4.0 | 29.7 | 3,404 | 3.8 | 29.1 | 6,520
25 | 3.9 | 30.4 | 4.3 | 29.6 | 457 | 4.2 | 29.8 | 873 | 4.0 | 29.2 | 1,693 | 3.8 | 29.2 | 3,275 | 3.7 | 29.1 | 6,276
26 | 4.1 | 30.9 | 4.4 | 30.0 | 453 | 4.2 | 29.7 | 873 | 4.0 | 29.5 | 1,688 | 4.3 | 29.5 | 3,658 | 4.0 | 29.3 | 6,747
27 | 4.0 | 30.8 | 4.1 | 29.8 | 435 | 4.1 | 30.0 | 851 | 4.0 | 29.6 | 1,694 | 4.0 | 29.6 | 3,395 | 3.9 | 29.4 | 6,667
28 | 4.3 | 31.0 | 4.2 | 29.9 | 435 | 4.0 | 29.9 | 829 | 3.9 | 29.7 | 1,653 | 3.9 | 28.8 | 3,357 | 3.9 | 29.7 | 6,523
29 | 4.2 | 31.2 | 4.2 | 30.2 | 438 | 4.1 | 29.9 | 847 | 4.0 | 29.8 | 1,673 | 4.1 | 29.0 | 3,508 | 3.9 | 29.7 | 6,613
30 | 4.5 | 31.8 | 4.4 | 30.6 | 454 | 4.3 | 29.8 | 896 | 4.2 | 30.2 | 1,746 | 4.2 | 29.3 | 3,578 | 4.1 | 29.7 | 6,861
31 | 4.4 | 32.3 | 4.4 | 31.0 | 445 | 4.3 | 30.3 | 884 | 4.2 | 30.0 | 1,752 | 4.2 | 29.4 | 3,578 | 4.2 | 30.2 | 6,970
32 | 4.5 | 32.6 | 4.3 | 31.0 | 434 | 4.3 | 30.6 | 868 | 4.1 | 29.9 | 1,723 | 4.2 | 29.5 | 3,541 | 4.0 | 30.3 | 6,571
33 | 4.3 | 32.4 | 4.3 | 30.9 | 437 | 4.3 | 30.3 | 879 | 4.2 | 29.8 | 1,745 | 4.3 | 29.7 | 3,644 | 4.1 | 30.5 | 6,674
34 | 4.3 | 32.3 | 4.3 | 30.6 | 443 | 4.5 | 30.5 | 917 | 4.1 | 29.9 | 1,710 | 4.6 | 30.3 | 3,811 | 4.0 | 30.2 | 6,611
35 | 4.6 | 32.2 | 4.5 | 30.7 | 453 | 4.2 | 30.2 | 868 | 4.5 | 29.7 | 1,907 | 4.3 | 30.1 | 3,541 | 4.2 | 30.2 | 6,964
36 | 4.4 | 32.4 | 4.4 | 30.9 | 445 | 4.2 | 30.1 | 875 | 4.2 | 29.9 | 1,754 | 4.3 | 30.1 | 3,533 | 4.1 | 30.1 | 6,869
37 | 4.2 | 31.6 | 4.4 | 30.6 | 445 | 4.3 | 30.1 | 897 | 4.2 | 29.7 | 1,761 | 4.0 | 29.7 | 3,383 | 4.0 | 30.1 | 6,654
38 | 4.3 | 31.9 | 4.4 | 30.9 | 447 | 4.4 | 30.1 | 905 | 4.1 | 29.3 | 1,746 | 4.3 | 29.9 | 3,583 | 4.2 | 30.0 | 6,971
39 | 4.1 | 31.9 | 4.2 | 30.4 | 432 | 4.4 | 29.6 | 922 | 3.9 | 29.4 | 1,653 | 4.4 | 30.1 | 3,642 | 4.1 | 29.9 | 6,798
40 | 4.2 | 31.3 | 4.3 | 30.3 | 448 | 4.3 | 29.7 | 911 | 4.5 | 29.8 | 1,872 | 4.3 | 30.1 | 3,526 | 4.1 | 29.9 | 6,790
Mean for weeks
2–13 | 4.2 | 25.0 | 4.4 | 24.9 | 553 | 4.3 | 24.1 | 1,110 | 4.0 | 24.1 | 2,105 | 4.2 | 24.6 | 4,316 | 4.0 | 24.2 | 8,261
14–40 | 4.2 | 30.8 | 4.3 | 29.9 | 453 | 4.2 | 29.5 | 897 | 4.1 | 29.3 | 1,739 | 4.2 | 29.5 | 3,551 | 4.0 | 29.4 | 6,805

a Grams of feed consumed per animal per day

b Milligrams of aspartame consumed per kilogram body weight per day

TABLE J4 Feed and Compound Consumption by Female p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame

Week | 0 ppm | | 3,125 ppm | | | 6,250 ppm | | | 12,500 ppm | | | 25,000 ppm | | | 50,000 ppm
Week | Feed (g)^a^ | Body Weight (g) | Feed (g) | Body Weight (g) | Dose (mg/kg)^b^ | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg)
2 | 3.9 | 18.5 | 4.1 | 18.1 | 706 | 4.0 | 18.2 | 1,378 | 4.2 | 18.1 | 2,898 | 4.1 | 18.2 | 5,686 | 3.8 | 17.7 | 10,687
3 | 4.4 | 19.6 | 4.3 | 19.2 | 695 | 4.0 | 18.9 | 1,313 | 4.1 | 18.7 | 2,724 | 4.2 | 19.0 | 5,551 | 4.0 | 18.6 | 10,601
4 | 4.7 | 20.0 | 4.8 | 20.2 | 737 | 4.5 | 19.9 | 1,407 | 4.7 | 19.9 | 2,938 | 4.4 | 20.1 | 5,428 | 4.0 | 19.3 | 10,387
5 | 4.9 | 20.8 | 4.7 | 20.5 | 714 | 4.7 | 20.5 | 1,444 | 4.8 | 20.3 | 2,991 | 4.5 | 20.1 | 5,589 | 4.2 | 19.9 | 10,482
6 | 4.8 | 21.0 | 4.7 | 20.5 | 722 | 4.8 | 21.2 | 1,404 | 4.6 | 20.6 | 2,798 | 4.4 | 20.6 | 5,344 | 4.3 | 20.3 | 10,630
7 | 5.2 | 20.7 | 4.7 | 20.7 | 707 | 4.8 | 20.5 | 1,465 | 4.9 | 20.6 | 2,950 | 4.7 | 20.8 | 5,670 | 4.6 | 19.9 | 11,459
8 | 5.0 | 21.5 | 4.5 | 20.9 | 676 | 5.0 | 21.4 | 1,451 | 4.8 | 21.3 | 2,827 | 4.5 | 21.0 | 5,347 | 4.5 | 21.3 | 10,536
9 | 4.8 | 21.7 | 4.7 | 21.5 | 689 | 5.0 | 22.0 | 1,414 | 5.0 | 21.4 | 2,934 | 4.9 | 21.7 | 5,581 | 4.3 | 21.3 | 9,994
10 | 5.3 | 22.1 | 5.0 | 21.8 | 714 | 4.9 | 22.0 | 1,380 | 4.8 | 22.2 | 2,699 | 4.9 | 21.7 | 5,648 | 3.9 | 21.9 | 8,969
11 | 5.6 | 22.1 | 4.8 | 22.0 | 687 | 5.3 | 22.4 | 1,474 | 5.1 | 22.3 | 2,830 | 5.1 | 22.2 | 5,702 | 4.6 | 21.8 | 10,565
12 | 5.1 | 22.0 | 4.8 | 22.0 | 682 | 4.4 | 22.6 | 1,222 | 5.1 | 22.5 | 2,828 | 4.6 | 22.3 | 5,157 | 4.8 | 21.9 | 10,939
13 | 5.1 | 22.2 | 4.9 | 22.6 | 683 | 4.7 | 23.4 | 1,261 | 4.7 | 22.5 | 2,635 | 4.8 | 22.5 | 5,349 | 4.6 | 22.3 | 10,385
14 | 4.5 | 22.6 | 4.4 | 23.0 | 592 | 4.2 | 23.5 | 1,106 | 4.5 | 22.9 | 2,448 | 4.6 | 22.9 | 5,026 | 4.3 | 22.6 | 9,436
15 | 4.3 | 22.9 | 4.6 | 23.2 | 621 | 4.3 | 23.9 | 1,134 | 4.2 | 22.9 | 2,267 | 5.1 | 23.6 | 5,416 | 4.6 | 22.9 | 10,064
16 | 4.7 | 22.7 | 5.0 | 23.3 | 670 | 4.4 | 24.0 | 1,146 | 5.1 | 23.3 | 2,735 | 4.7 | 23.4 | 4,989 | 5.0 | 23.1 | 10,709
17 | 4.9 | 23.1 | 4.8 | 23.4 | 640 | 4.9 | 24.0 | 1,272 | 4.7 | 23.6 | 2,493 | 4.7 | 22.9 | 5,080 | 4.0 | 23.0 | 8,713
18 | 4.9 | 23.3 | 4.8 | 23.4 | 640 | 4.5 | 24.4 | 1,153 | 5.6 | 24.4 | 2,852 | 4.8 | 23.3 | 5,140 | 4.8 | 23.5 | 10,290
19 | 4.6 | 23.6 | 4.5 | 23.5 | 598 | 4.3 | 24.8 | 1,074 | 4.8 | 24.6 | 2,440 | 4.6 | 23.6 | 4,891 | 4.6 | 23.6 | 9,754
20 | 4.6 | 23.7 | 4.3 | 23.8 | 569 | 4.2 | 24.8 | 1,051 | 4.5 | 25.1 | 2,227 | 4.4 | 23.8 | 4,643 | 4.5 | 24.1 | 9,340
21 | 4.0 | 23.7 | 4.2 | 23.5 | 563 | 4.3 | 25.1 | 1,080 | 4.4 | 25.1 | 2,195 | 4.3 | 24.0 | 4,473 | 4.3 | 24.3 | 8,764
22 | 4.9 | 24.1 | 4.4 | 23.7 | 584 | 4.6 | 25.0 | 1,139 | 4.9 | 25.1 | 2,436 | 4.5 | 23.7 | 4,702 | 4.3 | 24.0 | 8,868
23 | 4.8 | 24.0 | 4.7 | 23.4 | 623 | 4.7 | 25.3 | 1,164 | 4.3 | 24.9 | 2,165 | 4.7 | 23.7 | 4,915 | 4.1 | 23.6 | 8,710
24 | 4.8 | 24.2 | 4.7 | 23.8 | 613 | 4.5 | 25.5 | 1,112 | 4.5 | 24.7 | 2,295 | 4.5 | 23.8 | 4,686 | 4.6 | 24.2 | 9,482
25 | 4.8 | 24.2 | 4.7 | 23.6 | 617 | 4.6 | 25.4 | 1,120 | 4.7 | 24.7 | 2,382 | 4.6 | 23.5 | 4,888 | 4.4 | 24.1 | 9,102
26 | 4.5 | 24.3 | 4.6 | 23.7 | 607 | 4.8 | 25.7 | 1,156 | 4.8 | 25.1 | 2,418 | 4.8 | 24.3 | 4,956 | 4.5 | 24.4 | 9,152
27 | 4.7 | 23.9 | 4.3 | 23.4 | 579 | 4.5 | 25.7 | 1,090 | 4.4 | 25.1 | 2,218 | 4.4 | 24.0 | 4,540 | 4.5 | 24.2 | 9,354
28 | 4.9 | 24.5 | 4.4 | 23.4 | 590 | 4.6 | 25.8 | 1,109 | 4.8 | 25.1 | 2,376 | 4.6 | 23.9 | 4,761 | 4.5 | 24.3 | 9,267
29 | 4.6 | 24.2 | 4.6 | 23.4 | 616 | 4.7 | 25.8 | 1,144 | 4.7 | 25.1 | 2,340 | 4.5 | 24.0 | 4,676 | 4.3 | 24.4 | 8,775
30 | 4.7 | 25.0 | 4.5 | 24.1 | 579 | 4.5 | 25.5 | 1,102 | 4.6 | 25.8 | 2,238 | 4.7 | 24.2 | 4,851 | 4.2 | 24.3 | 8,690
31 | 4.4 | 25.2 | 4.3 | 24.1 | 555 | 4.4 | 25.7 | 1,068 | 4.4 | 26.0 | 2,115 | 4.6 | 24.5 | 4,712 | 4.3 | 24.7 | 8,720
32 | 4.4 | 25.3 | 4.4 | 24.4 | 559 | 4.3 | 25.8 | 1,033 | 4.4 | 25.8 | 2,141 | 4.2 | 24.3 | 4,273 | 4.5 | 24.6 | 9,187
33 | 4.7 | 24.9 | 4.4 | 24.0 | 572 | 4.5 | 25.8 | 1,093 | 4.7 | 25.9 | 2,252 | 4.7 | 24.5 | 4,795 | 4.6 | 25.0 | 9,121
34 | 4.6 | 25.2 | 4.6 | 24.5 | 589 | 4.3 | 25.9 | 1,032 | 4.4 | 25.9 | 2,133 | 4.5 | 24.9 | 4,525 | 4.5 | 24.6 | 9,199
35 | 4.8 | 25.2 | 4.5 | 24.7 | 564 | 6.8 | 25.8 | 1,650 | 5.3 | 25.8 | 2,572 | 5.1 | 24.9 | 5,113 | 4.6 | 24.5 | 9,396
36 | 4.6 | 25.4 | 4.5 | 24.7 | 569 | 4.7 | 26.4 | 1,117 | 4.4 | 26.0 | 2,131 | 4.5 | 25.1 | 4,444 | 4.3 | 24.9 | 8,708
37 | 4.7 | 25.3 | 4.5 | 24.6 | 567 | 4.5 | 26.3 | 1,074 | 4.8 | 26.0 | 2,291 | 4.6 | 25.0 | 4,578 | 4.3 | 24.8 | 8,746
38 | 4.9 | 25.7 | 4.5 | 24.4 | 580 | 4.8 | 26.6 | 1,135 | 4.9 | 26.0 | 2,336 | 4.8 | 25.4 | 4,719 | 4.5 | 25.1 | 9,009
39 | 4.4 | 25.7 | 4.6 | 24.4 | 585 | 4.5 | 26.5 | 1,066 | 4.4 | 25.8 | 2,134 | 4.9 | 25.4 | 4,844 | 4.5 | 25.0 | 8,939
40 | 4.7 | 26.1 | 4.5 | 24.3 | 580 | 4.6 | 26.2 | 1,086 | 4.6 | 25.4 | 2,252 | 4.7 | 25.3 | 4,617 | 4.7 | 25.1 | 9,338
Mean for weeks
2–13 | 4.9 | 21.0 | 4.7 | 20.8 | 701 | 4.7 | 21.1 | 1,384 | 4.7 | 20.9 | 2,838 | 4.6 | 20.9 | 5,504 | 4.3 | 20.5 | 10,469
14–40 | 4.6 | 24.4 | 4.5 | 23.8 | 593 | 4.6 | 25.4 | 1,130 | 4.7 | 25.0 | 2,329 | 4.6 | 24.2 | 4,787 | 4.5 | 24.2 | 9,216

a Grams of feed consumed per animal per day

b Milligrams of aspartame consumed per kilogram body weight per day

TABLE J5 Feed and Compound Consumption by Male Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame

Week | 0 ppm | | 3,125 ppm | | | 6,250 ppm | | | 12,500 ppm | | | 25,000 ppm | | | 50,000 ppm
Week | Feed (g)^a^ | Body Weight (g) | Feed (g) | Body Weight (g) | Dose (mg/kg)^b^ | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg)
2 | 4.4 | 22.4 | 4.3 | 22.2 | 598 | 4.7 | 22.4 | 1,301 | 4.2 | 22.1 | 2,367 | 4.0 | 22.0 | 4,525 | 3.9 | 22.3 | 8,802
3 | 4.6 | 23.1 | 4.5 | 23.2 | 608 | 4.4 | 23.0 | 1,200 | 4.6 | 22.9 | 2,520 | 4.1 | 22.7 | 4,555 | 4.1 | 23.0 | 8,809
4 | 4.6 | 23.6 | 4.4 | 23.8 | 578 | 4.4 | 23.4 | 1,181 | 4.4 | 23.8 | 2,284 | 4.2 | 23.0 | 4,575 | 4.2 | 23.6 | 8,881
5 | 4.8 | 25.0 | 4.8 | 24.9 | 597 | 4.6 | 24.6 | 1,164 | 4.7 | 24.8 | 2,391 | 4.7 | 24.7 | 4,788 | 4.4 | 24.9 | 8,835
6 | 5.1 | 25.6 | 4.6 | 25.5 | 558 | 4.6 | 25.1 | 1,145 | 4.5 | 25.2 | 2,231 | 4.2 | 25.0 | 4,202 | 4.5 | 25.1 | 9,012
7 | 4.8 | 26.1 | 4.9 | 26.5 | 581 | 4.6 | 26.2 | 1,086 | 4.7 | 25.6 | 2,276 | 4.6 | 26.1 | 4,419 | 4.5 | 26.4 | 8,491
8 | 4.7 | 26.7 | 4.7 | 26.7 | 550 | 4.6 | 26.3 | 1,095 | 4.8 | 26.7 | 2,229 | 4.7 | 26.6 | 4,439 | 4.4 | 26.5 | 8,308
9 | 4.9 | 27.4 | 4.9 | 27.7 | 553 | 4.4 | 26.5 | 1,042 | 4.2 | 27.2 | 1,945 | 4.2 | 27.1 | 3,845 | 4.1 | 26.9 | 7,709
10 | 5.1 | 28.6 | 4.5 | 27.9 | 505 | 4.9 | 27.1 | 1,135 | 4.7 | 27.6 | 2,108 | 4.1 | 27.7 | 3,714 | 4.7 | 27.3 | 8,670
11 | 4.8 | 28.9 | 4.7 | 27.9 | 526 | 4.8 | 27.9 | 1,085 | 4.7 | 28.2 | 2,091 | 4.5 | 28.0 | 4,021 | 4.8 | 28.1 | 8,499
12 | 4.9 | 29.4 | 4.9 | 28.4 | 542 | 4.9 | 28.2 | 1,086 | 4.6 | 28.3 | 2,039 | 4.2 | 28.2 | 3,715 | 4.8 | 28.9 | 8,385
13 | 4.9 | 30.0 | 4.6 | 28.8 | 499 | 4.6 | 28.3 | 1,013 | 4.7 | 29.0 | 2,042 | 5.0 | 29.1 | 4,255 | 4.8 | 29.2 | 8,263
14 | 4.9 | 30.1 | 4.8 | 29.1 | 517 | 4.8 | 28.7 | 1,047 | 5.1 | 29.6 | 2,147 | 4.6 | 29.1 | 3,951 | 4.8 | 29.4 | 8,192
15 | 5.0 | 30.8 | 5.1 | 29.4 | 543 | 5.3 | 29.8 | 1,120 | 5.0 | 29.9 | 2,079 | 4.8 | 29.5 | 4,066 | 4.8 | 29.9 | 8,047
16 | 5.1 | 30.6 | 4.9 | 29.8 | 516 | 4.6 | 29.8 | 966 | 5.3 | 30.7 | 2,159 | 4.8 | 29.8 | 3,991 | 4.8 | 30.4 | 7,849
17 | 4.8 | 31.6 | 4.4 | 30.7 | 448 | 4.7 | 30.8 | 960 | 4.8 | 31.7 | 1,907 | 4.4 | 30.5 | 3,641 | 4.5 | 31.4 | 7,214
18 | 4.9 | 32.4 | 4.6 | 31.1 | 463 | 4.1 | 30.5 | 847 | 5.2 | 32.1 | 2,028 | 4.5 | 31.6 | 3,556 | 4.4 | 31.6 | 7,012
19 | 4.5 | 32.8 | 4.4 | 31.5 | 440 | 4.4 | 30.1 | 904 | 4.5 | 32.4 | 1,732 | 4.5 | 32.0 | 3,482 | 4.6 | 32.1 | 7,177
20 | 4.5 | 33.3 | 4.8 | 32.1 | 463 | 4.8 | 30.9 | 971 | 4.5 | 32.8 | 1,697 | 4.7 | 32.2 | 3,642 | 4.7 | 32.7 | 7,242
21 | 4.8 | 34.0 | 4.9 | 32.6 | 472 | 4.8 | 31.9 | 941 | 5.0 | 33.1 | 1,874 | 4.8 | 33.0 | 3,673 | 4.5 | 32.8 | 6,908
22 | 4.8 | 34.2 | 4.6 | 32.7 | 441 | 4.6 | 32.2 | 898 | 4.5 | 32.7 | 1,733 | 4.5 | 33.1 | 3,376 | 4.4 | 33.1 | 6,639
23 | 4.8 | 34.4 | 4.7 | 32.7 | 451 | 4.4 | 32.2 | 864 | 4.5 | 33.0 | 1,695 | 4.6 | 33.0 | 3,447 | 4.3 | 33.0 | 6,458
24 | 4.3 | 34.5 | 4.3 | 32.7 | 407 | 4.3 | 32.2 | 840 | 4.5 | 33.3 | 1,672 | 4.4 | 33.0 | 3,310 | 4.3 | 33.4 | 6,495
25 | 4.8 | 34.6 | 4.6 | 32.8 | 440 | 4.5 | 32.2 | 881 | 4.4 | 33.2 | 1,649 | 4.3 | 32.9 | 3,281 | 4.3 | 33.3 | 6,481
26 | 4.5 | 34.6 | 4.4 | 32.7 | 425 | 4.5 | 32.2 | 866 | 4.7 | 33.6 | 1,754 | 4.4 | 33.1 | 3,335 | 4.4 | 33.5 | 6,551
27 | 4.6 | 34.6 | 4.6 | 32.7 | 443 | 4.5 | 32.6 | 873 | 4.6 | 33.8 | 1,701 | 4.5 | 33.3 | 3,397 | 4.5 | 33.7 | 6,626
28 | 4.7 | 35.1 | 4.7 | 33.4 | 439 | 4.5 | 32.9 | 847 | 4.7 | 34.3 | 1,695 | 4.6 | 33.9 | 3,397 | 4.4 | 33.8 | 6,559
29 | 4.8 | 35.6 | 4.7 | 33.9 | 438 | 4.3 | 33.3 | 815 | 4.6 | 34.6 | 1,659 | 4.4 | 34.3 | 3,201 | 4.3 | 33.9 | 6,382
30 | 4.6 | 35.9 | 4.4 | 33.8 | 407 | 4.6 | 33.8 | 850 | 4.4 | 35.0 | 1,570 | 4.6 | 34.6 | 3,347 | 4.4 | 34.3 | 6,474
31 | 4.5 | 35.8 | 4.4 | 33.4 | 414 | 4.4 | 33.9 | 812 | 4.6 | 34.8 | 1,639 | 4.6 | 34.5 | 3,332 | 4.4 | 34.4 | 6,455
32 | 5.0 | 36.1 | 4.7 | 33.5 | 438 | 4.3 | 33.7 | 800 | 4.6 | 34.8 | 1,644 | 4.4 | 34.6 | 3,202 | 4.4 | 34.0 | 6,442
33 | 4.9 | 35.6 | 5.0 | 33.5 | 462 | 4.8 | 34.0 | 878 | 4.7 | 34.3 | 1,714 | 4.8 | 34.6 | 3,488 | 4.6 | 33.9 | 6,844
34 | 4.7 | 36.1 | 4.4 | 33.1 | 419 | 4.3 | 34.2 | 791 | 4.3 | 34.9 | 1,547 | 4.4 | 35.1 | 3,133 | 4.4 | 34.4 | 6,462
35 | 5.4 | 35.4 | 5.1 | 33.0 | 485 | 4.9 | 33.9 | 897 | 5.4 | 35.3 | 1,895 | 4.5 | 34.8 | 3,258 | 4.8 | 34.3 | 7,040
36 | 4.9 | 35.6 | 4.7 | 33.6 | 440 | 4.8 | 34.3 | 865 | 4.8 | 35.5 | 1,687 | 4.7 | 35.3 | 3,346 | 4.7 | 34.3 | 6,871
37 | 4.7 | 35.6 | 4.7 | 33.1 | 446 | 4.7 | 34.1 | 856 | 5.0 | 35.1 | 1,781 | 4.7 | 34.9 | 3,364 | 4.6 | 33.9 | 6,811
38 | 4.9 | 35.9 | 4.6 | 32.6 | 445 | 5.0 | 34.0 | 926 | 4.9 | 35.2 | 1,742 | 4.7 | 35.0 | 3,338 | 4.7 | 34.1 | 6,883
39 | 4.7 | 35.6 | 4.5 | 32.4 | 436 | 4.4 | 33.9 | 818 | 4.6 | 34.9 | 1,641 | 4.6 | 35.4 | 3,261 | 4.6 | 34.4 | 6,738
40 | 5.0 | 35.7 | 5.2 | 33.1 | 495 | 4.9 | 33.7 | 916 | 4.8 | 35.0 | 1,716 | 4.8 | 35.6 | 3,388 | 4.8 | 34.2 | 7,042
2–13 | 4.8 | 26.4 | 4.6 | 26.1 | 558 | 4.6 | 25.7 | 1,128 | 4.6 | 25.9 | 2,210 | 4.4 | 25.8 | 4,254 | 4.4 | 26.0 | 8,555
14–40 | 4.8 | 34.3 | 4.7 | 32.4 | 453 | 4.6 | 32.4 | 891 | 4.7 | 33.5 | 1,769 | 4.6 | 33.3 | 3,452 | 4.5 | 33.1 | 6,885

a Grams of feed consumed per animal per day

b Milligrams of aspartame consumed per kilogram body weight per day

TABLE J6 Feed and Compound Consumption by Female Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame

Week | 0 ppm | | 3,125 ppm | | | 6,250 ppm | | | 12,500 ppm | | | 25,000 ppm | | | 50,000 ppm
Week | Feed (g)^a^ | Body Weight (g) | Feed (g) | Body Weight (g) | Dose (mg/kg)^b^ | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg) | Feed (g) | Body Weight (g) | Dose (mg/kg)
2 | 4.8 | 18.7 | 5.4 | 19.0 | 887 | 4.5 | 18.4 | 1,517 | 4.3 | 18.6 | 2,920 | 4.3 | 18.6 | 5,761 | 4.1 | 18.8 | 10,888
3 | 4.8 | 19.8 | 4.9 | 20.3 | 758 | 4.9 | 19.8 | 1,541 | 4.4 | 20.0 | 2,756 | 4.3 | 19.6 | 5,434 | 4.2 | 20.0 | 10,466
4 | 4.9 | 20.7 | 4.8 | 21.0 | 712 | 4.5 | 20.6 | 1,351 | 4.4 | 20.8 | 2,659 | 4.2 | 20.3 | 5,204 | 4.4 | 20.7 | 10,640
5 | 5.1 | 21.2 | 5.3 | 21.6 | 769 | 5.3 | 21.9 | 1,511 | 4.8 | 21.4 | 2,796 | 4.6 | 20.9 | 5,479 | 5.0 | 21.9 | 11,426
6 | 5.1 | 22.1 | 4.9 | 22.3 | 684 | 4.8 | 22.4 | 1,346 | 5.1 | 22.3 | 2,884 | 4.8 | 21.8 | 5,514 | 5.0 | 22.5 | 11,210
7 | 5.0 | 22.5 | 5.5 | 23.0 | 753 | 4.7 | 22.6 | 1,298 | 5.0 | 22.8 | 2,716 | 5.4 | 22.3 | 6,050 | 4.9 | 22.6 | 10,898
8 | 5.5 | 21.8 | 5.7 | 22.3 | 801 | 5.4 | 22.6 | 1,508 | 5.5 | 22.9 | 2,981 | 5.1 | 22.0 | 5,794 | 5.3 | 22.5 | 11,842
9 | 5.7 | 22.7 | 5.0 | 23.1 | 672 | 4.5 | 23.0 | 1,227 | 4.7 | 23.0 | 2,559 | 4.3 | 22.1 | 4,907 | 4.4 | 22.8 | 9,617
10 | 5.9 | 23.1 | 5.0 | 23.4 | 666 | 5.4 | 22.8 | 1,479 | 4.8 | 23.7 | 2,551 | 4.6 | 22.8 | 5,069 | 5.1 | 23.1 | 11,074
11 | 5.9 | 23.0 | 5.4 | 23.6 | 716 | 4.8 | 23.7 | 1,258 | 5.1 | 23.9 | 2,673 | 5.1 | 22.9 | 5,576 | 5.3 | 23.6 | 11,196
12 | 5.6 | 23.3 | 5.2 | 24.1 | 675 | 4.8 | 24.0 | 1,236 | 5.1 | 24.7 | 2,581 | 4.7 | 23.1 | 5,039 | 5.0 | 23.9 | 10,461
13 | 4.8 | 23.5 | 4.5 | 24.5 | 573 | 4.4 | 23.8 | 1,166 | 4.5 | 25.0 | 2,237 | 4.8 | 23.8 | 5,013 | 4.5 | 23.9 | 9,453
14 | 5.3 | 23.3 | 5.9 | 24.2 | 762 | 5.5 | 24.0 | 1,431 | 5.9 | 24.6 | 2,989 | 5.1 | 23.3 | 5,508 | 5.6 | 24.2 | 11,475
15 | 6.3 | 24.3 | 5.9 | 25.0 | 743 | 6.2 | 25.1 | 1,540 | 6.0 | 25.1 | 2,985 | 5.9 | 23.8 | 6,215 | 5.5 | 24.8 | 11,035
16 | 5.7 | 24.3 | 5.8 | 24.9 | 729 | 5.5 | 25.1 | 1,363 | 6.1 | 25.3 | 2,994 | 5.3 | 23.7 | 5,616 | 5.1 | 24.5 | 10,383
17 | 5.2 | 24.4 | 4.7 | 25.7 | 571 | 4.7 | 26.1 | 1,128 | 4.7 | 25.8 | 2,269 | 4.5 | 24.2 | 4,688 | 4.8 | 25.6 | 9,320
18 | 5.1 | 24.8 | 4.7 | 25.8 | 569 | 4.4 | 26.1 | 1,055 | 4.8 | 25.8 | 2,349 | 4.5 | 24.9 | 4,503 | 4.5 | 25.7 | 8,794
19 | 4.2 | 25.1 | 4.5 | 26.3 | 540 | 4.2 | 26.1 | 1,002 | 4.5 | 26.2 | 2,132 | 4.1 | 25.1 | 4,117 | 4.4 | 25.8 | 8,460
20 | 4.6 | 25.3 | 4.8 | 26.7 | 565 | 5.0 | 25.5 | 1,229 | 4.7 | 26.3 | 2,208 | 4.7 | 25.1 | 4,675 | 5.1 | 26.0 | 9,808
21 | 5.2 | 25.7 | 5.4 | 27.2 | 619 | 5.1 | 26.1 | 1,225 | 5.1 | 26.9 | 2,376 | 5.0 | 25.6 | 4,906 | 5.1 | 26.5 | 9,620
22 | 4.8 | 25.4 | 4.9 | 27.0 | 570 | 4.6 | 26.7 | 1,071 | 4.5 | 26.8 | 2,089 | 4.7 | 25.4 | 4,665 | 4.8 | 26.5 | 9,073
23 | 5.1 | 25.3 | 4.8 | 26.8 | 556 | 4.8 | 26.7 | 1,123 | 4.9 | 26.6 | 2,286 | 4.7 | 25.7 | 4,551 | 4.9 | 26.7 | 9,144
24 | 4.7 | 25.7 | 4.5 | 27.2 | 516 | 4.5 | 26.9 | 1,034 | 4.5 | 26.5 | 2,097 | 4.5 | 25.4 | 4,403 | 4.6 | 26.6 | 8,674
25 | 4.6 | 25.9 | 4.6 | 27.4 | 527 | 4.6 | 26.4 | 1,081 | 4.5 | 26.7 | 2,125 | 4.5 | 25.3 | 4,425 | 4.3 | 26.2 | 8,297
26 | 4.9 | 26.2 | 4.6 | 27.3 | 528 | 4.6 | 26.7 | 1,077 | 4.6 | 26.8 | 2,138 | 4.5 | 25.4 | 4,436 | 4.5 | 26.2 | 8,651
27 | 4.7 | 25.6 | 4.6 | 26.9 | 531 | 4.7 | 26.5 | 1,115 | 4.8 | 27.0 | 2,208 | 4.8 | 25.6 | 4,653 | 4.8 | 26.7 | 8,955
28 | 4.4 | 26.2 | 4.5 | 27.9 | 501 | 4.6 | 27.4 | 1,045 | 4.5 | 27.4 | 2,042 | 4.5 | 25.9 | 4,374 | 4.6 | 26.9 | 8,461
29 | 4.6 | 26.8 | 4.6 | 28.1 | 509 | 4.3 | 27.0 | 986 | 4.5 | 27.6 | 2,049 | 4.3 | 26.1 | 4,094 | 4.4 | 26.7 | 8,267
30 | 4.4 | 26.4 | 4.4 | 28.5 | 480 | 4.3 | 27.2 | 993 | 4.2 | 27.8 | 1,905 | 4.5 | 26.4 | 4,259 | 4.4 | 27.1 | 8,172
31 | 4.4 | 25.6 | 4.4 | 28.2 | 486 | 4.6 | 28.3 | 1,006 | 4.3 | 27.7 | 1,950 | 4.3 | 26.3 | 4,127 | 4.4 | 27.5 | 8,000
32 | 4.5 | 26.2 | 4.5 | 28.1 | 497 | 4.5 | 27.8 | 1,019 | 4.2 | 27.7 | 1,897 | 4.7 | 26.7 | 4,365 | 4.5 | 27.4 | 8,234
33 | 5.8 | 26.8 | 5.1 | 28.0 | 568 | 4.8 | 28.1 | 1,078 | 4.7 | 27.5 | 2,135 | 4.6 | 26.5 | 4,335 | 5.3 | 27.6 | 9,700
34 | 4.9 | 27.1 | 4.3 | 28.4 | 479 | 4.4 | 28.3 | 973 | 4.4 | 27.7 | 1,968 | 4.6 | 26.9 | 4,233 | 4.3 | 28.1 | 7,596
35 | 5.8 | 27.0 | 5.9 | 28.0 | 656 | 5.3 | 27.9 | 1,177 | 5.5 | 28.0 | 2,439 | 4.9 | 26.9 | 4,534 | 5.1 | 27.8 | 9,251
36 | 5.4 | 27.0 | 5.2 | 28.1 | 575 | 4.9 | 28.1 | 1,093 | 5.1 | 28.0 | 2,260 | 4.8 | 26.4 | 4,519 | 5.1 | 28.0 | 9,129
37 | 5.2 | 26.8 | 5.1 | 27.6 | 573 | 5.0 | 27.7 | 1,122 | 5.1 | 27.8 | 2,284 | 5.0 | 26.8 | 4,655 | 4.9 | 27.7 | 8,789
38 | 5.0 | 26.9 | 4.9 | 27.7 | 550 | 4.7 | 28.0 | 1,061 | 4.8 | 27.8 | 2,155 | 4.9 | 26.6 | 4,613 | 5.1 | 27.7 | 9,244
39 | 4.8 | 26.7 | 4.5 | 27.6 | 507 | 4.7 | 28.3 | 1,036 | 4.6 | 28.2 | 2,054 | 4.7 | 27.1 | 4,344 | 4.5 | 27.8 | 8,069
40 | 5.4 | 27.4 | 5.4 | 27.9 | 600 | 5.5 | 28.8 | 1,195 | 5.2 | 28.6 | 2,296 | 5.1 | 26.9 | 4,697 | 5.1 | 28.3 | 9,044
2–13 | 5.2 | 21.9 | 5.1 | 22.4 | 722 | 4.8 | 22.2 | 1,370 | 4.8 | 22.4 | 2,693 | 4.7 | 21.7 | 5,403 | 4.8 | 22.2 | 10,764
14–40 | 5.0 | 25.9 | 4.9 | 27.1 | 567 | 4.8 | 26.9 | 1,121 | 4.8 | 27.0 | 2,247 | 4.7 | 25.7 | 4,611 | 4.8 | 26.7 | 9,024

a Grams of feed consumed per animal per day

b Milligrams of aspartame consumed per kilogram body weight per day