# APPENDIX I CHEMICAL CHARACTERIZATION AND DOSE FORMULATION STUDIES

## Procurement and Characterization of Aspartame

Aspartame was obtained from Spectrum Quality Products, Inc. (Gardena, CA), in two shipments of one lot (8415-14-02 RTI) used for the 9-month studies in Tg.AC hemizygous, p53 haploinsufficient, and Cdkn2a deficient mice. Identity and purity analyses were conducted by the analytical chemistry laboratory, Research Triangle Institute (Research Triangle Park, NC), and the study laboratory, BioReliance Corporation (Rockville, MD); the study laboratory also conducted stability analyses. Reports on analyses performed in support of the aspartame studies are on file at the National Institute of Environmental Health Sciences.

Lot 8415-14-02 RTI of the chemical, a white, odorless, crystalline powder, was identified as aspartame by the analytical chemistry laboratory using infrared and proton nuclear magnetic resonance spectroscopy and by the study laboratory using infrared spectroscopy. All spectra were consistent with the structure of aspartame, and the infrared spectra matched a reference spectrum (Aldrich, 1981) of aspartame. The infrared and nuclear magnetic resonance spectra are presented in Figures I1 and I2.

The purity of lot 8415-14-02 RTI was determined by the analytical chemistry laboratory using a high-performance liquid chromatography (HPLC) system consisting of a Waters (Milford, MA) HPLC, a Symmetry C_18_ column, 15 cm × 3.9 mm (Waters), photodiode array (205 nm) detection, a mobile phase of 0.02 M pentanesulfonic acid in water, (pH 3.0, adjusted with phosphoric acid) and methanol (70:30), and a flow rate of 1.0 mL/minute (system 1). The study laboratory confirmed purity by conducting major peak comparisons of lot 8415-14-02 RTI with a reference sample of the same lot (stored at less than or equal to −20° C under nitrogen headspace) using an HPLC system similar to system 1 with a Hewlett-Packard (Palo Alto, CA) instrument and a variation in the mobile phase (0.02 M 1-pentanesulfonic acid, sodium salt, in deionized water:methanol; 55:45) (system 2).

For lot 8415-14-02 RTI, HPLC by the analytical chemistry laboratory indicated one major peak and three impurities with a combined area of 0.5% relative to the total peak area. HPLC by the study laboratory indicated a purity of 98.7% for lot 8415-14-02 RTI relative to the reference. The overall purity of lot 8415-14-02 RTI was determined to be greater than 98%.

To ensure stability, the bulk chemical was stored at room temperature, protected from light, in polyethlene bags inside metal drums. The stability of the bulk chemical was monitored during the studies by the study laboratory using HPLC system 2. No degradation of the bulk chemical was detected.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared every 2 weeks by mixing aspartame with feed (Table I1). A premix was prepared by hand and then blended with additional feed in a Patterson-Kelly twin-shell blender for 15 minutes using an intensifier bar for the initial five minutes. Formulations were stored in doubled polyethylene bags at 2° C to 8° C, protected from light, for up to 28 days.

Homogeneity and stability studies of dose formulations containing 1,000, 10,000, and 50,000 ppm aspartame were performed by the analytical chemistry laboratory using HPLC by system 1 with a variation in the mobile phase ratio (60:40). Homogeneity studies of formulations containing 3,125 and 50,000 ppm aspartame were performed by the study laboratory using HPLC (system 2). Homogeneity was confirmed, and stability was confirmed for up to 28 days at −20° C and 5° C for dose formulations stored in doubled polyethylene bags. There was no significant loss of aspartame from NTP-2000 feed formulations exposed to air and light for 7 days.

Periodic analyses of the dose formulations of aspartame were conducted by the study laboratory using HPLC by system 2. During the 9-month studies, the dose formulations were analyzed seven times; all (35/35) of the dose formulations analyzed were within 10% of the target concentrations (Table I2). Animal room samples of these dose formulations were also analyzed, and 27 of 35 animal room samples were within 10% of the target concentrations (Table I2). Dose formulations were stored refrigerated, protected from light, in doubled polyethylene bags for up to 28 days.

FIGURE I1 Infrared Absorption Spectrum of Aspartame

FIGURE I2 Proton Nuclear Magnetic Resonance Spectrum of Aspartame

TABLE I1 Preparation and Storage of Dose Formulations in the 9-Month Feed Studies of Aspartame

Preparation
A premix of feed and aspartame was prepared, then layered into the remaining feed and blended in a Patterson-Kelley twin-shell blender with the intensifier bar on for 5 minutes and off for 10 minutes. The dose formulations were prepared every 2 weeks.
Chemical Lot Number
8415-14-02 RTI
Maximum Storage Time
28 days
Storage Conditions
Stored in doubled polyethylene bags at 2° to 8° C, protected from light
Study Laboratory
BioReliance Corporation (Rockville, MD)

TABLE I2 Results of Analyses of Dose Formulations Administered to Tg.AC Hemizygous Mice, p53 Haploinsufficient Mice, and Cdkn2a Deficient Mice in the 9-Month Feed Studies of Aspartame

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration^a^ (ppm) | Difference from Target (%)
October 5, 1999 | October 5, 1999 | 3,125 | 3,090 | −1
October 5, 1999 | October 5, 1999 | 6,250 | 6,290 | +1
October 5, 1999 | October 5, 1999 | 12,500 | 12,400 | −1
October 5, 1999 | October 5, 1999 | 25,000 | 25,200 | +1
October 5, 1999 | October 5, 1999 | 50,000 | 51,200 | +2
October 5, 1999 | October 26, 1999^b^ | 3,125 | 2,610 | −16
October 5, 1999 | October 26, 1999^b^ | 6,250 | 5,480 | −12
October 5, 1999 | October 26, 1999^b^ | 12,500 | 11,300 | −10
October 5, 1999 | October 26, 1999^b^ | 25,000 | 23,100 | −8
October 5, 1999 | October 26, 1999^b^ | 50,000 | 45,700 | −9
November 30, 1999 | November 30, 1999 | 3,125 | 3,140 | 0
November 30, 1999 | November 30, 1999 | 6,250 | 6,210 | −1
November 30, 1999 | November 30, 1999 | 12,500 | 12,700 | +2
November 30, 1999 | November 30, 1999 | 25,000 | 24,700 | −1
November 30, 1999 | November 30, 1999 | 50,000 | 48,500 | −3
November 30, 1999 | December 28, 1999^b^ | 3,125 | 2,880 | −8
November 30, 1999 | December 28, 1999^b^ | 6,250 | 5,380 | −14
November 30, 1999 | December 28, 1999^b^ | 12,500 | 11,400 | −9
November 30, 1999 | December 28, 1999^b^ | 25,000 | 22,600 | −10
November 30, 1999 | December 28, 1999^b^ | 50,000 | 46,500 | −7
February 23, 2000 | February 23, 2000 | 3,125 | 3,370 | +8
February 23, 2000 | February 23, 2000 | 6,250 | 6,610 | +6
February 23, 2000 | February 23, 2000 | 12,500 | 13,300 | +6
February 23, 2000 | February 23, 2000 | 25,000 | 26,200 | +5
February 23, 2000 | February 23, 2000 | 50,000 | 51,200 | +2
February 23, 2000 | March 15, 2000^b^ | 3,125 | 3,030 | −3
February 23, 2000 | March 15, 2000^b^ | 6,250 | 6,030 | −4
February 23, 2000 | March 15, 2000^b^ | 12,500 | 12,200 | −2
February 23, 2000 | March 15, 2000^b^ | 25,000 | 24,400 | −2
February 23, 2000 | March 15, 2000^b^ | 50,000 | 49,300 | −1
April 4, 2000 | April 4, 2000 | 3,125 | 3,130 | 0
April 4, 2000 | April 4, 2000 | 6,250 | 6,430 | +3
April 4, 2000 | April 4, 2000 | 12,500 | 12,800 | +2
April 4, 2000 | April 4, 2000 | 25,000 | 25,200 | +1
April 4, 2000 | April 4, 2000 | 50,000 | 50,400 | +1
April 4, 2000 | April 26, 2000^b^ | 3,125 | 2,550 | −18
April 4, 2000 | April 26, 2000^b^ | 6,250 | 5,450 | −13
April 4, 2000 | April 26, 2000^b^ | 12,500 | 10,700 | −14
April 4, 2000 | April 26, 2000^b^ | 25,000 | 20,900 | −16
April 4, 2000 | April 26, 2000^b^ | 50,000 | 46,000 | −8
May 16, 2000 | May 16, 2000 | 3,125 | 2,820 | −10
May 16, 2000 | May 16, 2000 | 6,250 | 5,790 | −7
May 16, 2000 | May 16, 2000 | 12,500 | 12,400 | −1
May 16, 2000 | May 16, 2000 | 25,000 | 27,300 | +9
May 16, 2000 | May 16, 2000 | 50,000 | 52,800 | +6
May 16, 2000 | June 14, 2000^b^ | 3,125 | 2,700 | −14
May 16, 2000 | June 14, 2000^b^ | 6,250 | 5,610 | −10
May 16, 2000 | June 14, 2000^b^ | 12,500 | 11,700 | −6
May 16, 2000 | June 14, 2000^b^ | 25,000 | 22,700 | −9
May 16, 2000 | June 14, 2000^b^ | 50,000 | 48,500 | −3
June 27, 2000 | June 27, 2000 | 3,125 | 3,310 | +6
June 27, 2000 | June 27, 2000 | 6,250 | 6,420 | +3
June 27, 2000 | June 27, 2000 | 12,500 | 13,100 | +5
June 27, 2000 | June 27, 2000 | 25,000 | 26,000 | +4
June 27, 2000 | June 27, 2000 | 50,000 | 51,000 | +2
June 27, 2000 | August 14, 2000^b^ | 3,125 | 2,890 | −8
June 27, 2000 | August 14, 2000^b^ | 6,250 | 5,980 | −4
June 27, 2000 | August 14, 2000^b^ | 12,500 | 12,600 | +1
June 27, 2000 | August 14, 2000^b^ | 25,000 | 24,700 | −1
June 27, 2000 | August 14, 2000^b^ | 50,000 | 51,800 | +4
July 11, 2000 | July 11, 2000 | 3,125 | 3,320 | +6
July 11, 2000 | July 11, 2000 | 6,250 | 6,590 | +5
July 11, 2000 | July 11, 2000 | 12,500 | 13,000 | +4
July 11, 2000 | July 11, 2000 | 25,000 | 25,700 | +3
July 11, 2000 | July 11, 2000 | 50,000 | 49,800 | 0
July 11, 2000 | August 14, 2000^b^ | 3,125 | 2,970 | −5
July 11, 2000 | August 14, 2000^b^ | 6,250 | 5,930 | −5
July 11, 2000 | August 14, 2000^b^ | 12,500 | 11,600 | −7
July 11, 2000 | August 14, 2000^b^ | 25,000 | 24,000 | −4
July 11, 2000 | August 14, 2000^b^ | 50,000 | 47,100 | −6

a Results of duplicate analyses

b Animal room samples