# APPENDIX H ORGAN WEIGHTS AND ORGAN-WEIGHT-TO-BODY-WEIGHT RATIOS

TABLE H1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame^a^

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Male
n | 9 | 12 | 8 | 12 | 11 | 10
Necropsy body wt | 32.8 ± 0.4 | 31.3 ± 0.7 | 32.1 ± 0.8 | 31.2 ± 0.7 | 31.2 ± 1.1 | 31.7 ± 0.6
Brain
Absolute | 0.492 ± 0.007 | 0.507 ± 0.007 | 0.521 ± 0.012 | 0.510 ± 0.007 | 0.514 ± 0.010 | 0.525 ± 0.007^*^
Relative | 15.025 ± 0.221 | 16.297 ± 0.428 | 16.302 ± 0.483 | 16.436 ± 0.322 | 16.634 ± 0.540^*^ | 16.608 ± 0.379
Heart
Absolute | 0.154 ± 0.002 | 0.157 ± 0.003 | 0.164 ± 0.004 | 0.155 ± 0.003 | 0.163 ± 0.006 | 0.157 ± 0.002
Relative | 4.692 ± 0.064 | 5.022 ± 0.033^*^ | 5.115 ± 0.104^*^ | 5.000 ± 0.094 | 5.256 ± 0.120^**^ | 4.959 ± 0.088
R. Kidney
Absolute | 0.265 ± 0.006 | 0.262 ± 0.008 | 0.264 ± 0.012 | 0.260 ± 0.008^b^ | 0.279 ± 0.006 | 0.290 ± 0.012
Relative | 8.092 ± 0.115 | 8.398 ± 0.226 | 8.273 ± 0.401 | 8.382 ± 0.281^b^ | 9.013 ± 0.237^*^ | 9.136 ± 0.287^*^
Liver
Absolute | 1.549 ± 0.026 | 1.373 ± 0.051 | 1.405 ± 0.040 | 1.375 ± 0.034 | 1.425 ± 0.069 | 1.502 ± 0.063
Relative | 47.3 ± 1.1 | 43.8 ± 0.9 | 43.9 ± 1.1 | 44.1 ± 0.6 | 45.6 ± 1.4 | 47.4 ± 1.8
Lung
Absolute | 0.241 ± 0.015 | 0.217 ± 0.017 | 0.189 ± 0.007^*^ | 0.202 ± 0.008 | 0.211 ± 0.010 | 0.206 ± 0.006
Relative | 7.331 ± 0.428 | 6.956 ± 0.493 | 5.905 ± 0.195 | 6.512 ± 0.268 | 6.814 ± 0.304 | 6.530 ± 0.72
R. Testis
Absolute | 0.090 ± 0.001 | 0.077 ± 0.006 | 0.084 ± 0.003 | 0.087 ± 0.002 | 0.088 ± 0.002 | 0.082 ± 0.004
Relative | 2.748 ± 0.051 | 2.466 ± 0.196 | 2.624 ± 0.122 | 2.807 ± 0.078 | 2.854 ± 0.133 | 2.582 ± 0.141
Thymus
Absolute | 0.027 ± 0.003 | 0.021 ± 0.002 | 0.022 ± 0.001 | 0.022 ± 0.002 | 0.024 ± 0.003 | 0.021 ± 0.002
Relative | 0.825 ± 0.089 | 0.666 ± 0.054 | 0.671 ± 0.039 | 0.694 ± 0.066 | 0.760 ± 0.071 | 0.670 ± 0.058
Female
n | 11 | 1 0 | 9 | 9 | 11 | 8
Necropsy body wt | 26.5 ± 0.5 | 26.1 ± 0.4 | 27.2 ± 0.8 | 26.4 ± 0.9 | 26.7 ± 0.7 | 27.8 ± 1.4
Brain
Absolute | 0.509 ± 0.011 | 0.488 ± 0.005 | 0.509 ± 0.008 | 0.516 ± 0.003 | 0.506 ± 0.006 | 0.520 ± 0.011
Relative | 19.257 ± 0.481 | 18.756 ± 0.320 | 18.754 ± 0.352 | 19.744 ± 0.615 | 19.092 ± 0.477 | 19.206 ± 1.492
Heart
Absolute | 0.125 ± 0.003 | 0.121 ± 0.002 | 0.127 ± 0.004 | 0.123 ± 0.003 | 0.120 ± 0.003 | 0.125 ± 0.005
Relative | 4.726 ± 0.115 | 4.628 ± 0.095 | 4.682 ± 0.102 | 4.702 ± 0.137 | 4.529 ± 0.154 | 4.594 ± 0.326
R. Kidney
Absolute | 0.188 ± 0.005 | 0.183 ± 0.005 | 0.191 ± 0.007 | 0.199 ± 0.011 | 0.186 ± 0.005 | 0.189 ± 0.003
Relative | 7.089 ± 0.178 | 7.001 ± 0.162 | 7.009 ± 0.192 | 7.562 ± 0.340 | 7.016 ± 0.251 | 6.932 ± 0.427
Liver
Absolute | 1.279 ± 0.045 | 1.208 ± 0.035 | 1.259 ± 0.061 | 1.201 ± 0.045^c^ | 1.207 ± 0.033 | 1.351 ± 0.042
Relative | 48.2 ± 1.3 | 46.3 ± 1.0 | 46.1 ± 1.2 | 46.9 ± 1.7^c^ | 45.4 ± 1.3 | 49.4 ± 2.7
Lung
Absolute | 0.192 ± 0.007 | 0.225 ± 0.018 | 0.196 ± 0.012 | 0.207 ± 0.026 | 0.203 ± 0.008 | 0.209 ± 0.009
Relative | 7.269 ± 0.312 | 8.636 ± 0.713 | 7.298 ± 0.591 | 7.934 ± 1.017 | 7.685 ± 0.428 | 7.624 ± 0.459
Thymus
Absolute | 0.026 ± 0.001 | 0.024 ± 0.002 | 0.026 ± 0.003 | 0.028 ± 0.002 | 0.025 ± 0.002 | 0.031 ± 0.002
Relative | 0.983 ± 0.054 | 0.937 ± 0.080 | 0.965 ± 0.096 | 1.058 ± 0.056 | 0.930 ± 0.080 | 1.134 ± 0.082

* Significantly different (P≤0.05) from the chamber control group by Williams’ or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

b n = 11

c n = 8

TABLE H2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame^a^

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Male
n | 14 | 15 | 13 | 15 | 14 | 14
Necropsy body wt | 31.3 ± 1.2 | 30.4 ± 0.7 | 29.8 ± 0.8 | 30.0 ± 0.9 | 30.1 ± 0.8 | 30.1 ± 0.8
Brain
Absolute | 0.470 ± 0.008 | 0.474 ± 0.005 | 0.465 ± 0.006 | 0.464 ± 0.007 | 0.482 ± 0.006 | 0.464 ± 0.006
Relative | 15.244 ± 0.489 | 15.733 ± 0.379 | 15.715 ± 0.410 | 15.610 ± 0.418 | 16.144 ± 0.460 | 15.530 ± 0.401
Heart
Absolute | 0.161 ± 0.004 | 0.162 ± 0.002 | 0.160 ± 0.004 | 0.158 ± 0.004 | 0.165 ± 0.003 | 0.157 ± 0.002
Relative | 5.208 ± 0.143 | 5.372 ± 0.147 | 5.383 ± 0.110 | 5.306 ± 0.127 | 5.510 ± 0.140 | 5.234 ± 0.130
R. Kidney
Absolute | 0.237 ± 0.008 | 0.260 ± 0.005 | 0.245 ± 0.007 | 0.245 ± 0.008 | 0.250 ± 0.006 | 0.245 ± 0.007
Relative | 7.677 ± 0.300 | 8.615 ± 0.190^*^ | 8.242 ± 0.163 | 8.190 ± 0.209 | 8.350 ± 0.236 | 8.157 ± 0.228
Liver
Absolute | 1.359 ± 0.033 | 1.361 ± 0.036 | 1.334 ± 0.035 | 1.369 ± 0.050 | 1.378 ± 0.045 | 1.400 ± 0.059
Relative | 43.8 ± 0.8 | 44.9 ± 0.7 | 44.9 ± 0.8 | 45.6 ± 0.9 | 45.8 ± 0.9 | 46.4 ± 1.4
Lung
Absolute | 0.211 ± 0.009 | 0.223 ± 0.007 | 0.212 ± 0.014 | 0.225 ± 0.012 | 0.208 ± 0.007 | 0.206 ± 0.008
Relative | 6.803 ± 0.272 | 7.366 ± 0.154 | 7.128 ± 0.406 | 7.520 ± 0.380 | 6.953 ± 0.267 | 6.854 ± 0.232
R. Testis
Absolute | 0.109 ± 0.002 | 0.110 ± 0.003 | 0.109 ± 0.002 | 0.104 ± 0.004 | 0.108 ± 0.002 | 0.105 ± 0.002
Relative | 3.527 ± 0.117 | 3.646 ± 0.080 | 3.666 ± 0.076 | 3.499 ± 0.145 | 3.600 ± 0.100 | 3.520 ± 0.124
Thymus
Absolute | 0.041 ± 0.003 | 0.038 ± 0.001 | 0.038 ± 0.003 | 0.040 ± 0.002 | 0.036 ± 0.002 | 0.036 ± 0.002
Relative | 1.297 ± 0.085 | 1.263 ± 0.037 | 1.291 ± 0.095 | 1.327 ± 0.056 | 1.210 ± 0.071 | 1.186 ± 0.070
Female
n | 14 | 14 | 14 | 15 | 15 | 15
Necropsy body wt | 26.1 ± 0.8 | 24.6 ± 0.5 | 26.4 ± 1.0 | 25.8 ± 0.8 | 24.8 ± 0.4 | 25.8 ± 0.7
Brain
Absolute | 0.481 ± 0.004 | 0.475 ± 0.007 | 0.483 ± 0.006 | 0.483 ± 0.004 | 0.478 ± 0.005 | 0.476 ± 0.005
Relative | 18.660 ± 0.550 | 19.419 ± 0.398 | 18.521 ± 0.529 | 18.990 ± 0.610 | 19.329 ± 0.336 | 18.644 ± 0.466
Heart
Absolute | 0.142 ± 0.006 | 0.140 ± 0.006 | 0.140 ± 0.004 | 0.135 ± 0.003 | 0.138 ± 0.003 | 0.137 ± 0.003
Relative | 5.437 ± 0.118 | 5.684 ± 0.150 | 5.355 ± 0.128 | 5.290 ± 0.140 | 5.564 ± 0.102 | 5.338 ± 0.132
R. Kidney
Absolute | 0.183 ± 0.004 | 0.182 ± 0.006 | 0.195 ± 0.005 | 0.187 ± 0.005 | 0.195 ± 0.003 | 0.187 ± 0.004
Relative | 7.069 ± 0.161 | 7.416 ± 0.189 | 7.434 ± 0.199 | 7.291 ± 0.164 | 7.872 ± 0.138^*^ | 7.340 ± 0.252
Liver
Absolute | 1.221 ± 0.026^b^ | 1.181 ± 0.038 | 1.209 ± 0.043 | 1.184 ± 0.042 | 1.162 ± 0.023 | 1.185 ± 0.039
Relative | 48.2 ± 1.1^b^ | 48.1 ± 1.0 | 46.0 ± 1.1 | 46.0 ± 1.0 | 46.9 ± 0.9 | 46.0 ± 0.9
Lung
Absolute | 0.199 ± 0.006 | 0.200 ± 0.004 | 0.197 ± 0.008 | 0.207 ± 0.005 | 0.189 ± 0.004 | 0.203 ± 0.006
Relative | 7.725 ± 0.339 | 8.204 ± 0.225 | 7.502 ± 0.272 | 8.101 ± 0.261 | 7.639 ± 0.214 | 7.958 ± 0.300
Thymus
Absolute | 0.045 ± 0.004^b^ | 0.042 ± 0.002 | 0.048 ± 0.003 | 0.042 ± 0.002 | 0.043 ± 0.003 | 0.046 ± 0.002
Relative | 1.760 ± 0.161^b^ | 1.707 ± 0.101 | 1.820 ± 0.077 | 1.658 ± 0.081 | 1.747 ± 0.101 | 1.774 ± 0.091

* Significantly different (P≤0.05) from the chamber control group by Williams’ or Dunnett’s test

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

b n = 13

TABLE H3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame^a^

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Male
n | 14 | 14 | 15 | 14 | 14 | 15
Necropsy body wt | 35.86 ± 1.08 | 33.56 ± 0.72 | 34.29 ± 0.96 | 35.36 ± 1.21 | 35.69 ± 0.87 | 34.84 ± 1.13
Brain
Absolute | 0.478 ± 0.005 | 0.478 ± 0.005 | 0.486 ± 0.006 | 0.483 ± 0.004 | 0.489 ± 0.006 | 0.474 ± 0.007
Relative | 13.482 ± 0.442 | 14.331 ± 0.384 | 14.331 ± 0.463 | 13.896 ± 0.574 | 13.823 ± 0.415 | 13.764 ± 0.393
Heart
Absolute | 0.193 ± 0.005 | 0.181 ± 0.004 | 0.178 ± 0.005 | 0.182 ± 0.006 | 0.189 ± 0.006 | 0.192 ± 0.005
Relative | 5.452 ± 0.235 | 5.403 ± 0.122 | 5.215 ± 0.111 | 5.194 ± 0.143 | 5.323 ± 0.185 | 5.565 ± 0.200
R. Kidney
Absolute | 0.316 ± 0.009 | 0.312 ± 0.009 | 0.305 ± 0.007 | 0.315 ± 0.008 | 0.318 ± 0.009 | 0.330 ± 0.009
Relative | 8.872 ± 0.274 | 9.306 ± 0.209 | 8.943 ± 0.200 | 8.997 ± 0.233 | 8.946 ± 0.252 | 9.533 ± 0.273
Liver
Absolute | 1.660 ± 0.057 | 1.535 ± 0.036 | 1.507 ± 0.046 | 1.589 ± 0.048 | 1.569 ± 0.034 | 1.686 ± 0.061
Relative | 46.3 ± 0.9 | 45.8 ± 0.7 | 44.0 ± 0.6 | 45.1 ± 0.8 | 44.1 ± 0.8 | 48.5 ± 1.1
Lung
Absolute | 0.246 ± 0.013 | 0.223 ± 0.007 | 0.227 ± 0.006 | 0.216 ± 0.009 | 0.246 ± 0.011 | 0.226 ± 0.005
Relative | 6.939 ± 0.437 | 6.644 ± 0.189 | 6.716 ± 0.297 | 6.127 ± 0.219 | 6.959 ± 0.375 | 6.541 ± 0.214
R. Testis
Absolute | 0.122 ± 0.003 | 0.122 ± 0.003 | 0.125 ± 0.002 | 0.128 ± 0.004 | 0.128 ± 0.002 | 0.128 ± 0.002
Relative | 3.428 ± 0.094 | 3.653 ± 0.093 | 3.676 ± 0.089 | 3.634 ± 0.066 | 3.634 ± 0.123 | 3.710 ± 0.095
Thymus
Absolute | 0.034 ± 0.002 | 0.032 ± 0.002 | 0.039 ± 0.003 | 0.037 ± 0.002 | 0.032 ± 0.003 | 0.034 ± 0.003
Relative | 0.943 ± 0.045 | 0.963 ± 0.045 | 1.139 ± 0.087 | 1.061 ± 0.064 | 0.885 ± 0.071 | 0.992 ± 0.090
Female
n | 13 | 15 | 13 | 15 | 15 | 14
Necropsy body wt | 27.51 ± 0.97 | 28.21 ± 0.79 | 29.11 ± 1.09 | 29.39 ± 1.23 | 27.87 ± 0.81 | 29.12 ± 0.94
Brain
Absolute | 0.483 ± 0.008 | 0.488 ± 0.006 | 0.482 ± 0.008 | 0.484 ± 0.005 | 0.488 ± 0.004 | 0.484 ± 0.004
Relative | 17.794 ± 0.634 | 17.456 ± 0.496 | 16.754 ± 0.502 | 16.787 ± 0.570 | 17.673 ± 0.405 | 16.821 ± 0.516
Heart
Absolute | 0.147 ± 0.005 | 0.147 ± 0.004 | 0.144 ± 0.004 | 0.141 ± 0.003 | 0.145 ± 0.004 | 0.151 ± 0.005
Relative | 5.403 ± 0.194 | 5.251 ± 0.169 | 4.988 ± 0.148 | 4.878 ± 0.141 | 5.223 ± 0.106 | 5.199 ± 0.162
R. Kidney
Absolute | 0.209 ± 0.007 | 0.217 ± 0.011 | 0.215 ± 0.006 | 0.203 ± 0.005 | 0.211 ± 0.004 | 0.220 ± 0.006
Relative | 7.656 ± 0.290 | 7.757 ± 0.454 | 7.438 ± 0.182 | 6.999 ± 0.188 | 7.636 ± 0.193 | 7.585 ± 0.192
Liver
Absolute | 1.331 ± 0.071 | 1.281 ± 0.043 | 1.273 ± 0.045 | 1.280 ± 0.047 | 1.302 ± 0.057 | 1.326 ± 0.052
Relative | 48.2 ± 1.5 | 45.4 ± 0.8 | 44.1 ± 0.6^*^ | 43.7 ± 0.5^**^ | 46.6 ± 1.1 | 45.7 ± 0.8
Lung
Absolute | 0.232 ± 0.016 | 0.215 ± 0.006 | 0.211 ± 0.007 | 0.227 ± 0.011 | 0.203 ± 0.006 | 0.219 ± 0.010
Relative | 8.387 ± 0.428 | 7.687 ± 0.252 | 7.301 ± 0.216 | 7.794 ± 0.306 | 7.290 ± 0.133^*^ | 7.575 ± 0.328
Thymus
Absolute | 0.038 ± 0.002 | 0.039 ± 0.003 | 0.035 ± 0.004 | 0.040 ± 0.002 | 0.036 ± 0.003 | 0.039 ± 0.004
Relative | 1.407 ± 0.085 | 1.374 ± 0.084 | 1.194 ± 0.126 | 1.383 ± 0.082 | 1.272 ± 0.085 | 1.322 ± 0.113

* Significantly different (P≤0.05) from the chamber control group by Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).