# APPENDIX G GENETIC TOXICOLOGY

## Salmonella typhimurium Mutagenicity Test Protocol

Testing was performed as reported by Zeiger et al. (1992). Aspartame was sent to the laboratory as a coded aliquot from Radian Corporation (Austin, TX). It was incubated with the Salmonella typhimurium tester strains TA97, TA98, TA100, TA1535, and TA1537 either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague-Dawley rat or Syrian hamster liver) for 20 minutes at 37° C. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37° C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and five doses of aspartame. In the absence of toxicity, 10,000 µg/plate was selected as the high dose. All trials were repeated at the same or a higher S9 fraction.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive.

## Rat Bone Marrow Micronucleus Test Protocol

Preliminary range-finding studies were performed. Factors affecting dose selection included chemical solubility and toxicity and the extent of cell cycle delay induced by aspartame exposure. The standard three-exposure protocol is described in detail by Shelby et al. (1993). Male F344/N rats were given aspartame dissolved in corn oil by gavage [three times at 24-hour intervals]. Vehicle control animals were gavaged with corn oil only. The positive control animals received cyclophosphamide. The animals were killed 24 hours after the third dose, and blood smears were prepared from bone marrow cells obtained from the femurs. Air-dried smears were fixed and stained; 2,000 polychromatic erythrocytes (PCEs) were scored for the frequency of micronucleated cells in each of five animals per dose group. In addition, the percentage of PCEs among 200 erythrocytes in the bone marrow of each animal was scored as a measure of toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group plus or minus the standard error of the mean. The frequency of micronucleated cells among PCEs was analyzed by a statistical software package that tested for increasing trend over dose groups with a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each dosed group and the control group (ILS, 1990). In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single dose group is less than or equal to 0.025 divided by the number of dose groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials (as noted above). Ultimately, the final call is determined by the scientific staff after considering the results of statistical analyses, the reproducibility of any effects observed, and the magnitudes of those effects.

## Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by MacGregor et al. (1990). At the end of the 9-month toxicity studies, peripheral blood samples were obtained from male and female mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronuclei in 2,000 normochromatic erythrocytes (NCEs) in up to 12 Tg.AC hemizygous, 15 p53 haploinsufficient, and 15 Cdkn2a deficient mice per exposure group. In addition, the percent of PCEs among 1000 erythrocytes in peripheral blood was scored as a measure of toxicity.

The results were tabulated as described for PCEs in the rat bone marrow micronucleus test. Results of the 9-month studies were accepted without repeat tests, because additional test data could not be obtained.

## Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple aliquots of a chemical were tested in the same assay, and different results were obtained among aliquots and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the Abstract of this Report presents a result that represents a scientific judgement of the overall evidence for activity of the chemical in an assay.

## Results

Aspartame (100 to 10,000 µg/plate) was tested for induction of gene mutations in S. typhimurium with and without induced rat or hamster liver S9 metabolic activation enzymes (Table G1). No mutagenicity was detected in strains TA98, TA100, or TA1535 with or without S9. In addition, a single test in TA1537 with 30% rat liver S9 also gave negative results. In TA97 with 30% rat liver S9, however, a reproducible small increase in mutant colonies was observed, and this response was judged to be equivocal. No mutagenicity was detected in TA97 without S9 or with hamster liver S9.

No increase in micronucleated PCEs was observed in bone marrow of male F344/N rats administered aspartame by gavage over a dose range of 500 to 2,000 mg/kg (Table G2). The percent of PCEs was not greatly altered in treated rats (Table G2). However, a slight decrease in percent PCEs occurred in the 1,000 mg/kg group, and in the positive controls the percent of PCEs was dramatically lowered, an indication of marked toxicity.

Peripheral blood micronucleus tests were conducted in Tg.AC hemizygous, p53 haploinsufficient, and Cdkn2a deficient mice after 9 months exposure to 3,125 to 50,000 ppm aspartame in feed. Negative results were obtained in male and female Tg.AC hemizygous and Cdkn2a deficient mice (Tables G3 and G4). Negative results were also obtained in male p53 haploinsufficient mice (Table G5); in female p53 haploinsufficient mice, the results of the micronucleus test were judged to be positive based on a significant trend test and the increased frequency of micronucleated erythrocytes seen in the 50,000 ppm group. For all three strains of mice, the percent PCEs was not significantly altered by treatment with aspartame.

TABLE G1 Mutagenicity of Aspartame in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Revertants/Plate^b^
Strain | Dose (μg/plate) | -S9 | | +hamster S9
Strain | Dose (μg/plate) | Trial 1 | Trial 2 | 10% | 30%
TA100 | 0 | 143 ± 7.2 | 105 ± 3.7 | 108 ± 9.4 | 152 ± 12.0
TA100 | 100 | 159 ± 5.0 | 129 ± 7.6 | 141 ± 14.5 | 168 ± 4.4
TA100 | 333 | 181 ± 8.1 | 127 ± 11.2 | 118 ± 5.8 | 163 ± 6.7
TA100 | 1,000 | 185 ± 11.1 | 111 ± 6.7 | 113 ± 1.2 | 148 ± 5.9
TA100 | 3,333 | 170 ± 14.7 | 113 ± 6.6 | 129 ± 7.2 | 159 ± 19.3
TA100 | 10,000 | 178 ± 6.1 | 122 ± 8.4 | 119 ± 10.7 | 191 ± 16.5
Trial summary | | Negative | Negative | Negative | Negative
Positive control^c^ | | 312 ± 24.8 | 219 ± 15.0 | 812 ± 41.6 | 458 ± 15.3
| | +rat S9
| | 10% | 30% | 30% | 30%
TA100 (continued) | 0 | 115 ± 8.5 | 97 ± 5.2 | 95 ± 7.5 | 80 ± 5.0
TA100 (continued) | 100 | 118 ± 2.6 | 96 ± 4.6
TA100 (continued) | 333 | 114 ± 7.9 | 103 ± 6.4 | 89 ± 6.8 | 110 ± 11.7
TA100 (continued) | 1,000 | 116 ± 10.7 | 112 ± 4.7 | 96 ± 9.0 | 101 ± 11.4
TA100 (continued) | 3,333 | 127 ± 8.6 | 109 ± 6.4 | 96 ± 3.0 | 81 ± 5.7
TA100 (continued) | 6,667 | | | 80 ± 3.8 | 80 ± 6.7
TA100 (continued) | 10,000 | 127 ± 6.6 | 202 ± 39.4 | 77 ± 5.5 | 81 ± 3.5
Trial summary | | Negative | Equivocal | Negative | Negative
Positive control^c^ | | 586 ± 36. | 633 ± 30.3 | 636 ± 47.3 | 180 ± 9.4
| | -S9 | | +hamster S9
| | Trial 1 | Trial 2 | 10% | 30%
TA1535 | 0 | 13 ± 1.5 | 18 ± 2.9 | 13 ± 0.6 | 16 ± 2.0
TA1535 | 100 | 10 ± 2.0 | 12 ± 3.5 | 11 ± 0.7 | 10 ± 1.5
TA1535 | 333 | 19 ± 2.3 | 11 ± 2.6 | 12 ± 1.9 | 10 ± 1.0
TA1535 | 1,000 | 11 ± 0.9 | 12 ± 2.4 | 13 ± 1.5 | 10 ± 1.2
TA1535 | 3,333 | 11 ± 0.9 | 14 ± 4.0 | 10 ± 2.7 | 10 ± 2.9
TA1535 | 10,000 | 13 ± 1.5 | 14 ± 2.1 | 11 ± 5.6 | 12 ± 2.1
Trial summary | | Negative | Negative | Negative | Negative
Positive control^c^ | | 108 ± 4.8 | 166 ± 3.2 | 91 ± 5.6 | 97 ± 4.7
| | +rat S9
| | 10% | 30% | 30%
TA1535 (continued) | 0 | 13 ± 2.8 | 9 ± 1.8 | 12 ± 1.2
TA1535 (continued) | 100 | 15 ± 0.6 | 20 ± 3.4 | 12 ± 3.0
TA1535 (continued) | 333 | 11 ± 1.8 | 17 ± 4.8 | 15 ± 5.0
TA1535 (continued) | 1,000 | 12 ± 0.3 | 20 ± 3.4 | 12 ± 1.7
TA1535 (continued) | 3,333 | 7 ± 2.0 | 21 ± 2.6 | 14 ± 1.5
TA1535 (continued) | 10,000 | 10 ± 0.3 | 22 ± 1.7 | 13 ± 0.9
Trial summary | | Negative | Equivocal | Negative
Positive control^c^ | | 172 ± 1.2 | 73 ± 6.6 | 269 ± 3.41
| | +rat S9
| | 30%
TA1537 | 0 | 15 ± 0.3
TA1537 | 100 | 10 ± 3.5
TA1537 | 333 | 9 ± 0.7
TA1537 | 1,000 | 8 ± 1.2
TA1537 | 3,333 | 15 ± 1.5
TA1537 | 10,000 | 8 ± 0.9
Trial summary | | Negative
Positive control^c^ | | 57 ± 13.1
| | -S9 | | +hamster S9
| | Trial 1 | Trial 2 | 10% | 30%
TA97 | 0 | 105 ± 7.3 | 140 ± 12.1 | 141 ± 9.2 | 140 ± 2.9
TA97 | 100 | 122 ± 5.0 | 122 ± 0.3 | 135 ± 6.7 | 142 ± 1.9
TA97 | 333 | 108 ± 7.2 | 125 ± 10.2 | 141 ± 5.6 | 124 ± 8.7
TA97 | 1,000 | 122 ± 12.3 | 124 ± 2.6 | 135 ± 3.9 | 142 ± 10.8
TA97 | 3,333 | 103 ± 7.3 | 147 ± 5.4 | 118 ± 8.1 | 140 ± 4.1
TA97 | 10,000 | 107 ± 3.2 | 142 ± 6.0 | 132 ± 14.5 | 142 ± 10.1
Trial summary | | Negative | Negative | Negative | Negative
Positive control^c^ | | 354 ± 11.5 | 292 ± 13.0 | 1,062 ± 35.1 | 539 ± 73.6
| | +rat S9
| | 10% | 30% | 30%
TA97 (continued) | 0 | 153 ± 7.3 | 154 ± 22.9 | 126 ± 5.5
TA97 (continued) | 100 | 138 ± 9.6 | 150 ± 13.9 | 131 ± 14.1
TA97 (continued) | 333 | 125 ± 8.1 | 176 ± 10.7 | 128 ± 19.0
TA97 (continued) | 1,000 | 152 ± 5.0 | 179 ± 10.7 | 173 ± 29.0
TA97 (continued) | 3,333 | 130 ± 6.9 | 193 ± 8.1 | 168 ± 1.5
TA97 (continued) | 10,000 | 149 ± 7.6 | 204 ± 15.1 | 170 ± 19.2
Trial summary | | Negative | Equivocal | Equivocal
Positive control^c^ | | 898 ± 121.3 | 363 ± 25.4 | 732 ± 94.4
| | -S9 | | +hamster S9 | | +rat S9
| | Trial 1 | Trial 2 | 10% | 30% | 10% | 30%
TA98 | 0 | 11 ± 0.7 | 28 ± 2.8 | 36 ± 5.2 | 20 ± 1.8 | 37 ± 0.9 | 23 ± 1.8
TA98 | 100 | 12 ± 1.7 | 30 ± 4.7 | 34 ± 1.8 | 24 ± 0.9 | 29 ± 6.6 | 22 ± 2.0
TA98 | 333 | 17 ± 1.0 | 23 ± 2.8 | 27 ± 6.5 | 23 ± 2.7 | 31 ± 3.9 | 16 ± 2.8
TA98 | 1,000 | 14 ± 0.9 | 23 ± 2.7 | 31 ± 5.1 | 24 ± 3.2 | 35 ± 4.9 | 12 ± 1.7
TA98 | 3,333 | 17 ± 1.3 | 25 ± 2.6 | 32 ± 5.8 | 24 ± 2.2 | 33 ± 3.6 | 16 ± 1.2
TA98 | 10,000 | 12 ± 0.9 | 30 ± 0.7 | 32 ± 1.5 | 20 ± 1.7 | 35 ± 1.5 | 15 ± 0.6
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control^c^ | | 211 ± 3.8 | 205 ± 11.0 | 878 ± 36.0 | 523 ± 26.4 | 422 ± 14.2 | 147 ± 14.2

a Study performed at BioReliance. The detailed protocol is presented by Zeiger et al. (1992). 0 μg/plate was the solvent control.

b Revertants are presented as mean ± standard error from three plates.

c The positive controls in the absence of metabolic activation were sodium azide (TA100 and TA1535), 9-aminoacridine (TA97), and 4-nitro-o-phenylenediamine (TA98). The positive control for metabolic activation with all strains was 2-aminoanthracine.

TABLE G2 Induction of Micronuclei in Bone Marrow Polychromatic Erythrocytes of Male Rats Treated with Aspartame by Gavage^a^

Compound | Dose (mg/kg) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | PCEs (%)
Corn oil^d^ | | 5 | 1.40 ± 0.41 | | 60.8
Aspartame | 500 | 5 | 1.10 ± 0.33 | 0.7259 | 57.5
Aspartame | 1,000 | 5 | 1.10 ± 0.22 | 0.7259 | 39.0
Aspartame | 2,000 | 5 | 0.80 ± 0.41 | 0.8997 | 55.4
| | | P=0.889^e^
Cyclophosphamide^f^ | 25 | 5 | 34.50 ± 8.31 | | 10.7

a Study was performed at ILS, Inc. The detailed protocol is presented by Shelby et al. (1993); PCE=polychromatic erythrocyte.

b Mean ± standard error

c Pairwise comparison with the vehicle control, significant at P≤0.008 (ILS, 1990).

d Vehicle control

e Significance of micronucleated PCEs/1,000 PCEs tested by the one-tailed trend test, significant at P≤0.025 (ILS, 1990)

f Positive control

TABLE G3 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Tg.AC Hemizygous Mice Following Administration of Aspartame in Feed for 9 Months^a^

Dose (ppm) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | % PCE
Male
NTP-2000 feed^d^ | 9 | 0.67 ± 0.25 | | 2.28
3,125 | 11 | 0.82 ± 0.18 | 0.2909 | 1.97
6,250 | 8 | 1.38 ± 0.31 | 0.0196 | 2.01
12,500 | 12 | 0.88 ± 0.29 | 0.2254 | 1.97
25,000 | 11 | 0.86 ± 0.12 | 0.2406 | 2.08
50,000 | 10 | 0.95 ± 0.17 | 0.1670 | 2.10
| | P=0.401^e^
Female
NTP-2000 feed | 11 | 0.77 ± 0.21 | | 2.50
3,125 | 10 | 0.60 ± 0.15 | 0.7495 | 2.44
6,250 | 8 | 0.75 ± 0.16 | 0.5316 | 2.33
12,500 | 9 | 0.89 ± 0.22 | 0.3436 | 2.63
25,000 | 11 | 0.77 ± 0.18 | 0.5000 | 2.61
50,000 | 9 | 1.22 ± 0.29 | 0.0759 | 2.74
| | P=0.028

a The detailed protocol is presented by MacGregor et al. (1990); NCE=normochromatic erythrocyte, PCE=polychromatic erythrocytes.

b Mean ± standard error

c Pairwise comparison with the control, significant at P≤0.005 (ILS, 1990)

d Control

e Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test, significant at P≤0.025 (ILS, 1990)

TABLE G4 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Cdkn2a Deficient Mice Following Administration of Aspartame in Feed for 9 Months^a^

Dose (ppm) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | % PCE
Male
NTP-2000 feed^d^ | 14 | 1.86 ± 0.19 | | 2.74
3,125 | 14 | 1.82 ± 0.24 | 0.5393 | 2.28
6,250 | 15 | 2.00 ± 0.20 | 0.3477 | 2.62
12,500 | 14 | 1.54 ± 0.19 | 0.8223 | 2.54
25,000 | 14 | 1.82 ± 0.25 | 0.5393 | 2.48
50,000 | 15 | 1.50 ± 0.21 | 0.8536 | 2.60
| | P=0.886^e^
Female
NTP-2000 feed | 13 | 1.19 ± 0.20 | | 2.75
3,125 | 15 | 1.17 ± 0.20 | 0.5351 | 2.79
6,250 | 13 | 1.42 ± 0.26 | 0.2333 | 3.14
12,500 | 15 | 1.40 ± 0.27 | 0.2485 | 2.68
25,000 | 15 | 1.40 ± 0.15 | 0.2485 | 3.17
50,000 | 14 | 1.14 ± 0.19 | 0.5668 | 3.29
| | P=0.605

a The detailed protocol is presented by MacGregor et al. (1990); NCE=normochromatic erythrocyte, PCE=polychromatic erythrocytes.

b Mean ± standard error

c Pairwise comparison with the control, significant at P≤0.005 (ILS, 1990)

d Control

e Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test, significant at P≤0.025 (ILS, 1990)

TABLE G5 Frequency of Micronuclei in Peripheral Blood Erythrocytes of p53 Haploinsufficient Mice Following Administration of Aspartame in Feed for 9 Months^a^

Dose (ppm) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | % PCE
Male
NTP-2000 feed^d^ | 14 | 1.18 ± 0.19 | | 2.23
3,125 | 15 | 1.40 ± 0.20 | 0.2292 | 2.43
6,250 | 13 | 1.27 ± 0.25 | 0.3816 | 2.77
12,500 | 15 | 1.27 ± 0.18 | 0.3809 | 2.50
25,000 | 14 | 1.57 ± 0.16 | 0.1048 | 2.49
50,000 | 14 | 1.43 ± 0.22 | 0.2062 | 2.82
| | P=0.201^e^
Female
NTP-2000 feed | 14 | 0.79 ± 0.14 | | 3.33
3,125 | 14 | 1.04 ± 0.20 | 0.1634 | 2.93
6,250 | 14 | 0.96 ± 0.15 | 0.2374 | 2.81
12,500 | 15 | 1.13 ± 0.17 | 0.0890 | 2.85
25,000 | 15 | 1.03 ± 0.17 | 0.1620 | 2.83
50,000 | 15 | 1.80 ± 0.20 | 0.0004 | 2.99
| | P=0.000

a The detailed protocol is presented by MacGregor et al. (1990); NCE=normochromatic erythrocyte, PCE=polychromatic erythrocytes.

b Mean ± standard error

c Pairwise comparison with the control, significant at P≤0.005 (ILS, 1990)

d Control

e Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test, significant at P≤0.025 (ILS, 1990)