# APPENDIX F SUMMARY OF LESIONS IN FEMALE Cdkn2a DEFICIENT MICE IN THE 9-MONTH FEED STUDY OF ASPARTAME

TABLE F1 Summary of the Incidence of Neoplasms in Female Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame^a^

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund sacrifice | | | | | | 1
Natural death | 2 | | 2
Survivors
Terminal sacrifice | 13 | 15 | 13 | 15 | 15 | 14
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Gallbladder | (12) | (1) | | | | (14)
Histiocytic sarcoma | | 1 (100%)
Intestine large, cecum | (13) | | (1) | | | (15)
Leiomyoma | | | 1 (100%)
Liver | (15) | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | 2 (13%) | 1 (7%) | 1 (7%) | | | 2 (13%)
Pancreas | (15) | (1) | | | | (15)
Histiocytic sarcoma | | 1 (100%) | | | | 1 (7%)
Cardiovascular System
Heart | (15) | (15) | (15) | (15) | (15) | (15)
Hemangiosarcoma | | | 1 (7%)
Endocrine System
Adrenal medulla | (15) | (15) | (13) | (13) | (15) | (15)
Histiocytic sarcoma | | | | | | 1 (7%)
Pituitary gland | (10) | (13) | (13) | (12) | (11) | (12)
Adenoma | | 1 (8%)
General Body System
None
Genital System
Ovary | (15) | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | 3 (20%) | 2 (13%) | 2 (13%) | 2 (13%) | 2 (13%) | 2 (13%)
Uterus | (15) | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | 1 (7%)
Hematopoietic System
Bone marrow | (15) | | | | | (15)
Histiocytic sarcoma | 4 (27%) | | | | | 3 (20%)
Lymph node, mandibular | (14) | (15) | (13) | (15) | (15) | (15)
Histiocytic sarcoma | 1 (7%)
Lymph node, mesenteric | (14) | (15) | (14) | (15) | (15) | (14)
Histiocytic sarcoma | 1 (7%)
Lymph node, mediastinal | (14) | (15) | (12) | (13) | (12) | (12)
Histiocytic sarcoma | 1 (7%)
Spleen | (15) | (15) | (14) | (15) | (15) | (15)
Hemangiosarcoma | | | 1 (7%)
Histiocytic sarcoma | 1 (7%) | | | | | 2 (13%)
Thymus | (14) | (15) | (14) | (14) | (15) | (15)
Histiocytic sarcoma | 1 (7%)
Integumentary System
Mammary gland | (13) | (15) | (15) | (15) | (15) | (15)
Hemangiosarcoma | | | | | | 1 (7%)
Musculoskeletal System
None
Nervous System
Brain | (15) | (14) | (14) | (15) | (15) | (15)
Meninges, histiocytic sarcoma | | | | | | 1 (7%)
Respiratory System
Lung | (15) | (14) | (14) | (15) | (15) | (15)
Alveolar/bronchiolar adenoma | 1 (7%)
Alveolar/bronchiolar carcinoma | | | | | | 1 (7%)
Histiocytic sarcoma | 1 (7%) | | 1 (7%) | | | 2 (13%)
Special Senses System
Harderian gland | (15) | | | | | (15)
Adenoma | | | | | | 1 (7%)
Urinary System
None
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | 5 (33%) | 2 (13%) | 2 (13%) | 2 (13%) | 2 (13%) | 3 (20%)
Leukemia erythrocytic | | | | | 1 (7%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 6 | 3 | 5 | 2 | 3 | 6
Total primary neoplasms | 6 | 3 | 5 | 2 | 3 | 6
Total animals with benign neoplasms | 1 | 1 | 1 | | | 1
Total benign neoplasms | 1 | 1 | 1 | | | 1
Total animals with malignant neoplasms | 5 | 2 | 4 | 2 | 3 | 5
Total malignant neoplasms | 5 | 2 | 4 | 2 | 3 | 5

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE F2

Individual Animal Tumor Pathology of Female Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame: 0 ppm

Number of Days on Study | 0 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 1 | 1 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 3 | 9 | 5 | 5 | 5 | 5 | 5 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 6
Carcass ID Number | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | Total Tissues/Tumors
Carcass ID Number | 8 | 9 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 9 | 9 | 9 | 9 | 9 | Total Tissues/Tumors
Carcass ID Number | 8 | 2 | 1 | 3 | 5 | 6 | 7 | 2 | 4 | 9 | 0 | 1 | 3 | 4 | 5 | Total Tissues/Tumors
Alimentary System
Esophagus | A | + | + | M | + | + | + | + | + | + | + | M | + | + | + | 12
Gallbladder | A | A | + | + | + | + | + | M | + | + | + | + | + | + | + | 12
Intestine large, colon | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, rectum | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Intestine large, cecum | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Intestine small, duodenum | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Intestine small, jejunum | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Intestine small, ileum | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | | X | | X | | | | | | | | | | | | 2
Pancreas | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Stomach, glandular | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Tongue | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Cardiovascular System
Blood vessel | M | + | + | + | + | + | + | + | M | + | M | + | + | + | + | 12
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Islets, pancreatic | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Parathyroid gland | M | M | M | M | M | + | + | + | + | + | M | M | + | M | + | 7
Pituitary gland | M | + | I | + | I | + | I | + | + | M | + | + | + | + | + | 10
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Clitoral gland | M | M | M | M | + | + | M | M | M | + | + | + | + | + | + | 8
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | | | | X | | X | X | | | | | | | | | 3
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Vagina | + | + | + | M | + | + | + | + | + | + | + | + | + | + | + | 14
Hematopoietic System
Bone marrow | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | | | | X | | X | X | | | | X | | | | | 4
Lymph node, mandibular | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Histiocytic sarcoma | | X | | | | | | | | | | | | | | 1
Lymph node, mesenteric | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Histiocytic sarcoma | | X | | | | | | | | | | | | | | 1
Lymph node, mediastinal | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Histiocytic sarcoma | | X | | | | | | | | | | | | | | 1
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | | X | | | | | | | | | | | | | | 1
Thymus | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Histiocytic sarcoma | | X | | | | | | | | | | | | | | 1
Integumentary System
Mammary gland | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Skin | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Musculoskeletal System
Bone | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skeletal muscle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Larynx | M | + | + | + | M | + | I | M | M | M | I | M | M | M | I | 4
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Alveolar/bronchiolar adenoma | | | | | | | | | X | | | | | | | 1
Histiocytic sarcoma | | X | | | | | | | | | | | | | | 1
Nose | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Trachea | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
Eye | + | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Harderian gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Zymbal’s gland | + | + | + | M | M | M | + | M | + | + | + | + | + | + | M | 10
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary bladder | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | | X | | X | | X | X | | | | X | | | | | 5

Individual Animal Tumor Pathology of Female Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame: 3,125 ppm

Number of Days on Study | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 6 | 6 | 6 | 6 | 6
Carcass ID Number | 4 | 4 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 4 | 4 | 5 | 5 | 5 | Total Tissues/Tumors
Carcass ID Number | 9 | 9 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 9 | 9 | 0 | 0 | 0 | Total Tissues/Tumors
Carcass ID Number | 7 | 8 | 0 | 2 | 3 | 4 | 6 | 7 | 9 | 0 | 6 | 9 | 1 | 5 | 8 | Total Tissues/Tumors
Alimentary System
Gallbladder | | | | | | | | | + | | | | | | | 1
Histiocytic sarcoma | | | | | | | | | X | | | | | | | 1
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | | | | | | | | | X | | | | | | | 1
Pancreas | | | | | | | | | + | | | | | | | 1
Histiocytic sarcoma | | | | | | | | | X | | | | | | | 1
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | I | + | + | I | + | + | + | 13
Adenoma | | | X | | | | | | | | | | | | | 1
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | | | | | | | | | X | | | | | | X | 2
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | | | | | | | | | X | | | | | | | 1
Hematopoietic System
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mediastinal | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Mammary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Musculoskeletal System
None
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | A | + | + | + | + | 14
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | | + | + | + | 14
Trachea | + | | | | | | | | | | | + | | | | 2
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | | | | | | | | | X | | | | | | X | 2

Individual Animal Tumor Pathology of Female Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame: 6,250 ppm

Number of Days on Study | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 0 | 1 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 8 | 6 | 5 | 5 | 5 | 5 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 6
Carcass ID Number | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | Total Tissues/Tumors
Carcass ID Number | 1 | 1 | 1 | 2 | 2 | 2 | 1 | 1 | 1 | 1 | 1 | 1 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 7 | 6 | 1 | 0 | 3 | 5 | 2 | 3 | 4 | 5 | 8 | 9 | 1 | 2 | 4 | Total Tissues/Tumors
Alimentary System
Intestine large, cecum | A | | | | | | | | | | | | + | | | 1
Leiomyoma | | | | | | | | | | | | | X | | | 1
Intestine small, jejunum | A
Intestine small, ileum | A
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | | | | X | | | | | | | | | | | | 1
Stomach, forestomach | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Stomach, glandular | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hemangiosarcoma | | | | | | | | | | | X | | | | | 1
Endocrine System
Adrenal cortex | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Adrenal medulla | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Pituitary gland | I | I | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
Tissue NOS | | + | | | | | | | | | | | | | | 1
Genital System
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | | | | X | | X | | | | | | | | | | 2
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node, mandibular | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Lymph node, mesenteric | + | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mediastinal | A | A | + | + | + | + | + | + | + | + | + | + | I | + | + | 12
Spleen | + | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Hemangiosarcoma | X | | | | | | | | | | | | | | | 1
Thymus | + | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Integumentary System
Mammary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Musculoskeletal System
None
Nervous System
Brain | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Respiratory System
Lung | + | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Histiocytic sarcoma | | | | X | | | | | | | | | | | | 1
Special Senses System
None
Urinary System
Kidney | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Urinary bladder | | + | | | | | | | | | | | | | | 1
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | | | | X | | X | | | | | | | | | | 2

Individual Animal Tumor Pathology of Female Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame: 12,500 ppm

Number of Days on Study | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 5 | 5 | 5 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 6
Carcass ID Number | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | Total Tissues/Tumors
Carcass ID Number | 2 | 2 | 3 | 2 | 2 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 4 | Total Tissues/Tumors
Carcass ID Number | 8 | 9 | 3 | 6 | 7 | 0 | 1 | 2 | 4 | 5 | 6 | 7 | 8 | 9 | 0 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | M | + | M | + | + | + | + | + | + | + | + | + | + | + | 13
Pituitary gland | I | + | + | + | + | + | + | + | + | + | M | + | + | + | I | 12
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | | | | | | | X | | | | X | | | | | 2
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mediastinal | + | + | + | + | + | I | + | + | + | + | + | + | + | M | + | 13
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | M | + | + | + | + | + | + | + | + | + | + | + | 14
Integumentary System
Mammary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Musculoskeletal System
None
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | | | | | | | X | | | | X | | | | | 2

Individual Animal Tumor Pathology of Female Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame: 25,000 ppm

Number of Days on Study | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 5 | 5 | 5 | 5 | 5 | 5 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 6
Carcass ID Number | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | Total Tissues/Tumors
Carcass ID Number | 4 | 4 | 4 | 5 | 5 | 5 | 4 | 4 | 4 | 4 | 4 | 4 | 5 | 5 | 5 | Total Tissues/Tumors
Carcass ID Number | 2 | 3 | 5 | 1 | 2 | 5 | 1 | 4 | 6 | 7 | 8 | 9 | 0 | 3 | 4 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | I | + | + | + | + | + | I | I | + | + | M | + | + | + | 11
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | | | | | | | | | X | | X | | | | | 2
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mediastinal | M | I | + | + | + | + | + | + | + | + | + | + | + | + | M | 12
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Mammary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Musculoskeletal System
None
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | | | | | | | | | X | | X | | | | | 2
Leukemia erythrocytic | | | | | X | | | | | | | | | | | 1

Individual Animal Tumor Pathology of Female Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame: 50,000 ppm

Number of Days on Study | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 6 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 7 | 5 | 5 | 5 | 5 | 5 | 5 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 6
Carcass ID Number | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | Total Tissues/Tumors
Carcass ID Number | 6 | 5 | 5 | 6 | 6 | 6 | 6 | 5 | 5 | 6 | 6 | 6 | 6 | 6 | 7 | Total Tissues/Tumors
Carcass ID Number | 0 | 8 | 9 | 1 | 4 | 8 | 9 | 6 | 7 | 2 | 3 | 5 | 6 | 7 | 0 | Total Tissues/Tumors
Alimentary System
Esophagus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Gallbladder | + | + | + | M | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine large, colon | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, rectum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, cecum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, duodenum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, jejunum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, ileum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | X | | | | | | | | | | | | X | | | 2
Pancreas | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | | | | | | | | | | | | | X | | | 1
Salivary glands | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Tongue | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Cardiovascular System
Blood vessel | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | | | | | | | | | | | | | X | | | 1
Islets, pancreatic | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Parathyroid gland | + | + | + | M | M | M | + | M | M | M | M | M | M | M | M | 4
Pituitary gland | + | + | + | + | + | M | + | + | + | I | M | + | + | + | + | 12
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Clitoral gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | X | | | | | | | | | | | | X | | | 2
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Vagina | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Bone marrow | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | X | | X | | | | | | | | | | X | | | 3
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | M | + | + | + | + | + | + | + | 14
Lymph node, mediastinal | + | + | + | M | + | + | + | + | + | + | + | M | + | M | + | 12
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | X | | | | | | | | | | | | X | | | 2
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Mammary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hemangiosarcoma | | | | X | | | | | | | | | | | | 1
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Musculoskeletal System
Bone | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skeletal muscle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Meninges, histiocytic sarcoma | X | | | | | | | | | | | | | | | 1
Peripheral nerve | + | | | | | | | | | | | | | | | 1
Spinal cord | + | | | | | | | | | | | | | | | 1
Respiratory System
Larynx | I | + | I | I | + | I | + | I | M | I | I | M | + | I | + | 5
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Alveolar/bronchiolar carcinoma | | | | | | | | | | | | | | X | | 1
Histiocytic sarcoma | X | | | | | | | | | | | | X | | | 2
Nose | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Trachea | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
Eye | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Harderian gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adenoma | | | | | X | | | | | | | | | | | 1
Zymbal’s gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary bladder | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | X | | X | | | | | | | | | | X | | | 3

+: Tissue examined microscopically | M: Missing tissue | X: Lesion present
A: Autolysis precludes examination | I: Insufficient tissue | Blank: Not examined

TABLE F3 Statistical Analysis of Primary Neoplasms in Female Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
All Organs: Hemangiosarcoma
Overall rate^a^ | 0/15 (0%) | 0/15 (0%) | 2/15 (13%) | 0/15 (0%) | 0/15 (0%) | 1/15 (7%)
Adjusted rate^b^ | 0.0% | 0.0% | 13.8% | 0.0% | 0.0% | 6.7%
Terminal rate^c^ | 0/13 (0%) | 0/15 (0%) | 1/13 (8%) | 0/15 (0%) | 0/15 (0%) | 1/14 (7%)
First incidence (days) | —^e^ | —^f^ | 108 | — | — | 275 (T)
Poly-3 test^d^ | P=0.494 | — | P=0.247 | — | — | P=0.520
All Organs: Histiocytic Sarcoma
Overall rate | 5/15 (33%) | 2/15 (13%) | 2/15 (13%) | 2/15 (13%) | 2/15 (13%) | 3/15 (20%)
Adjusted rate | 35.7% | 13.3% | 14.8% | 13.3% | 13.3% | 20.0%
Terminal rate | 4/13 (31%) | 2/15 (13%) | 2/13 (15%) | 2/15 (13%) | 2/15 (13%) | 2/14 (14%)
First incidence (days) | 219 | 275 (T) | 275 (T) | 275 (T) | 275 (T) | 267
Poly-3 test | P=0.465N | P=0.166N | P=0.206N | P=0.166N | P=0.166N | P=0.302N
All Organs: Malignant Neoplasms
Overall rate | 5/15 (33%) | 2/15 (13%) | 4/15 (27%) | 2/15 (13%) | 3/15 (20%) | 5/15 (33%)
Adjusted rate | 35.7% | 13.3% | 27.6% | 13.3% | 20.0% | 33.3%
Terminal rate | 4/13 (31%) | 2/15 (13%) | 3/13 (23%) | 2/15 (13%) | 3/15 (20%) | 4/14 (29%)
First incidence (days) | 219 | 275 (T) | 108 | 275 (T) | 275 (T) | 267
Poly-3 test | P=0.349 | P=0.166N | P=0.476N | P=0.166N | P=0.302N | P=0.598N
All Organs: Benign or Malignant Neoplasms
Overall rate | 6/15 (40%) | 3/15 (20%) | 5/15 (33%) | 2/15 (13%) | 3/15 (20%) | 6/15 (40%)
Adjusted rate | 42.9% | 20.0% | 34.5% | 13.3% | 20.0% | 40.0%
Terminal rate | 5/13 (39%) | 3/15 (20%) | 4/13 (31%) | 2/15 (13%) | 3/15 (20%) | 5/14 (36%)
First incidence (days) | 219 | 275 (T) | 108 | 275 (T) | 275 (T) | 267
Poly-3 test | P=0.385 | P=0.178N | P=0.472N | P=0.082N | P=0.178N | P=0.585N

(T) Terminal sacrifice

a Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals necropsied.

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal sacrifice. A negative trend or a lower incidence in an exposed group is indicated by N.

e Not applicable; no neoplasms in animal group

f Value of statistic cannot be computed.

TABLE F4 Summary of the Incidence of Noneoplastic Lesions in Female Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame^a^

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund sacrifice | | | | | | 1
Natural death | 2 | | 2
Survivors
Terminal sacrifice | 13 | 15 | 13 | 15 | 15 | 14
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | | | | | | 2 (13%)
Infiltration cellular, focal, lymphocyte | | | | | | 1 (7%)
Infiltration cellular, lymphocyte | 1 (7%)
Inflammation, chronic active | 1 (7%)
Necrosis, focal | | | | | 1 (7%) | 2 (13%)
Hepatocyte, necrosis, focal | | 1 (7%)
Hepatocyte, periportal, vacuolization cytoplasmic | | | | | | 2 (13%)
Salivary glands | (15 | | | | | (15)
Infiltration cellular, focal, lymphocyte | 4 (27%) | | | | | 5 (33%)
Cardiovascular System
Heart | (15) | (15) | (15) | (15) | (15) | (15)
Myocardium, necrosis, focal | | | 1 (7%)
Endocrine System
Adrenal cortex | (15) | (15) | (13) | (15) | (15) | (15)
Accessory adrenal cortical nodule | | | | | 1 (7%)
Subcapsular, hyperplasia, focal | 14 (93%) | 15 (100%) | 12 (92%) | 15 (100%) | 15 (100%) | 15 (100%)
Thyroid gland | (15) | (15) | (15) | (15) | (15) | (15)
Ectopic thymus | | | | 2 (13%)
Ultimobranchial cyst | 1 (7%)
General Body System
Tissue NOS | | | (1)
Abdominal, fat, hemorrhage, focal | | | 1 (100%)
Genital System
Ovary | (15) | (15) | (15) | (15) | (15) | (15)
Cyst | | | | 1 (7%)
Uterus | (15) | (15) | (15) | (15) | (15) | (15)
Endometrium, hyperplasia, cystic | 14 (93%) | 13 (87%) | 13 (87%) | 15 (100%) | 15 (100%) | 14 (93%)
Hematopoietic System
Lymph node, mandibular | (14) | (15) | (13) | (15) | (15) | (15)
Hyperplasia | | | | | | 1 (7%)
Inflammation, chronic active | 1 (7%)
Lymph node, mesenteric | (14) | (15) | (14) | (15) | (15) | (14)
Hyperplasia, histiocytic | | | | | | 1 (7%)
Spleen | (15) | (15) | (14) | (15) | (15) | (15)
Accessory spleen | | | | 1 (7%)
Hematopoietic cell proliferation | 5 (33%) | 2 (13%) | 4 (29%) | 3 (20%) | 2 (13%) | 3 (20%)
Pigmentation | 1 (7%)
Thymus | (14) | (15) | (14) | (14) | (15) | (15)
Atrophy, diffuse | 1 (7%)
Atrophy, focal | | 1 (7%) | 1 (7%)
Integumentary System
None
Musculoskeletal System
Bone | (15) | | | | | (15)
Cranium, osteoporosis | 1 (7%)
Nervous System
Brain | (15) | (14) | (14) | (15) | (15) | (15)
Granuloma | 1 (7%)
Cerebellum, medulla, vacuolization cytoplasmic | 1 (7%)
Spinal cord | | | | | | (1)
Vacuolization cytoplasmic | | | | | | 1 (100%)
Respiratory System
Lung | (15) | (14) | (14) | (15) | (15) | (15)
Alveolar epithelium, hyperplasia, focal | 1 (7%)
Alveolus, crystals | 1 (7%)
Nose | (15) | | | | | (15)
Olfactory epithelium, atrophy | | | | | | 1 (7%)
Olfactory epithelium, hyaline droplet | 2 (13%) | | | | | 3 (20%)
Respiratory epithelium, hyaline droplet | 1 (7%) | | | | | 2 (13%)
Special Senses System
Eye | (14) | | | | | (15)
Cataract | 1 (7%)
Harderian gland | (15) | | | | | (15)
Hyperplasia | | | | | | 1 (7%)
Infiltration cellular, lymphocyte | | | | | | 1 (7%)
Urinary System
Kidney | (15) | (15) | (13) | (15) | (15) | (15)
Nephropathy | 1 (7%) | | | | | 1 (7%)
Glomerulus, hyalinization | | | | | | 1 (7%)
Renal tubule, dilatation, diffuse | 1 (7%) | 1 (7%) | | | 1 (7%)
Renal tubule, dilatation, focal | 10 (67%) | 7 (47%) | 5 (38%) | 5 (33%) | 5 (33%) | 9 (60%)

a Number of animals examined microscopically at the site and the number of animals with lesion