# APPENDIX E SUMMARY OF LESIONS IN MALE Cdkn2a DEFICIENT MICE IN THE 9-MONTH FEED STUDY OF ASPARTAME

TABLE E1 Summary of the Incidence of Neoplasms in Male Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame^a^

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Natural death | 1 | 1 | | 1 | 1
Survivors
Terminal sacrifice | 14 | 14 | 15 | 14 | 14 | 15
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (14) | (15) | (15)
Histiocytic sarcoma | | 1 (7%)
Cardiovascular System
Heart | (15) | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | 1 (7%)
Endocrine System
None
General Body System
None
Genital System
None
Hematopoietic System
Bone marrow | (15) | | | | | (15)
Histiocytic sarcoma | 2 (13%)
Lymph node, mandibular | (15) | (15) | (15) | (14) | (14) | (15)
Histiocytic sarcoma | | 1 (7%)
Lymph node, mesenteric | (15) | (15) | (15) | (14) | (14) | (15)
Histiocytic sarcoma | | 1 (7%)
Spleen | (15) | (15) | (15 | (14) | (15) | (15)
Hemangiosarcoma | | 1 (7%)
Histiocytic sarcoma | | 1 (7%)
Integumentary System
None
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15) | (15)
Alveolar/bronchiolar adenoma | | | | 1 (7%) | | 1 (7%)
Histiocytic sarcoma | | 1 (7%)
Special Senses System
None
Urinary System
Kidney | (15) | (15) | (15) | (14) | (15) | (15)
Histiocytic sarcoma | | 1 (7%)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | 2 (13%) | 1 (7%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 2 | 2 | | 1 | | 1
Total primary neoplasms | 2 | 2 | | 1 | | 1
Total animals with benign neoplasms | | | | 1 | | 1
Total benign neoplasms | | | | 1 | | 1
Total animals with malignant neoplasms | 2 | 2
Total malignant neoplasms | 2 | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE E2

Individual Animal Tumor Pathology of Male Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame: 0 ppm

Number of Days on Study | 0 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 6 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 3 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 5 | 5
Carcass ID Number | 4 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 4 | 4 | 4 | 4 | 3 | 4 | Total Tissues/Tumors
Carcass ID Number | 0 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 0 | 0 | 0 | 0 | 9 | 0 | Total Tissues/Tumors
Carcass ID Number | 1 | 1 | 2 | 3 | 4 | 5 | 7 | 8 | 9 | 0 | 2 | 4 | 5 | 6 | 3 | Total Tissues/Tumors
Alimentary System
Esophagus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Gallbladder | + | + | + | + | + | + | + | + | + | + | + | + | + | + | I | 14
Intestine large, colon | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, rectum | + | + | + | + | M | + | + | + | + | + | + | + | + | + | + | 14
Intestine large, cecum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, duodenum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, jejunum | A | + | + | + | + | + | + | A | + | + | + | + | + | + | + | 13
Intestine small, ileum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pancreas | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Tongue | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Cardiovascular System
Blood vessel | + | + | + | + | + | + | + | + | + | I | + | + | + | + | + | 14
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Islets, pancreatic | + | + | + | + | M | + | + | + | + | + | + | + | + | + | + | 14
Parathyroid gland | M | M | + | + | M | M | + | + | + | + | + | M | + | M | M | 8
Pituitary gland | + | + | + | I | + | + | + | + | + | + | + | + | + | + | I | 13
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | M | + | + | + | 14
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Preputial gland | + | + | + | + | + | + | + | M | + | + | + | + | + | + | + | 14
Prostate | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Seminal vesicle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Bone marrow | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | | | | | | X | | | | | X | | | | | 2
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mediastinal | M | + | + | + | + | + | + | M | + | + | M | + | + | + | + | 12
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Musculoskeletal System
Bone | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skeletal muscle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Larynx | I | + | M | M | M | M | M | M | M | M | M | + | M | M | M | 2
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nose | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Trachea | + | + | + | + | + | + | + | + | + | + | + | M | + | + | + | 14
Special Senses System
Eye | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Harderian gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Zymbal’s gland | M | + | + | + | + | + | M | + | + | + | + | + | + | + | + | 13
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary bladder | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | | | | | | X | | | | | X | | | | | 2

Individual Animal Tumor Pathology of Male Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame: 3,125 ppm

Number of Days on Study | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 3 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 2 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 5 | 5 | 5 | 5 | 5 | 5
Carcass ID Number | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | Total Tissues/Tumors
Carcass ID Number | 0 | 0 | 0 | 1 | 1 | 1 | 1 | 1 | 2 | 0 | 1 | 1 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 6 | 8 | 9 | 4 | 5 | 6 | 7 | 8 | 0 | 7 | 0 | 1 | 2 | 3 | 9 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | X | | | | | | | | | | | | | | | 1
Stomach, forestomach | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Stomach, glandular | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | X | | | | | | | | | | | | | | | 1
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | I | + | + | I | + | + | + | I | + | + | + | I | I | + | 10
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Prostate | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | X | | | | | | | | | | | | | | | 1
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | X | | | | | | | | | | | | | | | 1
Lymph node, mediastinal | M | + | + | + | I | + | + | + | + | + | + | + | + | + | + | 13
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hemangiosarcoma | | | | X | | | | | | | | | | | | 1
Histiocytic sarcoma | X | | | | | | | | | | | | | | | 1
Thymus | M | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Musculoskeletal System
Skeletal muscle | | | | | | | | | | + | | | | | | 1
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | X | | | | | | | | | | | | | | | 1
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | X | | | | | | | | | | | | | | | 1
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Histiocytic sarcoma | X | | | | | | | | | | | | | | | 1

Individual Animal Tumor Pathology of Male Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame: 6,250 ppm

Number of Days on Study | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 5 | 5 | 5 | 5 | 5 | 5
Carcass ID Number | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | Total Tissues/Tumors
Carcass ID Number | 2 | 2 | 2 | 2 | 2 | 3 | 3 | 3 | 3 | 2 | 2 | 2 | 2 | 3 | 3 | Total Tissues/Tumors
Carcass ID Number | 2 | 4 | 6 | 7 | 9 | 1 | 2 | 3 | 5 | 1 | 3 | 5 | 8 | 0 | 4 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | I | I | I | I | + | + | + | I | + | + | + | + | + | + | + | 10
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Prostate | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mediastinal | + | M | + | + | M | + | + | + | + | + | + | + | + | + | + | 13
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Musculoskeletal System
None
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Male Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame: 12,500 ppm

Number of Days on Study | 0 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 4 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 5 | 5 | 5 | 5
Carcass ID Number | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | Total Tissues/Tumors
Carcass ID Number | 3 | 3 | 3 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 5 | 3 | 4 | 4 | 4 | Total Tissues/Tumors
Carcass ID Number | 6 | 8 | 9 | 0 | 2 | 3 | 5 | 6 | 8 | 9 | 0 | 7 | 1 | 4 | 7 | Total Tissues/Tumors
Alimentary System
Liver | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Stomach, forestomach | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Stomach, glandular | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Adrenal medulla | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Pituitary gland | A | + | + | + | + | + | + | + | + | + | + | + | + | I | I | 12
Thyroid gland | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Prostate | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Hematopoietic System
Lymph node, mandibular | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mesenteric | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mediastinal | A | + | + | + | + | + | + | + | + | M | + | + | + | + | + | 13
Spleen | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Thymus | A | + | + | + | + | + | + | + | + | + | + | M | + | + | + | 13
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Musculoskeletal System
None
Nervous System
Brain | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Alveolar/bronchiolar adenoma | | | | | | | | | | | | X | | | | 1
Special Senses System
None
Urinary System
Kidney | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Male Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame: 25,000 ppm

Number of Days on Study | 0 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 2 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 2 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 5 | 5
Carcass ID Number | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | Total Tissues/Tumors
Carcass ID Number | 6 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 6 | 6 | 6 | 6 | 5 | 6 | Total Tissues/Tumors
Carcass ID Number | 5 | 1 | 2 | 3 | 4 | 5 | 7 | 8 | 9 | 0 | 1 | 3 | 4 | 6 | 2 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, glandular | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | I | + | I | I | + | I | + | I | + | + | + | + | + | + | + | 10
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Prostate | + | + | + | M | + | + | + | + | + | + | + | + | M | + | + | 13
Testes | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Hematopoietic System
Lymph node, mandibular | M | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mesenteric | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mediastinal | + | + | + | + | + | I | + | + | + | + | + | M | + | + | + | 13
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Musculoskeletal System
None
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Male Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame: 50,000 ppm

Number of Days on Study | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 5 | 5 | 5 | 5 | 5 | 5
Carcass ID Number | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | Total Tissues/Tumors
Carcass ID Number | 6 | 6 | 7 | 7 | 7 | 7 | 7 | 7 | 8 | 6 | 6 | 7 | 7 | 7 | 7 | Total Tissues/Tumors
Carcass ID Number | 7 | 9 | 0 | 1 | 2 | 5 | 8 | 9 | 0 | 6 | 8 | 3 | 4 | 6 | 7 | Total Tissues/Tumors
Alimentary System
Esophagus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Gallbladder | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, colon | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, rectum | + | + | + | M | + | + | + | + | + | + | + | M | + | + | + | 13
Intestine large, cecum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, duodenum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, jejunum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, ileum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pancreas | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Tongue | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Cardiovascular System
Blood vessel | + | M | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Islets, pancreatic | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Parathyroid gland | + | M | M | + | M | + | M | + | + | M | + | M | + | M | + | 8
Pituitary gland | + | + | + | I | + | + | + | I | I | + | + | I | + | + | + | 11
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Preputial gland | + | + | + | + | + | + | + | + | + | M | + | + | + | + | + | 14
Prostate | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Seminal vesicle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Bone marrow | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mediastinal | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Musculoskeletal System
Bone | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skeletal muscle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Larynx | + | M | M | + | M | M | I | M | + | I | I | M | M | M | I | 3
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Alveolar/bronchiolar adenoma | | X | | | | | | | | | | | | | | 1
Nose | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Trachea | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
Eye | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Harderian gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Zymbal’s gland | + | + | + | + | M | + | + | + | + | + | + | + | + | + | + | 14
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary bladder | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

+: Tissue examined microscopically | M: Missing tissue | X: Lesion present
A: Autolysis precludes examination | I: Insufficient tissue | Blank: Not examined

TABLE E3 Statistical Analysis of Primary Neoplasms in Male Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
All Organs: Hemangiosarcoma
Overall rate^a^ | 0/15 (0%) | 1/15 (7%) | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 0/15 (0%)
Adjusted rate^b^ | 0.0% | 6.9% | 0.0% | 0.0% | 0.0% | 0.0%
Terminal rate^c^ | 0/14 (0%) | 1/14 (7%) | 0/15 (0%) | 0/14 (0%) | 0/14 (0%) | 0/15 (0%)
First incidence (days) | —^e^ | 274 (T) | —^f^ | — | — | —
Poly-3 test^d^ | P=0.494N | P=0.508 | — | — | — | —
All Organs: Histiocytic Sarcoma
Overall rate | 2/15 (13%) | 1/15 (7%) | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 0/15 (0%)
Adjusted rate | 14.3% | 6.7% | 0.0% | 0.0% | 0.0% | 0.0%
Terminal rate | 2/14 (14%) | 0/14 (0%) | 0/15 (0%) | 0/14 (0%) | 0/14 (0%) | 0/15 (0%)
First incidence (days) | 274 (T) | 232 | — | — | — | —
Poly-3 test | P=0.138N | P=0.476N | P=0.216N | P=0.231N | P=0.231N | P=0.216N
All Organs: Malignant Tumors
Overall rate | 2/15 (13%) | 2/15 (13%) | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 0/15 (0%)
Adjusted rate | 14.3% | 13.3% | 0.0% | 0.0% | 0.0% | 0.0%
Terminal rate | 2/14 (14%) | 1/14 (7%) | 0/15 (0%) | 0/14 (0%) | 0/14 (0%) | 0/15 (0%)
First incidence (days) | 274 (T) | 232 | — | — | — | —
Poly-3 test | P=0.087N | P=0.673N | P=0.216N | P=0.231N | P=0.231N | P=0.216N
Organs: Benign or Malignant Neoplasms
Overall rate | 2/15 (13%) | 2/15 (13%) | 0/15 (0%) | 1/15 (7%) | 0/15 (0%) | 1/15 (7%)
Adjusted rate | 14.3% | 13.3% | 0.0% | 7.1% | 0.0% | 6.7%
Terminal rate | 2/14 (14%) | 1/14 (7%) | 0/15 (0%) | 1/14 (7%) | 0/14 (0%) | 1/15 (7%)
Incidence (days) | 274 (T) | 232 | — | 274 (T) | — | 274 (T)
Poly-3 test | P=0.361N | P=0.673N | P=0.216N | P=0.500N | P=0.231N | P=0.476

(T) Terminal sacrifice

a Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals necropsied.

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal sacrifice. A negative trend or a lower incidence in an exposed group is indicated by N.

e Not applicable; no neoplasms in animal group

f Value of statistic cannot be computed.

TABLE E4 Summary of the Incidence of Noneoplastic Lesions in Male Cdkn2a Deficient Mice in the 9-Month Feed Study of Aspartame^a^

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Natural death | 1 | 1 | | 1 | 1
Survivors
Terminal sacrifice | 14 | 14 | 15 | 14 | 14 | 15
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (14) | (15) | (15)
Infiltration cellular, focal, lymphocyte | 3 (20%) | | | | | 1 (7%)
Inflammation, acute | 2 (13%)
Necrosis, focal | 2 (13%) | | 3 (20%) | | 1 (7%) | 4 (27%)
Hepatocyte, necrosis, focal | | 1 (7%) | 1 (7%) | | 1 (7%) | 1 (7%)
Hepatocyte, vacuolization cytoplasmic, diffuse | | | | 1 (7%)
Hepatocyte, periportal, vacuolization cytoplasmic | 6 (40%) | 11 (73%) | 14 (93%) | 8 (57%) | 13 (87%) | 13 (87%)
Salivary glands | (15) | | | | | (15)
Infiltration cellular, focal, lymphocyte | 12 (80%) | | | | | 11 (73%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (14) | (15) | (15)
Accessory adrenal cortical nodule | | | | | | 1 (7%)
Subcapsular, hyperplasia, focal | 2 (13%) | 1 (7%) | | | 1 (7%) | 4 (27%)
General Body System
None
Genital System
Epididymis | (15) | (15) | (15) | (15) | (15) | (15)
Inflammation, chronic active, focal | | | 1 (7%)
Bilateral, spermatozoa, degeneration | 1 (7%)
Testes | (15) | (15) | (15) | (14) | (14) | (15)
Germinal epithelium, degeneration | | 1 (7%) | 1 (7%)
Hematopoietic System
Lymph node, mandibular | (15) | (15) | (15) | (14) | (14) | (15)
Hyperplasia | 1 (7%) | | | 1 (7%)
Necrosis | 1 (7%)
Lymph node, mesenteric | (15) | (15) | (15) | (14) | (14) | (15)
Hyperplasia | | | 2 (13%)
Spleen | (15) | (15) | (15) | (14) | (15) | (15)
Atrophy, diffuse | 1 (7%) | | | | 1 (7%)
Hematopoietic cell proliferation | | 1 (7%) | 2 (13%) | 3 (21%) | | 1 (7%)
Pigmentation | | | | | | 1 (7%)
Lymphoid follicle, atrophy | 1 (7%)
Thymus | (15) | (14) | (15) | (13) | (15) | (15)
Atrophy, diffuse | 1 (7%) | | 1 (7%) | | 1 (7%)
Atrophy, focal | 1 (7%) | 2 (14%) | | | 1 (7%)
Integumentary System
None
Musculoskeletal System
None
Nervous System
Brain | (15) | (15) | (15) | (14) | (15) | (15)
Cerebellum, medulla, vacuolization cytoplasmic | 1 (7%) | 1 (7%)
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15) | (15)
Infiltration cellular, focal, lymphocyte | | 1 (7%)
Special Senses System
Harderian gland | (15) | | | | | (15)
Infiltration cellular, lymphocyte | 2 (13%) | | | | | 2 (13%)
Urinary System
Kidney | (15) | (15) | (15) | (14) | (15) | (15)
Nephropathy | 2 (13%) | | | | | 7 (47%)

a Number of animals examined microscopically at the site and the number of animals with lesion