# APPENDIX D SUMMARY OF LESIONS IN FEMALE p53 HAPLOINSUFFICIENT MICE IN THE 9-MONTH FEED STUDY OF ASPARTAME

TABLE D1 Summary of the Incidence of Neoplasms in Female p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame^a^

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | 1 | | 1
Natural deaths | | 1
Survivors
Terminal sacrifice | 14 | 14 | 14 | 15 | 15 | 15
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Gallbladder | (14) | | | | | (15)
Intestine large, cecum | (15) | | | | (1) | (15)
Liver | (15) | (15) | (15) | (15) | (15) | (15)
Sarcoma | | | | 1 (7%)
Cardiovascular System
None
Endocrine System
Pituitary gland | (9) | (14) | (13) | (14) | (11) | (14)
Pars distalis, adenoma | 1 (11%)
Thyroid gland | (14) | (13) | (14) | (14) | (13) | (15)
Follicular cell, adenoma | | | | | 1 (8%)
General Body System
None
Genital System
None
Hematopoietic System
Lymph node | | | | | (1)
Lymph node, mandibular | (15) | (13) | (13) | (15) | (15) | (14)
Lymph node, mesenteric | (15) | (14) | (14) | (14) | (15) | (15)
Sarcoma | | | | 1 (7%)
Lymph node, mediastinal | (12) | (13) | (13) | (12) | (13) | (15)
Spleen | (15) | (15) | (15) | (15) | (15) | (15)
Thymus | (14) | (14) | (14) | (15) | (15) | (15)
Integumentary System
Mammary gland | (13) | (14) | (14) | (15) | (12) | (15)
Carcinoma | 1 (8%) | | | 1 (7%)
Skin | (15) | | (1) | | | (15)
Subcutaneous tissue, fibrosarcoma | | | 1 (100%)
Musculoskeletal System
Bone | (15) | | (1) | | | (15)
Femur, osteosarcoma | 1 (7%) | | | | | 1 (7%)
Vertebra, osteosarcoma | | | 1 (100%)
Nervous System
None
Respiratory System
Lung | (15) | (15) | (14) | (15) | (15) | (15)
Special Senses System
None
Urinary System
Kidney | (15) | (14) | (15) | (15) | (15) | (15)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15) | (15) | (15)
Lymphoma malignant | 1 (7%) | | | | 1 (7%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 4 | | 2 | 2 | 1 | 1
Total primary neoplasms | 4 | | 2 | 3 | 2 | 1
Total animals with benign neoplasms | 1 | | | | 1
Total benign neoplasms | 1 | | | | 1
Total animals with malignant neoplasms | 3 | | 2 | 2 | 1 | 1
Total malignant neoplasms | 3 | | 2 | 3 | 1 | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE D2

Individual Animal Tumor Pathology of Female p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame: 0 ppm

Number of Days on Study | 0 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 3 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 6 | 5 | 5 | 5 | 5 | 5 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8
Carcass ID Number | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | Total Tissues/Tumors
Carcass ID Number | 1 | 0 | 0 | 0 | 1 | 1 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 3 | 4 | 7 | 8 | 0 | 1 | 1 | 2 | 3 | 5 | 6 | 9 | 2 | 4 | 5 | Total Tissues/Tumors
Alimentary System
Esophagus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Gallbladder | + | M | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine large, colon | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, rectum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, cecum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, duodenum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, jejunum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, ileum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pancreas | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Tongue | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Cardiovascular System
Blood vessel | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | M | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Islets, pancreatic | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Parathyroid gland | M | M | M | + | + | + | M | M | M | + | M | M | M | + | + | 6
Pituitary gland | I | + | + | + | + | + | M | M | + | I | + | I | + | I | + | 9
Pars distalis, adenoma | | | | | | X | | | | | | | | | | 1
Thyroid gland | + | M | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
General Body System
None
Genital System
Clitoral gland | M | + | + | + | + | + | M | + | + | + | + | + | + | + | M | 12
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Vagina | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Bone marrow | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mediastinal | + | + | M | + | + | + | M | + | + | + | + | + | + | M | + | 12
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | M | + | + | + | + | + | + | + | + | 14
Integumentary System
Mammary gland | + | + | M | M | + | + | + | + | + | + | + | + | + | + | + | 13
Carcinoma | | | | | | | X | | | | | | | | | 1
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Musculoskeletal System
Bone | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Femur, osteosarcoma | | | | | | | | | | X | | | | | | 1
Skeletal muscle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Larynx | + | + | M | + | + | I | M | M | M | M | M | M | I | M | M | 4
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nose | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Trachea | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
Eye | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Harderian gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Zymbal’s gland | + | M | + | + | + | + | M | M | + | + | + | + | + | + | + | 12
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary bladder | M | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymphoma malignant | | | X | | | | | | | | | | | | | 1

Individual Animal Tumor Pathology of Female p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame: 3,125 ppm

Number of Days on Study | 0 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 9 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 8 | 5 | 5 | 5 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8
Carcass ID Number | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | Total Tissues/Tumors
Carcass ID Number | 2 | 1 | 1 | 2 | 1 | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 3 | Total Tissues/Tumors
Carcass ID Number | 5 | 7 | 9 | 6 | 6 | 8 | 0 | 1 | 2 | 3 | 4 | 7 | 8 | 9 | 0 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Cardiovascular System
Blood vessel | | | | | + | | | | | | | | | | | 1
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | M | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Thyroid gland | A | M | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
General Body System
None
Genital System
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node, mandibular | A | + | + | + | + | + | + | + | + | + | + | + | + | M | + | 13
Lymph node, mesenteric | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mediastinal | M | + | + | + | + | + | + | + | + | + | M | + | + | + | + | 13
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | M | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Integumentary System
Mammary gland | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Musculoskeletal System
None
Nervous System
Brain | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Female p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame: 6,250 ppm

Number of Days on Study | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 6 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 8 | 5 | 5 | 5 | 5 | 5 | 5 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8
Carcass ID Number | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | Total Tissues/Tumors
Carcass ID Number | 4 | 3 | 3 | 3 | 3 | 4 | 4 | 3 | 3 | 3 | 3 | 3 | 4 | 4 | 4 | Total Tissues/Tumors
Carcass ID Number | 1 | 2 | 5 | 6 | 9 | 0 | 3 | 1 | 3 | 4 | 7 | 8 | 2 | 4 | 5 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | I | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Stomach, glandular | I | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Cardiovascular System
Heart | I | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Endocrine System
Adrenal cortex | I | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Adrenal medulla | I | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Pituitary gland | M | + | + | + | I | + | + | + | + | + | + | + | + | + | + | 13
Thyroid gland | + | + | + | + | + | + | + | M | + | + | + | + | + | + | + | 14
General Body System
None
Genital System
Ovary | I | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node, mandibular | + | + | + | + | + | + | + | M | + | + | + | M | + | + | + | 13
Lymph node, mesenteric | M | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mediastinal | M | + | + | + | + | + | M | + | + | + | + | + | + | + | + | 13
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | I | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Integumentary System
Mammary gland | M | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Skin | | | | | + | | | | | | | | | | | 1
Subcutaneous tissue, fibrosarcoma | | | | | X | | | | | | | | | | | 1
Musculoskeletal System
Bone | | | | | | + | | | | | | | | | | 1
Vertebra, osteosarcoma | | | | | | X | | | | | | | | | | 1
Nervous System
Brain | I | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Respiratory System
Lung | I | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Female p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame: 12,500 ppm

Number of Days on Study | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 8 | 8 | 8 | 8 | 8 | 8
Carcass ID Number | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | Total Tissues/Tumors
Carcass ID Number | 4 | 4 | 5 | 5 | 5 | 5 | 5 | 5 | 6 | 4 | 4 | 5 | 5 | 5 | 5 | Total Tissues/Tumors
Carcass ID Number | 6 | 9 | 0 | 3 | 4 | 5 | 7 | 9 | 0 | 7 | 8 | 1 | 2 | 6 | 8 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Sarcoma | | | | | | | X | | | | | | | | | 1
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | I | + | + | + | + | + | + | 14
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | I | + | + | + | 14
General Body System
None
Genital System
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | M | + | + | + | + | 14
Sarcoma | | | | | | | X | | | | | | | | | 1
Lymph node, mediastinal | + | + | + | + | + | M | M | + | + | M | + | + | + | + | + | 12
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Mammary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Carcinoma | | | X | | | | | | | | | | | | | 1
Musculoskeletal System
None
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Female p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame: 25,000 ppm

Number of Days on Study | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 5 | 5 | 5 | 5 | 5 | 5 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8
Carcass ID Number | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | Total Tissues/Tumors
Carcass ID Number | 6 | 6 | 6 | 6 | 7 | 7 | 6 | 6 | 6 | 6 | 6 | 7 | 7 | 7 | 7 | Total Tissues/Tumors
Carcass ID Number | 1 | 4 | 7 | 9 | 4 | 5 | 2 | 3 | 5 | 6 | 8 | 0 | 1 | 2 | 3 | Total Tissues/Tumors
Alimentary System
Intestine large, cecum | | | | | | | | | | | | | + | | | 1
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | M | + | + | I | + | + | M | + | + | I | + | + | 11
Thyroid gland | + | + | + | + | + | + | I | + | + | + | + | M | + | + | + | 13
Follicular cell, adenoma | | | | | | | | | | | | | X | | | 1
General Body System
None
Genital System
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | | | | | | | | | | | | | + | | | 1
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mediastinal | + | + | + | M | + | + | + | + | + | I | + | + | + | + | + | 13
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Mammary gland | + | + | + | M | + | + | + | + | + | + | + | + | M | + | M | 12
Musculoskeletal System
None
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymphoma malignant | | | | | | | | | | | | | X | | | 1

Individual Animal Tumor Pathology of Female p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame: 50,000 ppm

Number of Days on Study | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 5 | 5 | 5 | 5 | 5 | 5 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8
Carcass ID Number | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | 3 | Total Tissues/Tumors
Carcass ID Number | 7 | 7 | 8 | 8 | 8 | 8 | 7 | 7 | 8 | 8 | 8 | 8 | 8 | 8 | 9 | Total Tissues/Tumors
Carcass ID Number | 6 | 8 | 3 | 4 | 5 | 8 | 7 | 9 | 0 | 1 | 2 | 6 | 7 | 9 | 0 | Total Tissues/Tumors
Alimentary System
Esophagus | + | + | + | + | + | + | M | + | + | + | + | + | + | + | + | 14
Gallbladder | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, colon | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, rectum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, cecum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, duodenum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, jejunum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, ileum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pancreas | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Tongue | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Cardiovascular System
Blood vessel | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Islets, pancreatic | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Parathyroid gland | + | + | + | M | + | M | + | + | + | + | M | + | + | M | + | 11
Pituitary gland | + | + | + | + | + | + | + | + | + | M | + | + | + | + | + | 14
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Clitoral gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Vagina | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Bone marrow | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | M | + | + | + | + | + | 14
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mediastinal | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Mammary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Musculoskeletal System
Bone | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Femur, osteosarcoma | | | | | | | | | | | X | | | | | 1
Skeletal muscle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Larynx | I | M | I | I | + | I | + | M | + | + | I | I | I | + | I | 5
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nose | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Trachea | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
Eye | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Harderian gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Zymbal’s gland | + | + | + | + | M | M | + | + | + | + | M | + | + | M | + | 11
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary bladder | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

+: Tissue examined microscopically | M: Missing tissue | X: Lesion present
A: Autolysis precludes examination | I: Insufficient tissue | Blank: Not examined

TABLE D3 Statistical Analysis of Primary Neoplasms in Female p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
All Organs: Malignant Lymphoma
Overall rate^a^ | 1/15 (7%) | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 1/15 (7%) | 0/15 (0%)
Adjusted rate^b^ | 7.1% | 0.0% | 0.0% | 0.0% | 6.7% | 0.0%
Terminal rate^c^ | 1/14 (7%) | 0/14 (0%) | 0/14 (0%) | 0/15 (0%) | 1/15 (7%) | 0/15 (0%)
First incidence (days) | 275 (T) | —^e^ | — | — | 275 (T) | —
Poly-3 test^d^ | P=0.578N | P=0.499N | P=0.497N | P=0.486N | P=0.745N | P=0.486N
All Organs: Malignant Neoplasms
Overall rate | 3/15 (20%) | 0/15 (0%) | 2/15 (13%) | 2/15 (13%) | 1/15 (7%) | 1/15 (7%)
Adjusted rate | 21.4% | 0.0% | 14.1% | 13.3% | 6.7% | 6.7%
Terminal rate | 3/14 (21%) | 0/14 (0%) | 2/14 (14%) | 2/15 (13%) | 1/15 (7%) | 1/15 (7%)
First incidence (days) | 275 (T) | — | 275 (T) | 275 (T) | 275 (T) | 275 (T)
Poly-3 test | P=0.315N | P=0.105N | P=0.492N | P=0.467N | P=0.273N | P=0.273N
All Organs: Benign or Malignant Neoplasms
Overall rate | 4/15 (27%) | 0/15 (0%) | 2/15 (13%) | 2/15 (13%) | 1/15 (7%) | 1/15 (7%)
Adjusted rate | 28.6% | 0.0% | 14.1% | 13.3% | 6.7% | 6.7%
Terminal rate | 4/14 (29%) | 0/14 (0%) | 2/14 (14%) | 2/15 (13%) | 1/15 (7%) | 1/15 (7%)
First incidence (days) | 275 (T) | — | 275 (T) | 275 (T) | 275 (T) | 275 (T)
Poly-3 test | P=0.217N | P=0.044N | P=0.318N | P=0.293N | P=0.141N | P=0.141N

(T) Terminal sacrifice

a Number of neoplasm-bearing animals/number of animals necropsied.

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal sacrifice. A negative trend or a lower incidence in an exposed group is indicated by N.

e Not applicable; no neoplasms in animal group

TABLE D4 Summary of the Incidence of Nonneoplastic Lesions in Female p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame^a^

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | 1 | | 1
Natural deaths | | 1
Survivors
Terminal sacrifice | 14 | 14 | 14 | 15 | 15 | 15
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15) | (15) | (15)
Infiltration cellular, focal, lymphocyte | 4 (27%) | 3 (20%) | 4 (27%) | 6 (40%) | 4 (27%) | 4 (27%)
Necrosis, focal | | | | | | 1 (7%)
Pigmentation, focal, hemosiderin | 1 (7%)
Tension lipidosis | 1 (7%)
Hepatocyte, necrosis, focal | | | | | 2 (13%)
Hepatocyte, vacuolization cytoplasmic, focal | | | | | 1 (7%)
Salivary glands | (15) | | | | | (15)
Infiltration cellular, focal, lymphocyte | 6 (40%) | | | | | 8 (53%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (15) | (15) | (14) | (15) | (15) | (15)
Hyperplasia, focal | | | 1 (7%) | 1 (7%) | 1 (7%)
Subcapsular, hyperplasia, focal | 12 (80%) | 13 (87%) | 13 (93%) | 15 (100%) | 15 (100%) | 15 (100%)
Pituitary gland | (9) | (14) | (13) | (14) | (11) | (14)
Pars intermedia, hypertrophy | | | 1 (8%) | | 2 (18%) | 2 (14%)
Thyroid gland | (14) | (13) | (14) | (14) | (13) | (15)
Ectopic thymus | 2 (14%) | 1 (8%) | 1 (7%) | 3 (21%) | 1 (8%) | 2 (13%)
General Body System
None
Genital System
Ovary | (15) | (15) | (14) | (15) | (15) | (15)
Atrophy | | | 1 (7%)
Cyst | 1 (7%)
Uterus | (15) | (15) | (15) | (15) | (15) | (15)
Hydrometra | | 1 (7%)
Endometrium, hyperplasia, cystic | 14 (93%) | 14 (93%) | 15 (100%) | 14 (93%) | 15 (100%) | 15 (100%)
Hematopoietic System
Lymph node, mandibular | (15) | (13) | (13) | (15) | (15) | (14)
Congestion | | | | | 1 (7%)
Hyperplasia | 1 (7%) | 2 (15%) | | 1 (7%) | 1 (7%)
Hyperplasia, histiocytic | 1 (7%)
Hyperplasia, lymphoid | 2 (13%)
Hyperplasia, plasma cell | 1 (7%)
Lymph node, mesenteric | (15) | (14) | (14) | (14) | (15) | (15)
Hyperplasia | | 1 (7%)
Hyperplasia, lymphoid | 1 (7%)
Lymph node, mediastinal | (12) | (13) | (13) | (12) | (13) | (15)
Hyperplasia, lymphoid | 1 (8%)
Spleen | (15) | (15) | (15) | (15) | (15) | (15)
Depletion cellular, diffuse | | 1 (7%)
Hematopoietic cell proliferation | 3 (20%) | 4 (27%) | 1 (7%) | 3 (20%) | 1 (7%) | 1 (7%)
Pigmentation | | | | | 1 (7%)
Thymus | (14) | (14) | (14) | (15) | (15) | (15)
Atrophy, focal | 1 (7%)
Hyperplasia | | | 1 (7%) | | | 1 (7%)
Hyperplasia, atypical, focal | | | | 1 (7%)
Integumentary System
None
Musculoskeletal System
Bone | (15) | | (1) | | | (15)
Femur, fibrous osteodystrophy, focal | | | | | | 1 (7%)
Nervous System
Brain | (15) | (14) | (14) | (15) | (15) | (15)
Medulla, cyst epithelial inclusion | | | | 1 (7%)
Respiratory System
Lung | (15) | (15) | (14) | (15) | (15) | (15)
Infiltration cellular, focal, lymphocyte | 1 (7%) | | | | 1 (7%) | 1 (7%)
Special Senses System
Harderian gland | (15) | | | | | (15)
Infiltration cellular, focal, lymphocyte | 1 (7%) | | | | | 3 (20%)
Inflammation, chronic active | | | | | | 1 (7%)
Urinary System
Kidney | (15) | (14) | (15) | (15) | (15) | (15)
Infiltration cellular, focal, lymphocyte | | 1 (7%) | | 1 (7%)
Glomerulus, hyalinization | | | | | | 1 (7%)
Renal tubule, dilatation, diffuse | 1 (7%) | 2 (14%) | 3 (20%)
Renal tubule, dilatation, focal | 6 (40%) | 5 (36%) | 2 (13%) | 5 (33%) | 4 (27%) | 4 (27%)

a Number of animals examined microscopically at the site and the number of animals with lesion