# APPENDIX C SUMMARY OF LESIONS IN MALE p53 HAPLOINSUFFICIENT MICE IN THE 9-MONTH FEED STUDY OF ASPARTAME

TABLE C1 Summary of the Incidence of Neoplasms in Male p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame^a^

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | | | 1 | | | 1
Natural deaths | 1 | | 1 | | 1
Survivors
Terminal sacrifice | 14 | 15 | 13 | 15 | 14 | 14
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Intestine small, duodenum | (14) | | | | | (15)
Polyp adenomatous | | | | | | 1 (7%)
Liver | (15) | (15) | (15) | (15) | (14) | (15)
Salivary glands | (15) | (1) | (1) | | (1) | (15)
Cardiovascular System
None
Endocrine System
None
General Body System
None
Genital System
Prostate | (14) | (15) | (15) | (15) | (14) | (15)
Sarcoma | | | | | 1 (7%) | 1 (7%)
Hematopoietic System
Lymph node, mandibular | (14) | (15) | (14) | (15) | (14) | (15)
Lymph node, mesenteric | (14) | (14) | (15) | (13) | (14) | (15)
Lymph node, mediastinal | (13) | (14) | (14) | (13) | (12) | (13)
Spleen | (15) | (15) | (15) | (15) | (14) | (15)
Thymus | (14) | (15) | (15) | (14) | (15) | (14)
Integumentary System
Skin | (15) | | | | | (15)
Subcutaneous tissue, sarcoma | | | | | | 1 (7%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | (15) | (15) | (15) | (14) | (15)
Special Senses System
None
Urinary System
Kidney | (14) | (15) | (15) | (15) | (14) | (15)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15) | (15) | (15)
Lymphoma malignant | | | 2 (13%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | | | 2 | | 1 | 3
Total primary neoplasms | | | 2 | | 1 | 3
Total animals with benign neoplasms | | | | | | 1
Total benign neoplasms | | | | | | 1
Total animals with malignant neoplasms | | | 2 | | 1 | 2
Total malignant neoplasms | | | 2 | | 1 | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE C2

Individual Animal Tumor Pathology of Male p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame: 0 ppm

Number of Days on Study | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 0 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 2 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 5 | 5
Carcass ID Number | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 2 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 2 | 2 | 2 | 2 | 2 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 0 | 1 | 3 | 4 | 5 | 6 | 7 | 9 | 1 | 2 | 3 | 4 | 5 | 2 | 8 | Total Tissues/Tumors
Alimentary System
Esophagus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Gallbladder | A | I | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Intestine large, colon | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine large, rectum | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine large, cecum | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine small, duodenum | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine small, jejunum | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine small, ileum | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pancreas | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Salivary glands | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Stomach, glandular | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Tongue | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Cardiovascular System
Blood vessel | + | + | + | + | + | + | + | + | + | + | + | M | + | + | + | 14
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Islets, pancreatic | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Parathyroid gland | M | + | + | M | M | M | M | M | + | + | M | + | M | M | + | 6
Pituitary gland | I | + | + | + | + | + | I | + | + | + | + | + | + | + | + | 13
Thyroid gland | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Preputial gland | + | M | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Prostate | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Seminal vesicle | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Bone marrow | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mandibular | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mesenteric | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mediastinal | A | + | M | + | + | + | + | + | + | + | + | + | + | + | + | 13
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Musculoskeletal System
Bone | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skeletal muscle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nervous System
Brain | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Peripheral nerve | | | | | | | | | | | + | | | | | 1
Spinal cord | | | | | | | | | | | + | | | | | 1
Respiratory System
Larynx | M | M | M | M | M | M | M | M | + | M | M | + | + | + | M | 4
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nose | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Trachea | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Special Senses System
Eye | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Harderian gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Zymbal’s gland | + | + | + | + | + | + | + | + | M | + | M | M | + | + | + | 12
Urinary System
Kidney | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Urinary bladder | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Male p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame: 3,125 ppm

Number of Days on Study | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 5 | 5 | 5 | 5 | 5 | 5 | 5
Carcass ID Number | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 2 | 2 | 3 | 3 | 3 | 3 | 3 | 4 | 2 | 2 | 3 | 3 | 3 | 3 | 3 | Total Tissues/Tumors
Carcass ID Number | 7 | 8 | 0 | 2 | 3 | 6 | 9 | 0 | 6 | 9 | 1 | 4 | 5 | 7 | 8 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | | | | | | | + | | | | | | | | | 1
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | I | + | + | + | + | + | + | + | + | I | + | + | + | + | 13
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Prostate | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | M | + | + | + | 14
Lymph node, mediastinal | + | + | + | + | + | + | + | + | + | + | + | M | + | + | + | 14
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Musculoskeletal System
None
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Male p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame: 6,250 ppm

Number of Days on Study | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 1 | 1 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 4 | 0 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 5 | 5 | 5 | 5
Carcass ID Number | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 5 | 5 | 5 | 5 | 4 | 4 | 5 | 5 | Total Tissues/Tumors
Carcass ID Number | 6 | 9 | 1 | 2 | 3 | 5 | 8 | 1 | 2 | 4 | 5 | 4 | 7 | 0 | 3 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | | + | | | | | | | | | | | | | | 1
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | I | I | I | + | + | + | + | + | + | + | + | I | + | + | 11
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Prostate | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node, mandibular | + | + | I | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mediastinal | + | + | + | + | M | + | + | + | + | + | + | + | + | + | + | 14
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Musculoskeletal System
None
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
Eye | | | | | | + | | | | | | | | | | 1
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymphoma malignant | X | X | | | | | | | | | | | | | | 2

Individual Animal Tumor Pathology of Male p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame: 12,500 ppm

Number of Days on Study | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 5 | 5 | 5 | 5
Carcass ID Number | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 5 | 5 | 5 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 7 | 5 | 6 | 6 | 6 | Total Tissues/Tumors
Carcass ID Number | 7 | 8 | 9 | 0 | 1 | 2 | 4 | 5 | 6 | 8 | 0 | 6 | 3 | 7 | 9 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | M | I | I | I | + | I | I | + | + | + | M | + | + | + | 8
Thyroid gland | + | + | + | + | + | + | + | + | + | + | I | + | + | + | + | 14
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Prostate | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | | | | | | | | | | + | | | | | | 1
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | I | + | + | M | + | + | + | + | + | + | 13
Lymph node, mediastinal | + | M | + | + | + | M | + | + | + | + | + | + | + | + | + | 13
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | M | + | + | + | 14
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Musculoskeletal System
None
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Male p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame: 25,000 ppm

Number of Days on Study | 0 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 4 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 9 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 5 | 5 | 5 | 5 | 5
Carcass ID Number | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 8 | 8 | 7 | 8 | 8 | 8 | 8 | Total Tissues/Tumors
Carcass ID Number | 5 | 1 | 2 | 3 | 4 | 6 | 8 | 9 | 0 | 2 | 7 | 1 | 3 | 4 | 5 | Total Tissues/Tumors
Alimentary System
Liver | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Salivary glands | | | | | | | | | | | | + | | | | 1
Stomach, forestomach | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Stomach, glandular | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | A | + | M | + | I | + | I | + | + | + | + | + | + | I | + | 10
Thyroid gland | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
General Body System
None
Genital System
Epididymis | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Prostate | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Sarcoma | | | | | | | X | | | | | | | | | 1
Testes | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Hematopoietic System
Lymph node, mandibular | M | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mesenteric | M | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mediastinal | M | + | + | + | + | + | M | + | + | + | + | + | M | + | + | 12
Spleen | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Musculoskeletal System
None
Nervous System
Brain | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Respiratory System
Lung | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Special Senses System
None
Urinary System
Kidney | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Male p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame: 50,000 ppm

Number of Days on Study | 0 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 1 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 5 | 5 | 5
Carcass ID Number | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 3 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 9 | 8 | 8 | 8 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 0 | 8 | 9 | 9 | Total Tissues/Tumors
Carcass ID Number | 1 | 6 | 7 | 9 | 2 | 4 | 5 | 6 | 7 | 8 | 9 | 0 | 8 | 0 | 3 | Total Tissues/Tumors
Alimentary System
Esophagus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Gallbladder | + | + | + | + | + | + | + | M | + | M | + | + | M | + | + | 12
Intestine large, colon | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, rectum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, cecum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, duodenum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Polyp adenomatous | | | X | | | | | | | | | | | | | 1
Intestine small, jejunum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, ileum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pancreas | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Tongue | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Tooth | | | | | | | | | | | | | + | | | 1
Cardiovascular System
Blood vessel | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Islets, pancreatic | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Parathyroid gland | M | + | + | M | + | + | + | + | + | + | + | + | + | + | + | 13
Pituitary gland | I | + | + | + | + | + | + | + | + | M | + | + | + | I | + | 12
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Preputial gland | + | + | + | + | + | + | M | + | + | + | + | + | + | + | M | 13
Prostate | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Sarcoma | | | | | | | | | X | | | | | | | 1
Seminal vesicle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Bone marrow | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mediastinal | + | + | M | + | + | + | + | + | M | + | + | + | + | + | + | 13
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | I | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Subcutaneous tissue, sarcoma | X | | | | | | | | | | | | | | | 1
Musculoskeletal System
Bone | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skeletal muscle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Larynx | M | M | + | M | M | M | M | I | M | + | M | M | M | M | I | 2
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nose | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Trachea | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
Eye | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Harderian gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Zymbal’s gland | + | + | M | + | + | + | + | + | + | + | + | + | + | + | + | 14
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary bladder | + | + | + | + | + | + | + | + | + | + | + | + | M | + | + | 14
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

+: Tissue examined microscopically | M: Missing tissue | X: Lesion present
A: Autolysis precludes examination | I: Insufficient tissue | Blank: Not examined

TABLE C3 Statistical Analysis of Primary Neoplasms in Male p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
All Organs: Malignant Lymphoma
Overall rate^a^ | 0/15 (0%) | 0/15 (0%) | 2/15 (13%) | 0/15 (0%) | 0/15 (0%) | 0/15 (0%)
Adjusted rate^b^ | 0.0% | 0.0% | 13.3% | 0.0% | 0.0% | 0.0%
Terminal rate^c^ | 0/14 (0%) | 0/15 (0%) | 0/13 (0%) | 0/15 (0%) | 0/14 (0%) | 0/14 (0%)
First incidence (days) | —^e^ | — | 114 | — | — | —
Poly-3 test^d^ | P=0.378N | —^f^ | P=0.247 | — | — | —
All Organs: Malignant Neoplasms
Overall rate | 0/15 (0%) | 0/15 (0%) | 2/15 (13%) | 0/15 (0%) | 1/15 (7%) | 2/15 (13%)
Adjusted rate | 0.0% | 0.0% | 13.3% | 0.0% | 7.1% | 13.3%
Terminal rate | 0/14 (0%) | 0/15 (0%) | 0/13 (0%) | 0/15 (0%) | 1/14 (7%) | 1/14 (7%)
First incidence (days) | — | — | 114 | — | 274 (T) | 71
Poly-3 test | P=0.123 | — | P=0.247 | — | P=0.499 | P=0.247
All Organs: Benign or Malignant Neoplasms
Overall rate | 0/15 (0%) | 0/15 (0%) | 2/15 (13%) | 0/15 (0%) | 1/15 (7%) | 3/15 (20%)
Adjusted rate | 0.0% | 0.0% | 13.3% | 0.0% | 7.1% | 20.0%
Terminal rate | 0/14 (0%) | 0/15 (0%) | 0/13 (0%) | 0/15 (0%) | 1/14 (7%) | 2/14 (14%)
First incidence (days) | — | — | 114 | — | 274 (T) | 71
Poly-3 test | P=0.027 | — | P=0.247 | — | P=0.499 | P=0.118

(T) Terminal sacrifice

a Number of neoplasm-bearing animals/number of animals necropsied.

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal sacrifice. A negative trend is indicated by N.

e Not applicable; no neoplasms in animal group

f Value of statistic cannot be computed.

TABLE C4 Summary of the Incidence of Nonneoplastic Lesions in Male p53 Haploinsufficient Mice in the 9-Month Feed Study of Aspartame^a^

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | | | 1 | | | 1
Natural deaths | 1 | | 1 | | 1
Survivors
Terminal sacrifice | 14 | 15 | 13 | 15 | 14 | 14
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15) | (14) | (15)
Infiltration cellular, focal, lymphocyte | 2 (13%) | 2 (13%) | 4 (27%) | 1 (7%) | 2 (14%) | 5 (33%)
Inflammation, chronic | 1 (7%)
Inflammation, chronic active | 3 (20%) | | | | | 1 (7%)
Necrosis, focal | 2 (13%) | 1 (7%) | | | | 1 (7%)
Hepatocyte, periportal, vacuolization cytoplasmic, diffuse | 2 (13%) | | | | | 4 (27%)
Salivary glands | (15) | (1) | (1) | | (1) | (15)
Infiltration cellular, focal, lymphocyte | 9 (60%) | 1 (100%) | | | 1 (100%) | 10 (67%)
Tooth | | | | | | (1)
Peridontal tissue, cyst | | | | | | 1 (100%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15) | (15) | (15)
Atrophy | 14 (93%) | 14 (93%) | 12 (80%) | 12 (80%) | 10 (67%) | 13 (87%)
Hypertrophy, focal | | 1 (7%) | 3 (20%) | 2 (13%) | 1 (7%) | 3 (20%)
Subcapsular, hyperplasia, focal | 1 (7%) | | 2 (13%) | 1 (7%) | 2 (13%) | 1 (7%)
General Body System
None
Genital System
Epididymis | (15) | (15) | (15) | (15) | (14) | (15)
Epithelium, degeneration, focal | | 1 (7%)
Testes | (15) | (15) | (15) | (15) | (14) | (15)
Mineralization, focal | | 1 (7%)
Germinal epithelium, degeneration, diffuse | | 1 (7%)
Germinal epithelium, degeneration, focal | | 1 (7%) | | 1 (7%)
Rete testes, inflammation, focal | 1 (7%)
Hematopoietic System
Bone marrow | (14) | | | | | (15)
Hyperplasia | | | | | | 1 (7%)
Lymph node | | | | (1)
Iliac, pigmentation, focal | | | | 1 (100%)
Lymph node, mandibular | (14) | (15) | (14) | (15) | (14) | (15)
Hyperplasia | | 3 (20%) | | 2 (13%)
Hyperplasia, plasma cell | 1 (7%) | | | | | 2 (13%)
Lymph node, mesenteric | (14) | (14) | (15) | (13) | (14) | (15)
Hyperplasia | | | | | 1 (7%)
Lymph node, mediastinal | (13) | (14) | (14) | (13) | (12) | (13)
Hyperplasia | | | | | 1 (8%)
Spleen | (15) | (15) | (15) | (15) | (14) | (15)
Atrophy | 2 (13%)
Hematopoietic cell proliferation | | | | | 1 (7%) | 2 (13%)
Hyperplasia, lymphoid | | | | | | 1 (7%)
Thymus | (14) | (15) | (15) | (14) | (15) | (14)
Atrophy, diffuse | | | | | 1 (7%)
Atrophy, focal | | | | | | 2 (14%)
Integumentary System
None
Musculoskeletal System
None
Nervous System
Brain | (14) | (15) | (15) | (15) | (14) | (15)
Hydrocephalus | | | 1 (7%)
Corpus callosum, medulla, vacuolization cytoplasmic, focal | | | 1 (7%)
Medulla, vacuolization cytoplasmic, focal | | | | | | 1 (7%)
Ventricle, hydrocephalus | | 1 (7%)
Peripheral nerve | (1)
Vacuolization cytoplasmic, diffuse | 1 (100%)
Spinal cord | (1)
Vacuolization cytoplasmic, focal | 1 (100%)
Respiratory System
Lung | (15) | (15) | (15) | (15) | (14) | (15)
Infiltration cellular, focal, lymphocyte | | | | | | 1 (7%)
Inflammation, chronic active, diffuse | | | 1 (7%)
Perivascular, infiltration cellular, lymphocyte | | | | | 2 (14%)
Nose | (14) | | | | | (15)
Inflammation, acute | 1 (7%)
Special Senses System
Eye | (14) | | (1) | | | (15)
Developmental malformation | | | 1 (100%)
Harderian gland | (15) | | | | | (15)
Infiltration cellular, focal, lymphocyte | 5 (33%) | | | | | 1 (7%)
Inflammation, chronic active | | | | | | 1 (7%)
Urinary System
Kidney | (14) | (15) | (15) | (15) | (14) | (15)
Infiltration cellular, focal, lymphocyte | | 1 (7%) | | 1 (7%)
Nephropathy | 4 (29%) | | | | | 3 (20%)
Renal tubule, dilatation, diffuse | | 2 (13%) | | 1 (7%) | | 1 (7%)
Renal tubule, dilatation, focal | | 2 (13%)

a Number of animals examined microscopically at the site and the number of animals with lesion