# APPENDIX B SUMMARY OF LESIONS IN FEMALE Tg.AC HEMIZYGOUS MICE IN THE 9-MONTH FEED STUDY OF ASPARTAME

TABLE B1 Summary of the Incidence of Neoplasms in Female Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame^a^

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Disposition Summary
Animais initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | 3 | 2 | 3 | 4 | 3 | 2
Natural deaths | 1 | 3 | 3 | 2 | 1 | 5
Survivors
Terminal sacrifice | 11 | 10 | 9 | 9 | 11 | 8
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (14) | (15) | (14) | (14)
Sarcoma stromal, metastatic, uterus | | | | 1 (7%)
Pancreas | (15) | | | | | (13)
Salivary glands | (15) | | | (1) | | (13)
Duct, carcinoma | | | | 1 (100%) | | 1 (8%)
Stomach, forestomach | (15) | (13) | (13) | (15) | (14) | (11)
Squamous cell papilloma | 2 (13%) | 6 (46%) | 1 (8%) | 7 (47%) | 3 (21%) | 5 (45%)
Squamous cell papilloma, multiple | 2 (13%) | 3 (23%) | 3 (23%) | | 4 (29%)
Tooth | (4) | (4) | (2) | (5) | (5) | (1)
Odontogenic tumor | 4 (100%) | | | | | 1 (100%)
Odontoma | | 4 (100%) | 2 (100%) | 5 (100%) | 5 (100%)
Cardiovascular System
Heart | (15) | (15) | (15) | (15) | (15) | (15)
Endocrine System
Adrenal cortex | (15) | (12) | (13) | (13) | (14) | (15)
Adrenal medulla | (15) | (12) | (13) | (13) | (14) | (14)
Islets, pancreatic | (15) | | | | | (11)
Pituitary gland | (13) | (11) | (12) | (10) | (11) | (9)
Thyroid gland | (15) | (13) | (12) | (15) | (14) | (11)
General Body System
None
Genital System
Ovary | (15) | (15) | (13) | (14) | (14) | (14)
Uterus | (15) | (13) | (13) | (12) | (14) | (14)
Sarcoma stromal | | | | 1 (8%)
Hematopoietic System
Bone marrow | (15 | | | | | (12)
Lymph node | (1) | | | (1)
Pancreatic, sarcoma stromal, metastatic, uterus | | | | 1 (100%)
Lymph node, mediastinal | (12) | (11) | (11) | (12) | (11) | (11)
Carcinoma, metastatic, salivary glands | | | | 1 (8%)
Spleen | (15 | (14) | (14) | (12 | (14 | (14)
Integumentary System
Mammary gland | (15) | (13) | (13) | (14) | (14) | (11)
Skin | (15) | (3) | (1) | | (3) | (15)
Squamous cell papilloma | | 2 (67%) | 1 (100%)
Vulva, squamous cell papilloma | 1 (7%) | 1 (33%) | | | 2 (67%)
Musculoskeletal System
None
Nervous System
Brain | (15) | (12) | (13) | (13) | (14) | (11)
Respiratory System
Lung | (15) | (14) | (14) | (15) | (14) | (14)
Alveolar/bronchiolar adenoma | 1 (7%)
Carcinoma, metastatic, salivary glands | | | | 1 (7%)
Nose | (15) | | | | | (13)
Special Senses System
None
Urinary System
Kidney | (15) | (12) | (13) | (14) | (14) | (14)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15) | (15) | (15)
Leukemia erythrocytic | 1 (7%) | 3 (20%) | 1 (7%) | | | 1 (7%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 8 | 12 | 8 | 11 | 11 | 7
Total primary neoplasms | 11 | 19 | 8 | 14 | 14 | 8
Total animals with benign neoplasms | 4 | 12 | 7 | 9 | 11 | 5
Total benign neoplasms | 6 | 16 | 7 | 12 | 14 | 5
Total animals with malignant neoplasms | 1 | 3 | 1 | 2 | | 2
Total malignant neoplasms | 1 | 3 | 1 | 2 | | 2
Total animals with metastatic neoplasms | | | | 2
Total metastatic neoplasms | | | | 4
Total animals with uncertain neoplasms-benign or malignant | 4 | | | | | 1
Total uncertain neoplasms | 4 | | | | | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE B2

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame: 0 ppm

Number of Days on Study | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 0 | 0 | 4 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 9 | 0 | 2 | 0 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5
Carcass ID Number | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 1 | 1 | 0 | 1 | 0 | 0 | 0 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 2 | Total Tissues/Tumors
Carcass ID Number | 7 | 1 | 6 | 4 | 7 | 8 | 9 | 0 | 2 | 3 | 5 | 6 | 8 | 9 | 0 | Total Tissues/Tumors
Alimentary System
Esophagus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Gallbladder | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine large, colon | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, rectum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine large, cecum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, duodenum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, jejunum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Intestine small, ileum | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pancreas | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | | X | X | | | | | | | | | | 2
Squamous cell papilloma, multiple | | | | | | | | X | | | | | | | X | 2
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Tongue | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Tooth | + | + | + | + | | | | | | | | | | | | 4
Odontogenic tumor | X | X | X | X | | | | | | | | | | | | 4
Cardiovascular System
Blood vessel | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Islets, pancreatic | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Parathyroid gland | M | M | M | M | + | M | + | M | + | + | M | M | M | M | M | 4
Pituitary gland | + | I | + | + | + | + | M | + | + | + | + | + | + | + | + | 13
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
Tissue nos | | | | | | | | | + | | + | | | | | 2
Genital System
Clitoral gland | M | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Vagina | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Bone marrow | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node | | | | | | | | | | | | | + | | | 1
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mediastinal | + | M | + | + | + | + | + | I | + | + | + | M | + | + | + | 12
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Mammary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Vulva, squamous cell papilloma | | | | | X | | | | | | | | | | | 1
Musculoskeletal System
Bone | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skeletal muscle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Larynx | M | M | M | M | M | M | M | M | I | M | M | M | M | M | M
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Alveolar/bronchiolar adenoma | | | | | X | | | | | | | | | | | 1
Nose | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Trachea | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
Eye | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Harderian gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Zymbal’s gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary bladder | + | + | + | + | + | + | I | + | + | + | + | + | + | + | + | 14
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Leukemia erythrocytic | X | | | | | | | | | | | | | | | 1

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame: 3,125 ppm

Number of Days on Study | 0 | 1 | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 8 | 9 | 9 | 0 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 1 | 2 | 8 | 6 | 1 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5
Carcass ID Number | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 3 | 2 | 3 | 3 | 3 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 3 | 3 | Total Tissues/Tumors
Carcass ID Number | 2 | 1 | 4 | 3 | 0 | 2 | 3 | 4 | 5 | 6 | 7 | 8 | 9 | 1 | 5 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | A | + | + | A | + | + | + | + | + | + | + | + | + | + | + | 13
Squamous cell papilloma | | | | | X | X | | | X | | | X | X | X | | 6
Squamous cell papilloma, multiple | | X | | | | | | | | X | | | | | X | 3
Stomach, glandular | A | A | + | A | + | + | + | + | + | + | + | + | + | + | + | 12
Tooth | | | | + | + | + | | | | | | | | + | | 4
Odontoma | | | | X | X | X | | | | | | | | X | | 4
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | A | A | + | A | + | + | + | + | + | + | + | + | + | + | + | 12
Adrenal medulla | A | A | + | A | + | + | + | + | + | + | + | + | + | + | + | 12
Pituitary gland | + | + | I | A | I | M | + | + | + | + | + | + | + | + | + | 11
Thyroid gland | A | + | + | A | + | + | + | + | + | + | + | + | + | + | + | 13
General Body System
None
Genital System
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Uterus | A | + | + | A | + | + | + | + | + | + | + | + | + | + | + | 13
Hematopoietic System
Lymph node, mandibular | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mesenteric | A | + | + | A | + | + | + | + | + | + | + | + | + | + | + | 13
Lymph node, mediastinal | A | M | + | A | + | + | + | + | + | + | + | M | + | + | + | 11
Spleen | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Thymus | A | + | M | + | + | + | + | + | + | + | + | + | + | + | + | 13
Integumentary System
Mammary gland | A | + | + | A | + | + | + | + | + | + | + | + | + | + | + | 13
Skin | | | + | | | | + | | | | | | + | | | 3
Squamous cell papilloma | | | X | | | | | | | | | | X | | | 2
Vulva, squamous cell papilloma | | | | | | | X | | | | | | | | | 1
Musculoskeletal System
None
Nervous System
Brain | A | A | + | A | + | + | + | + | + | + | + | + | + | + | + | 12
Respiratory System
Lung | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Special Senses System
None
Urinary System
Kidney | A | A | + | A | + | + | + | + | + | + | + | + | + | + | + | 12
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Leukemia erythrocytic | | X | X | X | | | | | | | | | | | | 3

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame: 6,250 ppm

Number of Days on Study | 0 | 0 | 1 | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 6 | 6 | 1 | 4 | 0 | 0 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 1 | 7 | 3 | 8 | 0 | 7 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5
Carcass ID Number | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 3 | 4 | 4 | 3 | 3 | 4 | 3 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 5 | Total Tissues/Tumors
Carcass ID Number | 8 | 8 | 1 | 9 | 7 | 9 | 6 | 0 | 2 | 3 | 4 | 5 | 6 | 7 | 0 | Total Tissues/Tumors
Alimentary System
Liver | + | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 14
Stomach, forestomach | + | + | A | A | + | + | + | + | + | + | + | + | + | + | + | 13
Squamous cell papilloma | | | | | | | | X | | | | | | | | 1
Squamous cell papilloma, multiple | | | | | | | X | | | | | X | X | | | 3
Stomach, glandular | + | + | A | A | + | + | + | + | + | + | + | + | + | + | + | 13
Tooth | | | | | + | + | | | | | | | | | | 2
Odontoma | | | | | X | X | | | | | | | | | | 2
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | A | A | + | + | + | + | + | + | + | + | + | + | + | 13
Adrenal medulla | + | + | A | A | + | + | + | + | + | + | + | + | + | + | + | 13
Pituitary gland | M | + | A | A | + | + | + | + | + | + | + | + | + | + | + | 12
Thyroid gland | + | + | A | A | + | + | + | + | + | + | M | + | + | + | + | 12
General Body System
None
Genital System
Ovary | + | + | A | A | + | + | + | + | + | + | + | + | + | + | + | 13
Uterus | + | + | A | A | + | + | + | + | + | + | + | + | + | + | + | 13
Hematopoietic System
Lymph node, mandibular | + | + | A | + | M | M | + | + | + | + | + | + | + | + | + | 12
Lymph node, mesenteric | M | + | A | A | + | + | + | + | + | + | + | + | + | + | + | 12
Lymph node, mediastinal | + | + | A | A | + | + | + | + | M | + | + | M | + | + | + | 11
Spleen | + | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 14
Thymus | + | + | A | A | M | + | + | + | + | + | + | + | + | + | + | 12
Integumentary System
Mammary gland | + | + | A | A | + | + | + | + | + | + | + | + | + | + | + | 13
Skin | | | | | | | | | | | | | | + | | 1
Squamous cell papilloma | | | | | | | | | | | | | | X | | 1
Musculoskeletal System
None
Nervous System
Brain | + | + | A | A | + | + | + | + | + | + | + | + | + | + | + | 13
Respiratory System
Lung | + | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 14
Special Senses System
None
Urinary System
Kidney | + | + | A | A | + | + | + | + | + | + | + | + | + | + | + | 13
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Leukemia erythrocytic | | | | X | | | | | | | | | | | | 1

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame: 12,500 ppm

Number of Days on Study | 0 | 1 | 1 | 1 | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 9 | 3 | 6 | 6 | 8 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 7 | 4 | 5 | 5 | 4 | 1 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5
Carcass ID Number | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 5 | 5 | 5 | 6 | 6 | 5 | 5 | 5 | 5 | 5 | 5 | 6 | 6 | 6 | 6 | Total Tissues/Tumors
Carcass ID Number | 6 | 3 | 4 | 0 | 4 | 9 | 1 | 2 | 5 | 7 | 8 | 1 | 2 | 3 | 5 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Sarcoma stromal, metastatic, uterus | | | | | | | | | | | X | | | | | 1
Salivary glands | + | | | | | | | | | | | | | | | 1
Duct, carcinoma | X | | | | | | | | | | | | | | | 1
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | | X | X | | X | | X | | X | X | | X | 7
Stomach, glandular | + | + | + | + | + | A | + | + | + | + | + | + | + | + | + | 14
Tooth | | | + | + | + | + | | | | | | + | | | | 5
Odontoma | | | X | X | X | X | | | | | | X | | | | 5
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | A | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 13
Adrenal medulla | A | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 13
Pituitary gland | I | M | + | M | + | + | + | + | + | + | + | + | M | + | I | 10
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Ovary | + | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 14
Uterus | A | + | A | + | + | A | + | + | + | + | + | + | + | + | + | 12
Sarcoma stromal | | | | | | | | | | | X | | | | | 1
Hematopoietic System
Lymph node | | | | | | | | | | | + | | | | | 1
Pancreatic, sarcoma stromal, metastatic, uterus | | | | | | | | | | | X | | | | | 1
Lymph node, mandibular | A | + | A | M | + | + | + | + | + | + | + | + | + | + | + | 12
Lymph node, mesenteric | A | A | + | + | + | + | + | + | + | + | I | + | + | + | + | 12
Lymph node, mediastinal | + | + | A | + | + | + | + | + | + | + | + | M | + | + | M | 12
Carcinoma, metastatic, salivary glands | X | | | | | | | | | | | | | | | 1
Spleen | A | A | + | + | + | A | + | + | + | + | + | + | + | + | + | 12
Thymus | M | A | M | + | + | + | + | + | + | + | + | + | + | + | + | 12
Integumentary System
Mammary gland | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Musculoskeletal System
None
Nervous System
Brain | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Carcinoma, metastatic, salivary glands | X | | | | | | | | | | | | | | | 1
Special Senses System
None
Urinary System
Kidney | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame: 25,000 ppm

Number of Days on Study | 0 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 2 | 6 | 6 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 3 | 7 | 9 | 0 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5
Carcass ID Number | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 7 | 6 | 7 | 6 | 6 | 6 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 8 | Total Tissues/Tumors
Carcass ID Number | 8 | 7 | 3 | 8 | 6 | 9 | 0 | 1 | 2 | 4 | 5 | 6 | 7 | 9 | 0 | Total Tissues/Tumors
Alimentary System
Liver | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Stomach, forestomach | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Squamous cell papilloma | | | | X | | | | X | X | | | | | | | 3
Squamous cell papilloma, multiple | | X | | | | X | X | | | | | | | | X | 4
Stomach, glandular | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Tooth | | + | + | + | | | | | | | | + | | + | | 5
Odontoma | | X | X | X | | | | | | | | X | | X | | 5
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Adrenal medulla | M | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Pituitary gland | A | + | + | I | + | + | I | + | I | + | + | + | + | + | + | 11
Thyroid gland | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
General Body System
None
Genital System
Ovary | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Uterus | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Hematopoietic System
Lymph node, mandibular | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mesenteric | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mediastinal | A | + | + | + | M | + | + | + | M | I | + | + | + | + | + | 11
Spleen | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Thymus | A | M | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Integumentary System
Mammary gland | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Skin | | | | | | | | + | | | + | + | | | | 3
Vulva, squamous cell papilloma | | | | | | | | X | | | X | | | | | 2
Musculoskeletal System
None
Nervous System
Brain | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Respiratory System
Lung | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Special Senses System
None
Urinary System
Kidney | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame: 50,000 ppm

Number of Days on Study | 0 | 0 | 0 | 1 | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 7 | 9 | 9 | 5 | 8 | 1 | 6 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 9 | 2 | 2 | 1 | 4 | 5 | 9 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5
Carcass ID Number | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 8 | 8 | 9 | 9 | 9 | 9 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 9 | 9 | Total Tissues/Tumors
Carcass ID Number | 8 | 2 | 2 | 1 | 0 | 4 | 7 | 1 | 3 | 4 | 5 | 6 | 9 | 3 | 5 | Total Tissues/Tumors
Alimentary System
Esophagus | + | A | A | + | M | A | + | + | + | + | + | + | + | + | + | 11
Gallbladder | A | A | M | A | M | A | + | M | + | M | M | + | + | + | + | 6
Intestine large, colon | A | A | A | A | + | A | + | + | + | + | + | + | + | + | + | 10
Intestine large, rectum | A | A | A | A | + | A | + | + | + | + | + | + | + | + | + | 10
Intestine large, cecum | A | A | A | A | + | A | + | + | + | + | + | + | + | + | + | 10
Intestine small, duodenum | A | A | A | A | + | A | + | + | + | + | + | + | + | + | + | 10
Intestine small, jejunum | A | A | A | A | + | A | + | + | + | + | + | + | + | + | + | 10
Intestine small, ileum | A | A | A | A | + | A | + | + | + | + | + | + | + | + | + | 10
Liver | + | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 14
Pancreas | + | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 13
Salivary glands | + | + | A | + | + | A | + | + | + | + | + | + | + | + | + | 13
Duct, carcinoma | | | | | | | X | | | | | | | | | 1
Stomach, forestomach | + | A | A | A | + | A | + | + | + | + | + | + | + | + | + | 11
Squamous cell papilloma | | | | | X | | | X | | X | X | | | | X | 5
Stomach, glandular | A | A | A | A | + | A | + | + | + | + | + | + | + | + | + | 10
Tongue | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Tooth | | | | | + | | | | | | | | | | | 1
Odontogenic tumor | | | | | X | | | | | | | | | | | 1
Cardiovascular System
Blood vessel | A | A | A | + | + | A | + | + | M | + | + | + | + | + | + | 10
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | M | + | + | + | 14
Islets, pancreatic | A | A | A | A | + | + | + | + | + | + | + | + | + | + | + | 11
Parathyroid gland | M | M | M | A | M | M | I | M | M | M | M | + | M | + | + | 3
Pituitary gland | M | M | M | A | + | A | + | + | + | I | + | + | + | + | + | 9
Thyroid gland | + | A | A | A | + | + | + | + | + | + | M | + | + | + | + | 11
General Body System
None
Genital System
Clitoral gland | + | + | A | M | M | A | + | + | M | + | + | + | + | + | + | 10
Ovary | + | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 14
Uterus | + | + | + | A | + | + | + | + | + | + | + | + | + | + | + | 14
Vagina | A | A | A | + | + | A | + | + | + | + | + | + | + | + | + | 11
Hematopoietic System
Bone marrow | A | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 12
Lymph node, mandibular | A | + | A | + | + | A | + | + | + | + | + | + | + | + | + | 12
Lymph node, mesenteric | A | A | A | A | + | A | + | + | + | + | + | + | + | M | + | 9
Lymph node, mediastinal | A | A | A | M | + | + | + | + | + | + | + | + | + | + | + | 11
Spleen | + | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 14
Thymus | + | A | A | A | + | A | + | + | + | + | + | + | + | + | + | 11
Integumentary System
Mammary gland | A | A | A | + | + | + | + | + | M | + | + | + | + | + | + | 11
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Musculoskeletal System
Bone | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Skeletal muscle | + | + | + | + | + | A | + | + | + | + | + | + | + | + | + | 14
Nervous System
Brain | A | A | A | + | + | A | + | + | + | + | + | + | + | + | + | 11
Respiratory System
Larynx | M | M | M | M | M | M | M | M | I | M | M | M | I | M | I
Lung | + | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 14
Nose | A | + | A | + | + | + | + | + | + | + | + | + | + | + | + | 13
Trachea | A | A | A | A | + | A | + | + | + | + | + | + | + | + | + | 10
Special Senses System
Eye | A | A | A | A | + | A | + | + | + | + | + | + | + | + | + | 10
Harderian gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Zymbal’s gland | + | + | M | + | + | + | + | + | + | + | M | + | + | + | + | 13
Urinary System
Kidney | + | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Urinary bladder | A | A | A | A | + | A | + | + | + | + | + | + | + | + | + | 10
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Leukemia erythrocytic | | | | | | X | | | | | | | | | | 1

+: Tissue examined microscopically | M: Missing tissue | X: Lesion present
A: Autolysis precludes examination | I: Insufficient tissue | Blank: Not examined

TABLE B3 Statistical Analysis of Primary Neoplasms in Female Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Lung: Alveolar/bronchiolar Adenoma
Overall rate^a^ | 1/15 (7%) | 0/14 (0%) | 0/14 (0%) | 0/15 (0%) | 0/14 (0%) | 0/14 (0%)
Adjusted rate^b^ | 7.7% | 0.0% | 0.0% | 0.0% | 0.0% | 0.0%
Terminal rate^c^ | 1/11 (9%) | 0/10 (0%) | 0/9 (0%) | 0/9 (0%) | 0/11 (0%) | 0/8 (0%)
First incidence (days) | 275 (T) | —^e^ | — | — | — | —
Poly-3 test^d^ | P=0.332N | P=0.516N | P=0.553N | P=0.537N | P=0.489N | P=0.554N
Salivary Glands: Carcinoma
Overall rate | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 1/15 (7%) | 0/15 (0%) | 1/15 (7%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 8.5% | 0.0% | 10.0%
Terminal rate | 0/11 (0%) | 0/10 (0%) | 0/9 (0%) | 0/9 (0%) | 0/11 (0%) | 0/8 (0%)
First incidence (days) | — | — | — | 97 | — | 269
Poly-3 test | P=0.204 | —^f^ | — | P=0.480 | — | P=0.448
Skin: Squamous Cell Papilloma
Overall rate | 1/15 (7%) | 3/15 (20%) | 1/15 (7%) | 0/15 (0%) | 2/15 (13%) | 0/15 (0%)
Adjusted rate | 7.7% | 23.5% | 9.9% | 0.0% | 14.5% | 0.0%
Terminal rate | 1/11 (9%) | 2/10 (20%) | 1/9 (11%) | 0/9 (0%) | 2/11 (18%) | 0/8 (0%)
First incidence (days) | 275 (T) | 198 | 275 (T) | — | 275 (T) | —
Poly-3 test | P=0.244N | P=0.286 | P=0.700 | P=0.537N | P=0.519 | P=0.553N
Stomach (Forestomach): Squamous Cell Papilloma
Overall rate | 4/15 (27%) | 9/15 (60%) | 4/15 (27%) | 7/15 (47%) | 7/15 (47%) | 5/15 (33%)
Adjusted rate | 30.6% | 70.2% | 39.8% | 60.4% | 50.2% | 46.8%
Terminal rate | 4/11 (36%) | 7/10 (70%) | 4/9 (44%) | 5/9 (56%) | 5/11 (46%) | 4/8 (50%)
First incidence (days) | 275 (T) | 192 | 275 (T) | 184 | 267 | 184
Poly-3 test | P=0.539 | P=0.042 | P=0.493 | P=0.136 | P=0.261 | P=0.352
Tooth: Odontogenic Tumor
Overall rate | 4/15 (27%) | 4/15 (27%) | 2/15 (13%) | 5/15 (33%) | 5/15 (33%) | 1/15 (7%)
Adjusted rate | 26.7% | 31.4% | 17.8% | 38.0% | 35.7% | 9.4%
Terminal rate | 0/11 (0%) | 2/10 (20%) | 0/9 (0%) | 1/9 (11%) | 2/11 (18%) | 0/8 (0%)
First incidence (days) | 109 | 206 | 200 | 165 | 267 | 184
Poly-3 test | P=0.296N | P=0.556 | P=0.475N | P=0.409 | P=0.452 | P=0.287N
All Organs: Erythrocytic Leukemia
Overall rate | 1/15 (7%) | 3/15 (20%) | 1/15 (7%) | 0/15 (0%) | 0/15 (0%) | 1/15 (7%)
Adjusted rate | 7.1% | 21.5% | 9.2% | 0.0% | 0.0% | 9.5%
Terminal rate | 0/11 (0%) | 0/10 (0%) | 0/9 (0%) | 0/9 (0%) | 0/11 (0%) | 0/8 (0%)
First incidence (days) | 109 | 192 | 148 | — | — | 215
Poly-3 test | P=0.293N | P=0.296 | P=0.703 | P=0.550N | P=0.503N | P=0.693
All Organs: Benign Neoplasms
Overall rate | 4/15 (27%) | 12/15 (80%) | 7/15 (47%) | 9/15 (60%) | 11/15 (73%) | 5/15 (33%)
Adjusted rate | 30.6% | 85.6% | 62.2% | 68.4% | 78.6% | 46.8%
Terminal rate | 4/11 (36%) | 8/10 (80%) | 5/9 (56%) | 5/9 (56%) | 8/11 (73%) | 4/8 (50%)
First incidence (days) | 275 (T) | 192 | 200 | 165 | 267 | 184
Poly-3 test | P=0.535N | P=0.002 | P=0.120 | P=0.053 | P=0.010 | P=0.352
All Organs: Malignant Neoplasms
Overall rate | 1/15 (7%) | 3/15 (20%) | 1/15 (7%) | 2/15 (13%) | 0/15 (0%) | 2/15 (13%)
Adjusted rate | 7.1% | 21.5% | 9.2% | 16.9% | 0.0% | 18.9%
Terminal rate | 0/11 (0%) | 0/10 (0%) | 0/9 (0%) | 1/9 (11%) | 0/11 (0%) | 0/8 (0%)
First incidence (days) | 109 | 192 | 148 | 97 | — | 215
Poly-3 test | P=0.564N | P=0.296 | P=0.703 | P=0.439 | P=0.503N | P=0.400
All Organs: Benign or Malignant Neoplasms
Overall rate | 8/15 (53%) | 12/15 (80%) | 8/15 (53%) | 11/15 (73%) | 11/15 (73%) | 7/15 (47%)
Adjusted rate | 53.3% | 85.6% | 66.1% | 77.9% | 78.6% | 62.1%
Terminal rate | 4/11 (36%) | 8/10 (80%) | 5/9 (56%) | 6/9 (67%) | 8/11 (73%) | 4/8 (50%)
First incidence (days) | 109 | 192 | 148 | 97 | 267 | 184
Poly-3 test | P=0.541 | P=0.065 | P=0.393 | P=0.157 | P=0.150 | P=0.480

(T) Terminal sacrifice

a Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for lung; for other tissues, denominator is number of animals necropsied.

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal sacrifice. A negative trend or a lower incidence in an exposed group is indicated by N.

e Not applicable; no neoplasms in animal group

f Value of statistic cannot be computed.

TABLE B4 Summary of the Incidence of Nonneoplastic Lesions in Female Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame^a^

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | 3 | 2 | 3 | 4 | 3 | 2
Natural deaths | 1 | 3 | 3 | 2 | 1 | 5
Survivors
Terminal sacrifice | 11 | 10 | 9 | 9 | 11 | 8
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Gallbladder | (14) | | | | | (6)
Inflammation, chronic active | 1 (7%)
Liver | (15) | (15) | (14) | (15) | (14) | (14)
Infiltration cellular, focal, lymphocyte | | 1 (7%)
Infiltration cellular, focal, polymorphonuclear | | | | 1 (7%)
Inflammation, acute, focal | 1 (7%) | | | | 1 (7%) | 2 (14%)
Inflammation, chronic active, focal | 2 (13%) | | | | 1 (7%) | 1 (7%)
Necrosis | | | 1 (7%)
Necrosis, focal | 1 (7%) | | | | | 4 (29%)
Hepatocyte, necrosis, focal | | 1 (7%) | | 4 (27%) | 1 (7%)
Stomach, forestomach | (15) | (13) | (13) | (15) | (14) | (11)
Infiltration cellular, focal, lymphocyte | | | 1 (8%)
Muscularis, inflammation, acute, focal | | | 1 (8%)
Tongue | (15) | | | | | (15)
Ulcer | 1 (7%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (15) | (12) | (13) | (13) | (14) | (15)
Accessory adrenal cortical nodule | 1 (7%)
Atrophy | 3 (20%) | 2 (17%) | 1 (8%) | 4 (31%) | 5 (36%) | 5 (33%)
Capsule, inflammation, acute, focal | | | | | 1 (7%)
Subcapsular, hyperplasia, focal | 12 (80%) | 6 (50%) | 6 (46%) | 5 (38%) | 6 (43%) | 6 (40%)
Zona reticularis, vacuolization cytoplasmic | 12 (80%) | 9 (75%) | 6 (46%) | 8 (62%) | 9 (64%) | 8 (53%)
Pituitary gland | (13) | (11) | (12) | (10) | (11) | (9)
Cyst | 2 (15%)
Pars intermedia, hypertrophy | | | | | 1 (9%)
Thyroid gland | (15) | (13) | (12) | (15) | (14) | (11)
Follicle, cyst | 1 (7%)
General Body System
Tissue NOS | (2)
Pigmentation | 1 (50%)
Abdominal, fat, necrosis, focal | 1 (50%)
Genital System
Ovary | (15) | (15) | (13) | (14) | (14) | (14)
Atrophy | 2 (13%) | | 1 (8%)
Cyst, focal | | | | | 1 (7%)
Hemorrhage, focal | | | | | 1 (7%)
Uterus | (15) | (13) | (13) | (12) | (14) | (14)
Cyst, focal | | | | 1 (8%)
Hydrometra | | | | | 1 (7%)
Endometrium, hyperplasia, cystic | 10 (67%) | 8 (62%) | 9 (69%) | 10 (83%) | 10 (71%) | 10 (71%)
Hematopoietic System
Lymph node | (1) | | | (1)
Renal, hyperplasia | 1 (100%)
Lymph node, mandibular | (15) | (14) | (12) | (12) | (14) | (12)
Hyperplasia | | 2 (14%) | | 2 (17%) | 2 (14%)
Hyperplasia, plasma cell | 2 (13%) | | | | | 1 (8%)
Inflammation, acute, focal | | | | | 1 (7%)
Lymph node, mediastinal | (12) | (11) | (11) | (12) | (11) | (11)
Hyperplasia | 1 (8%) | | | | 1 (9%)
Spleen | (15) | (14) | (14) | (12) | (14) | (14)
Accessory spleen | | 1 (7%)
Hematopoietic cell proliferation | 10 (67%) | 4 (29%) | 7 (50%) | 6 (50%) | 8 (57%) | 5 (36%)
Pigmentation | 10 (67%) | 10 (71%) | 11 (79%) | 10 (83%) | 11 (79%) | 9 (64%)
Thymus | (15) | (13) | (12) | (12) | (13) | (11)
Atrophy, diffuse | 3 (20%) | 1 (8%) | 1 (8%) | 2 (17%) | 2 (15%) | 2 (18%)
Atrophy, focal | 2 (13%) | 1 (8%) | 1 (8%) | | | 1 (9%)
Hyperplasia, diffuse | | 1 (8%)
Integumentary System
Skin | (15) | (3) | (1) | | (3) | (15)
Lip, control epidermis, hyperplasia, focal | | | | | 1 (33%)
Musculoskeletal System
None
Nervous System
Brain | (15) | (12) | (13) | (13) | (14) | (11)
Abscess, focal | | | | | 1 (7%)
Inflammation, acute, focal | | | | | 1 (7%)
Cerebellum, corpus callosum, pons, vacuolization cytoplasmic, focal | | | 1 (8%)
Cortex, cerebrum, degeneration, focal | | | | | | 1 (9%)
Cortex, cerebrum, neuron, necrosis | | | 1 (8%)
Medulla, vacuolization cytoplasmic | | | | | 1 (7%)
Pyramidal cell, hippocampus, necrosis | | | 1 (8%)
Respiratory System
Lung | (15) | (14) | (14) | (15) | (14) | (14)
Hemorrhage, focal | 1 (7%)
Infiltration cellular, focal, lymphocyte | 1 (7%)
Inflammation, chronic active, focal | 1 (7%)
Alveolar epithelium, hyperplasia, focal | 1 (7%) | 1 (7%)
Perivascular, infiltration cellular, lymphocyte | | | | 1 (7%) | 1 (7%)
Special Senses System
Eye | (15) | | | | | (10)
Retina, atrophy | 15 (100%) | | | | | 10 (100%)
Harderian gland | (15) | | | | | (15)
Inflammation, chronic active | | | | | | 1 (7%)
Urinary System
Kidney | (15) | (12) | (13) | (14) | (14) | (14)
Infiltration cellular, focal, lymphocyte | 1 (7%)
Inflammation, acute, focal | | | | | 1 (7%)
Mineralization, focal | | | | | | 1 (7%)
Nephropathy | 1 (7%) | | | | | 1 (7%)
Renal tubule, dilatation, focal | 1 (7%) | 2 (17%) | 1 (8%) | | | 1 (7%)

a Number of animals examined microscopically at the site and the number of animals with lesion