# APPENDIX A SUMMARY OF LESIONS IN MALE Tg.AC HEMIZYGOUS MICE IN THE 9-MONTH FEED STUDY OF ASPARTAME

TABLE A1 Summary of the Incidence of Neoplasms in Male Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame^a^

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | 3 | 3 | 4 | 2 | 3 | 4
Natural deaths | 3 | | 3 | 1 | 1 | 1
Survivors
Terminal sacrifice | 9 | 12 | 8 | 12 | 11 | 10
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (14) | (15) | (14) | (15)
Salivary glands | (13) | | (2) | | (2) | (14)
Duct, carcinoma | | | 2 (100%) | | 1 (50%) | 1 (7%)
Stomach, forestomach | (12) | (15) | (13) | (14) | (14) | (14)
Squamous cell papilloma | 4 (33%) | 1 (7%) | 1 (8%) | 3 (21%) | 4 (29%) | 5 (36%)
Squamous cell papilloma, multiple | 4 (33%) | 4 (27%) | 1 (8%) | 2 (14%) | 2 (14%) | 1 (7%)
Tooth | (4) | (4) | (2) | (2) | (2) | (6)
Odontogenic tumor | 3 (75%) | 4 (100%) | 2 (100%) | 2 (100%) | 2 (100%) | 6 (100%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (13) | (15) | (13) | (14) | (15) | (13)
General Body System
None
Genital System
None
Hematopoietic System
Lymph node, mandibular | (12) | (15) | (13) | (14) | (14) | (14)
Lymph node, mesenteric | (13) | (15) | (13) | (14) | (15) | (14)
Lymph node, mediastinal | (11) | (13) | (11) | (10) | (14) | (13)
Spleen | (14) | (15) | (13) | (15) | (14) | (14)
Thymus | (12) | (14) | (12) | (13) | (14) | (12)
Integumentary System
Skin | (15) | (2) | | | (1) | (15)
Squamous cell papilloma | | 2 (100%) | | | 1 (100%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (14) | (15) | (14) | (15) | (14) | (14)
Alveolar/bronchiolar adenoma | | | 2 (14%) | 1 (7%) | 2 (14%) | 2 (14%)
Special Senses System
Harderian gland | (15) | | | | | (15)
Adenoma | | | | | | 1 (7%)
Zymbal’s gland | (14) | | | | (1) | (14)
Carcinoma | | | | | 1 (100%)
Urinary System
Kidney | (15) | (15) | (13) | (15) | (14) | (15)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15) | (15) | (15)
Leukemia erythrocytic | 1 (7%) | | 1 (7%) | 2 (13%)
Lymphoma malignant | | | 1 (7%) | | | 1 (7%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 10 | 9 | 7 | 8 | 11 | 11
Total primary neoplasms | 12 | 11 | 10 | 10 | 13 | 17
Total animals with benign neoplasms | 8 | 6 | 3 | 5 | 8 | 8
Total benign neoplasms | 8 | 7 | 4 | 6 | 9 | 9
Total animals with malignant neoplasms | 1 | | 4 | 2 | 2 | 2
Total malignant neoplasms | 1 | | 4 | 2 | 2 | 2
Total animals with uncertain neoplasms-benign or malignant | 3 | 4 | 2 | 2 | 2 | 6
Total uncertain neoplasms | 3 | 4 | 2 | 2 | 2 | 6

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A2

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame: 0 ppm

Number of Days on Study | 0 | 1 | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 7 | 8 | 9 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 6 | 3 | 7 | 1 | 1 | 1 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | Total Tissues/Tumors
Carcass ID Number | 0 | 1 | 1 | 0 | 1 | 1 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 4 | 4 | 5 | 6 | 2 | 3 | 1 | 2 | 3 | 5 | 7 | 8 | 9 | 0 | 1 | Total Tissues/Tumors
Alimentary System
Esophagus | + | A | + | + | + | + | + | + | + | + | + | + | + | M | + | 13
Gallbladder | A | A | A | + | + | + | + | + | + | M | + | + | M | + | + | 10
Intestine large, colon | A | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 12
Intestine large, rectum | A | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 12
Intestine large, cecum | A | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 12
Intestine small, duodenum | A | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 12
Intestine small, jejunum | A | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 12
Intestine small, ileum | A | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 12
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pancreas | + | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 13
Salivary glands | + | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 13
Stomach, forestomach | A | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 12
Squamous cell papilloma | | | | | | | X | | | | | X | X | X | | 4
Squamous cell papilloma, multiple | | | | X | X | X | | X | | | | | | | | 4
Stomach, glandular | A | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 12
Tongue | + | A | A | + | + | M | + | + | + | + | + | + | + | + | + | 12
Tooth | + | | | + | + | + | | | | | | | | | | 4
Odontogenic tumor | X | | | | X | X | | | | | | | | | | 3
Cardiovascular System
Blood vessel | + | A | A | + | + | + | + | + | + | + | + | + | + | M | + | 12
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 13
Adrenal medulla | + | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 13
Islets, pancreatic | + | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 13
Parathyroid gland | + | A | A | + | M | M | + | M | + | M | I | M | M | + | M | 5
Pituitary gland | I | A | A | + | + | + | + | + | + | + | + | + | I | I | I | 9
Thyroid gland | A | M | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Preputial gland | + | A | A | + | + | + | + | + | + | + | + | M | + | + | + | 12
Prostate | + | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 13
Seminal vesicle | + | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 13
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Bone marrow | + | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mandibular | + | A | M | + | + | + | + | + | + | M | + | + | + | + | + | 12
Lymph node, mesenteric | + | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 13
Lymph node, mediastinal | + | M | A | + | I | I | + | + | + | + | + | + | + | + | + | 11
Spleen | + | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Thymus | A | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 12
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Musculoskeletal System
Bone | + | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 13
Skeletal muscle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Larynx | I | A | A | I | M | I | + | I | I | I | + | I | + | M | M | 3
Lung | + | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Nose | + | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Trachea | + | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 13
Special Senses System
Eye | A | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 12
Harderian gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Zymbal’s gland | + | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary bladder | + | A | A | + | + | + | + | + | + | + | + | + | + | + | + | 13
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Leukemia erythrocytic | | | X | | | | | | | | | | | | | 1

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame: 3,125 ppm

Number of Days on Study | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 9 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 8 | 1 | 1 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | Total Tissues/Tumors
Carcass ID Number | 2 | 2 | 2 | 1 | 1 | 1 | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 3 | Total Tissues/Tumors
Carcass ID Number | 9 | 4 | 5 | 6 | 7 | 8 | 9 | 0 | 1 | 2 | 3 | 6 | 7 | 8 | 0 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | | | | | | | | | X | | | | 1
Squamous cell papilloma, multiple | | | | | | | X | X | | X | | | | | X | 4
Stomach, glandular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Tooth | + | + | + | | | | | + | | | | | | | | 4
Odontogenic tumor | X | X | X | | | | | X | | | | | | | | 4
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | I | + | + | + | M | + | + | + | + | + | + | + | + | 13
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Penis | + | | | | | | | | | | | | | | | 1
Preputial gland | | | | | | | | | | | | + | | | | 1
Prostate | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mediastinal | + | + | + | + | + | + | + | + | + | + | + | M | + | M | + | 13
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | M | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Skin | | | | | | | | | + | | | | | | + | 2
Squamous cell papilloma | | | | | | | | | X | | | | | | X | 2
Musculoskeletal System
None
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame: 6,250 ppm

Number of Days on Study | 0 | 1 | 1 | 1 | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 7 | 3 | 3 | 5 | 9 | 0 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 8 | 2 | 8 | 0 | 7 | 7 | 1 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | Total Tissues/Tumors
Carcass ID Number | 3 | 3 | 4 | 3 | 3 | 4 | 3 | 3 | 3 | 3 | 3 | 4 | 4 | 4 | 4 | Total Tissues/Tumors
Carcass ID Number | 9 | 3 | 3 | 7 | 4 | 2 | 1 | 2 | 5 | 6 | 8 | 0 | 1 | 4 | 5 | Total Tissues/Tumors
Alimentary System
Liver | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Salivary glands | | | + | | | + | | | | | | | | | | 2
Duct, carcinoma | | | X | | | X | | | | | | | | | | 2
Stomach, forestomach | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Squamous cell papilloma | | | | | | | | | | | | | | | X | 1
Squamous cell papilloma, multiple | | | | | | | X | | | | | | | | | 1
Stomach, glandular | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Tooth | | | | | | | + | + | | | | | | | | 2
Odontogenic tumor | | | | | | | X | X | | | | | | | | 2
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Adrenal medulla | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Pituitary gland | A | M | M | I | + | + | I | + | + | + | I | M | I | I | + | 6
Thyroid gland | M | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
General Body System
None
Genital System
Coagulating gland | | | | | | | | | | | | | | | + | 1
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Preputial gland | | | | | | | | | | + | | | | | | 1
Prostate | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node, mandibular | A | + | + | + | + | + | + | + | + | + | + | M | + | + | + | 13
Lymph node, mesenteric | A | + | + | M | + | + | + | + | + | + | + | + | + | + | + | 13
Lymph node, mediastinal | M | M | + | + | + | + | M | M | + | + | + | + | + | + | + | 11
Spleen | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Thymus | M | M | + | + | + | M | + | + | + | + | + | + | + | + | + | 12
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Musculoskeletal System
None
Nervous System
Brain | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Respiratory System
Lung | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Alveolar/bronchiolar adenoma | | | | | | | | | | | | | X | | X | 2
Special Senses System
None
Urinary System
Kidney | A | A | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Leukemia erythrocytic | | | | | X | | | | | | | | | | | 1
Lymphoma malignant | | | | | | | X | | | | | | | | | 1

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame: 12,500 ppm

Number of Days on Study | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 9 | 0 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 9 | 6 | 1 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | Total Tissues/Tumors
Carcass ID Number | 5 | 5 | 4 | 4 | 4 | 4 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 6 | Total Tissues/Tumors
Carcass ID Number | 8 | 0 | 6 | 7 | 8 | 9 | 1 | 2 | 3 | 4 | 5 | 6 | 7 | 9 | 0 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Squamous cell papilloma | | | | | | X | | X | | | X | | | | | 3
Squamous cell papilloma, multiple | | | X | X | | | | | | | | | | | | 2
Stomach, glandular | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Tooth | | | + | | | | | | | + | | | | | | 2
Odontogenic tumor | | | X | | | | | | | X | | | | | | 2
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Adrenal medulla | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Pituitary gland | M | + | + | + | I | + | + | I | + | + | I | + | + | + | + | 11
Thyroid gland | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Prostate | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Hematopoietic System
Lymph node, mandibular | + | M | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mesenteric | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mediastinal | + | + | + | + | + | M | + | M | M | + | I | + | + | + | M | 10
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | A | M | + | + | + | + | + | + | + | + | + | + | + | + | + | 13
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Musculoskeletal System
None
Nervous System
Brain | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Alveolar/bronchiolar adenoma | | | | X | | | | | | | | | | | | 1
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Leukemia erythrocytic | X | X | | | | | | | | | | | | | | 2

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame: 25,000 ppm

Number of Days on Study | 0 | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 9 | 3 | 3 | 6 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 6 | 8 | 9 | 1 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | Total Tissues/Tumors
Carcass ID Number | 6 | 7 | 6 | 7 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 7 | 7 | 7 | 7 | Total Tissues/Tumors
Carcass ID Number | 1 | 5 | 8 | 2 | 2 | 3 | 4 | 5 | 6 | 7 | 9 | 0 | 1 | 3 | 4 | Total Tissues/Tumors
Alimentary System
Liver | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Salivary glands | | + | + | | | | | | | | | | | | | 2
Duct, carcinoma | | X | | | | | | | | | | | | | | 1
Stomach, forestomach | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Squamous cell papilloma | | | | | | | | | X | | | X | X | X | | 4
Squamous cell papilloma, multiple | | | | | X | X | | | | | | | | | | 2
Stomach, glandular | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Tooth | | | | + | + | | | | | | | | | | | 2
Odontogenic tumor | | | | X | X | | | | | | | | | | | 2
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | A | + | + | + | + | + | M | + | + | + | + | + | + | + | + | 13
Thyroid gland | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Prostate | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Seminal vesicle | | | | | | | + | | | | | | | | | 1
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node, mandibular | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mediastinal | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Spleen | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Thymus | I | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Skin | | | | | | | | + | | | | | | | | 1
Squamous cell papilloma | | | | | | | | X | | | | | | | | 1
Musculoskeletal System
None
Nervous System
Brain | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Respiratory System
Lung | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Alveolar/bronchiolar adenoma | | | | | | | | | | | | | | X | X | 2
Special Senses System
Zymbal’s gland | | | + | | | | | | | | | | | | | 1
Carcinoma | | | X | | | | | | | | | | | | | 1
Urinary System
Kidney | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame: 50,000 ppm

Number of Days on Study | 1 | 1 | 1 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2 | 2
Number of Days on Study | 4 | 8 | 8 | 0 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Number of Days on Study | 1 | 0 | 0 | 0 | 1 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4
Carcass ID Number | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | Total Tissues/Tumors
Carcass ID Number | 8 | 8 | 9 | 8 | 8 | 7 | 7 | 7 | 7 | 8 | 8 | 8 | 8 | 8 | 8 | Total Tissues/Tumors
Carcass ID Number | 9 | 4 | 0 | 0 | 3 | 6 | 7 | 8 | 9 | 1 | 2 | 5 | 6 | 7 | 8 | Total Tissues/Tumors
Alimentary System
Esophagus | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Gallbladder | A | + | + | + | + | M | + | M | + | + | + | + | + | + | + | 12
Intestine large, colon | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine large, rectum | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine large, cecum | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine small, duodenum | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine small, jejunum | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Intestine small, ileum | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pancreas | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Salivary glands | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Duct, carcinoma | | | | | X | | | | | | | | | | | 1
Stomach, forestomach | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Squamous cell papilloma | | X | | | | | X | X | X | | | | | X | | 5
Squamous cell papilloma, multiple | | | | | | | | | | | | | X | | | 1
Stomach, glandular | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Tongue | A | + | + | + | + | + | + | + | + | + | + | + | M | + | + | 13
Tooth | | + | + | + | + | | | | + | | | | + | | | 6
Odontogenic tumor | | X | X | X | X | | | | X | | | | X | | | 6
Cardiovascular System
Blood vessel | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | A | + | + | + | + | + | + | + | + | + | + | + | + | + | I | 13
Adrenal medulla | A | + | + | + | + | + | + | + | + | + | + | + | + | + | M | 13
Islets, pancreatic | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Parathyroid gland | A | M | M | M | + | M | + | M | M | + | M | M | M | M | + | 4
Pituitary gland | A | + | I | M | + | + | + | I | + | + | + | + | I | + | I | 9
Thyroid gland | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
General Body System
None
Genital System
Coagulating gland | | | | | | | | | | | | + | | | | 1
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Penis | | | | + | | | | | | | | | | | | 1
Preputial gland | A | + | + | + | + | + | + | M | + | + | + | + | M | + | + | 12
Prostate | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Seminal vesicle | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Bone marrow | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mandibular | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mesenteric | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mediastinal | A | + | M | + | + | + | + | + | + | + | + | + | + | + | + | 13
Spleen | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Thymus | A | M | M | + | + | + | + | + | + | + | + | + | + | + | + | 12
Integumentary System
Mammary gland | M | M | M | M | M | M | M | M | M | M | M | M | M | M | M
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Musculoskeletal System
Bone | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Skeletal muscle | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Nervous System
Brain | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Respiratory System
Larynx | M | M | M | M | M | + | M | M | + | I | M | M | M | M | M | 2
Lung | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Alveolar/bronchiolar adenoma | | | | | | X | | | | X | | | | | | 2
Nose | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Trachea | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Special Senses System
Eye | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Harderian gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adenoma | | | | | | X | | | | | | | | | | 1
Zymbal’s gland | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary bladder | A | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymphoma malignant | | | | X | | | | | | | | | | | | 1

+: Tissue examined microscopically | M: Missing tissue | X: Lesion present
A: Autolysis precludes examination | I: Insufficient tissue | Blank: Not examined

TABLE A3 Statistical Analysis of Primary Neoplasms in Male Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Lung: Alveolar/bronchiolar Adenoma
Overall rate^a^ | 0/14 (0%) | 0/15 (0%) | 2/14 (14%) | 1/15 (7%) | 2/14 (14%) | 2/14 (14%)
Adjusted rate^b^ | 0.0% | 0.0% | 19.7% | 7.3% | 15.8% | 16.8%
Terminal rate^c^ | 0/9 (0%) | 0/12 (0%) | 2/8 (25%) | 1/12 (8%) | 2/11 (18%) | 2/10 (20%)
First incidence (days) | —^e^ | — | 274 (T) | 274 (T) | 274 (T) | 274 (T)
Poly-3 test^d^ | P=0.098 | —^f^ | P=0.187 | P=0.523 | P=0.236 | P=0.222
Salivary Glands: Carcinoma
Overall rate | 0/15 (0%) | 0/15 (0%) | 2/15 (13%) | 0/15 (0%) | 1/15 (7%) | 1/15 (7%)
Adjusted rate | 0.0% | 0.0% | 17.2% | 0.0% | 7.4% | 8.3%
Terminal rate | 0/9 (0%) | 0/12 (0%) | 0/8 (0%) | 0/12 (0%) | 0/11 (0%) | 0/10 (0%)
First incidence (days) | — | — | 138 | — | 138 | 271
Poly-3 test | P=0.326 | — | P=0.211 | — | P=0.515 | P=0.492
Skin: Squamous Cell Papilloma
Overall rate | 0/15 (0%) | 2/15 (13%) | 0/15 (0%) | 0/15 (0%) | 1/15 (7%) | 0/15 (0%)
Adjusted rate | 0.0% | 14.0% | 0.0% | 0.0% | 7.9% | 0.0%
Terminal rate | 0/9 (0%) | 2/12 (17%) | 0/8 (0%) | 0/12 (0%) | 1/11 (9%) | 0/10 (0%)
First incidence (days) | — | 274 (T) | — | — | 274 (T) | —
Poly-3 test | P=0.404N | P=0.261 | — | — | P=0.502 | —
Stomach (Forestomach): Squamous Cell Papilloma
Overall rate | 8/15 (53%) | 5/15 (33%) | 2/15 (13%) | 5/15 (33%) | 6/15 (40%) | 6/15 (40%)
Adjusted rate | 63.0% | 34.9% | 19.6% | 36.2% | 47.3% | 47.0%
Terminal rate | 5/9 (56%) | 5/12 (42%) | 1/8 (13%) | 4/12 (33%) | 6/11 (55%) | 5/10 (50%)
First incidence (days) | 271 | 274 (T) | 271 | 271 | 274 (T) | 180
Poly-3 test | P=0.456 | P=0.139N | P=0.039N | P=0.157N | P=0.344N | P=0.338N
Tooth: Odontogenic Tumor
Overall rate | 3/15 (20%) | 4/15 (27%) | 2/15 (13%) | 2/15 (13%) | 2/15 (13%) | 6/15 (40%)
Adjusted rate | 22.0% | 26.7% | 19.6% | 14.5% | 15.6% | 42.4%
Terminal rate | 0/9 (0%) | 1/12 (8%) | 1/8 (13%) | 1/12 (8%) | 1/11 (9%) | 2/10 (20%)
First incidence (days) | 76 | 198 | 271 | 271 | 261 | 180
Poly-3 test | P=0.128 | P=0.556 | P=0.635N | P=0.494N | P=0.529N | P=0.230
All Organs: Erythrocytic Leukemia
Overall rate | 1/15 (7%) | 0/15 (0%) | 1/15 (7%) | 2/15 (13%) | 0/15 (0%) | 0/15 (0%)
Adjusted rate | 7.6% | 0.0% | 9.2% | 13.4% | 0.0% | 0.0%
Terminal rate | 0/9 (0%) | 0/12 (0%) | 0/8 (0%) | 0/12 (0%) | 0/11 (0%) | 0/10 (0%)
First incidence (days) | 197 | — | 197 | 199 | — | —
Poly-3 test | P=0.296N | P=0.484N | P=0.716 | P=0.544 | P=0.508N | P=0.518N
All Organs: Benign Neoplasms
Overall rate | 8/15 (53%) | 6/15 (40%) | 3/15 (20%) | 5/15 (33%) | 8/15 (53%) | 8/15 (53%)
Adjusted rate | 63.0% | 41.9% | 29.3% | 36.2% | 63.0% | 62.6%
Terminal rate | 5/9 (56%) | 6/12 (50%) | 2/8 (25%) | 4/12 (33%) | 8/11 (73%) | 7/10 (70%)
First incidence (days) | 271 | 274 (T) | 271 | 271 | 274 (T) | 180
Poly-3 test | P=0.167 | P=0.239N | P=0.111N | P=0.157N | P=0.659N | P=0.651N
All Organs: Malignant Neoplasms
Overall rate | 1/15 (7%) | 0/15 (0%) | 4/15 (27%) | 2/15 (13%) | 2/15 (13%) | 2/15 (13%)
Adjusted rate | 7.6% | 0.0% | 32.5% | 13.4% | 14.4% | 15.7%
Terminal rate | 0/9 (0%) | 0/12 (0%) | 0/8 (0%) | 0/12 (0%) | 0/11 (0%) | 0/10 (0%)
First incidence (days) | 197 | — | 138 | 199 | 138 | 200
Poly-3 test | P=0.371 | P=0.484N | P=0.136 | P=0.544 | P=0.518 | P=0.486
All Organs: Benign or Malignant Neoplasms
Overall rate | 10/15 (67%) | 9/15 (60%) | 7/15 (47%) | 8/15 (53%) | 11/15 (73%) | 11/15 (73%)
Adjusted rate | 69.9% | 60.0% | 56.9% | 53.3% | 78.3% | 77.8%
Terminal rate | 5/9 (56%) | 6/12 (50%) | 3/8 (38%) | 5/12 (42%) | 8/11 (73%) | 7/10 (70%)
First incidence (days) | 76 | 198 | 138 | 199 | 138 | 180
Poly-3 test | P=0.146 | P=0.432N | P=0.387N | P=0.296N | P=0.468 | P=0.480

(T) Terminal sacrifice

a Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for lung; for other tissues, denominator is number of animals necropsied.

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal sacrifice. A negative trend or a lower incidence in an exposed group is indicated by N.

e Not applicable; no neoplasms in animal group

f Value of statistic cannot be computed.

TABLE A4 Summary of the Incidence of Nonneoplastic Lesions in Male Tg.AC Hemizygous Mice in the 9-Month Feed Study of Aspartame^a^

| 0 ppm | 3,125 ppm | 6,250 ppm | 12,500 ppm | 25,000 ppm | 50,000 ppm
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | 3 | 3 | 4 | 2 | 3 | 4
Natural deaths | 3 | | 3 | 1 | 1 | 1
Survivors
Terminal sacrifice | 9 | 12 | 8 | 12 | 11 | 10
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (14) | (15) | (14) | (15)
Hematopoietic cell proliferation | | | | 1 (7%) | | 1 (7%)
Infiltration cellular, focal, lymphocyte | 1 (7%) | | | | | 1 (7%)
Inflammation, acute, focal | 1 (7%)
Necrosis, focal | | | | | | 2 (13%)
Stomach, forestomach | (12) | (15) | (13) | (14) | (14) | (14)
Epithelium, hyperplasia | 1 (8%)
Stomach, glandular | (12) | (15) | (13) | (14) | (14) | (14)
Inflammation, acute | | | | | | 1 (7%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (13) | (15) | (13) | (14) | (15) | (13)
Atrophy | 10 (77%) | 12 (80%) | 8 (62%) | 9 (64%) | 8 (53%) | 6 (46%)
Hypertrophy, focal | 9 (69%) | 5 (33%) | 5 (38%) | 6 (43%) | 7 (47%) | 5 (38%)
Subcapsular, hyperplasia, focal | | | | | | 1 (8%)
Thyroid gland | (13) | (15) | (13) | (14) | (14) | (14)
Follicle, cyst | 2 (15)%)
General Body System
None
Genital System
Coagulating gland | | | (1) | | | (1)
Cyst | | | 1 (100%)
Epididymis | (15) | (15) | (15) | (15) | (15) | (15)
Bilateral, aspermia | | 1 (7%)
Bilateral, spermatozoa, degeneration | | | | 1 (7%) | | 1 (7%)
Unilateral, aspermia | 1 (7%) | 3 (20%) | 4 (27%) | 2 (13%) | 3 (20%) | 2 (13%)
Unilateral, cyst | 1 (7%) | | 1 (7%) | | | 1 (7%)
Unilateral, inflammation, chronic active | | | 2 (13%)
Unilateral, duct, hyperplasia, regenerative | 1 (7%) | | | | 1 (7%)
Unilateral, spermatozoa, degeneration | | | | | | 1 (7%)
Preputial gland | (12) | (1) | (1) | | | (12)
Cyst | 1 (8%) | 1 (100%) | 1 (100%)
Prostate | (13) | (15) | (15) | (15) | (15) | (14)
Inflammation, acute, focal | | 1 (7%)
Seminal vesicle | (13) | | | | (1) | (14)
Dilatation | | | | | 1 (100%)
Testes | (15) | (15) | (15) | (14) | (15) | (15)
Cyst | | | 1 (7%) | 1 (7%) | 1 (7%)
Bilateral, germinal epithelium, degeneration | | 2 (13%) | | 1 (7%) | | 1 (7%)
Unilateral, cyst | 1 (7%) | 2 (13%) | 3 (20%) | 2 (14)%) | 2 (13%) | 1 (7%)
Unilateral, germinal epithelium, degeneration | 1 (7%) | 2 (13%) | 4 (27%) | 2 (14)%) | 3 (20%) | 3 (20%)
Hematopoietic System
Bone marrow | (14) | | | | | (14)
Hyperplasia | | | | | | 2 (14%)
Lymph node, mandibular | (12) | (15) | (13) | (14) | (14) | (14)
Hyperplasia | | 2 (13%) | | 2 (14)%)
Hyperplasia, plasma cell | 1 (8%) | | | | | 1 (7%)
Necrosis | 2 (17%)
Lymph node, mesenteric | (13) | (15) | (13) | (14) | (15) | (14)
Hyperplasia | | | 1 (8%)
Necrosis | 1 (8%)
Lymph node, mediastinal | (11) | (13) | (11) | (10) | (14) | (13)
Hyperplasia | | | | 1 (10%)
Spleen | (14) | (15) | (13) | (15) | (14) | (14)
Hematopoietic cell proliferation | 3 (21%) | 3 (20%) | 8 (62%) | 2 (13%) | 8 (57%) | 4 (29%)
Pigmentation | 9 (64%) | 12 (80%) | 8 (62%) | 12 (80%) | 13 (93%) | 11 (79%)
Lymphoid follicle, depletion cellular | | 1 (7%)
Thymus | (12) | (14) | (12) | (13) | (14) | (12)
Atrophy, diffuse | 1 (8%) | | 1 (8%) | | 4 (29%)
Atrophy, focal | | | | 1 (8%) | 2 (14)%) | 2 (17%)
Integumentary System
Skin | (15) | (2) | | | (1) | (15)
Control epidermis, hyperplasia, focal | | | | | 1 (100%)
Musculoskeletal System
None
Nervous System
Brain | (15) | (15) | (13) | (14) | (14) | (15)
Cortex, cerebrum, degeneration, focal | | | | | | 1 (7%)
Respiratory System
Lung | (14) | (15) | (14) | (15) | (14) | (14)
Hemorrhage, focal | | 3 (20%) | | | 1 (7%)
Alveolar epithelium, hyperplasia, focal | | | | | | 1 (7%)
Special Senses System
Eye | (12) | | | | | (14)
Retina, atrophy | 12 (100%) | | | | | 14 (100%)
Urinary System
Kidney | (15) | (15) | (13) | (15) | (14) | (15)
Dilatation, diffuse | | | 1 (8%)
Nephropathy | 3 (20%) | | | | | 1 (7%)
Renal tubule, cyst | | | | | | 1 (7%)
Renal tubule, dilatation, diffuse | | | | 1 (7%) | | 1 (7%)
Renal tubule, dilatation, focal | 1 (7%) | | 1 (8%)

a Number of animals examined microscopically at the site and the number of animals with lesion