# Explanation of Levels of Evidence for Reproductive Toxicity

The National Toxicology Program (NTP) describes the results of individual studies of chemical agents and other test articles and notes the strength of the evidence for conclusions regarding each study. Generally, each study is confined to a single laboratory animal species, although in some instances, multiple species may be investigated under the purview of a single study report. Negative results, in which the study animals do not exhibit evidence of reproductive toxicity, do not necessarily imply that the test article is not a reproductive toxicant, but only that exposure to the test article did not result in reproductive toxicity under the specific conditions of this study. Positive results demonstrating that the test article causes reproductive toxicity in laboratory animals under the study conditions are assumed relevant to humans, unless data are available that demonstrate otherwise. In addition, such positive effects are assumed to be primary effects, unless there is clear evidence that they are secondary consequences of excessive toxicity to nonreproductive organ systems. Given that developmental events are interrelated in the reproductive process, developmental toxicity may be detected in reproductive studies. Evaluation of such adverse effects on development should be based on the criteria outlined in the Levels of Evidence for Evaluating Developmental Toxicity.

It is critical to recognize that the “level-of-evidence” categories herein only identify whether exposure to the test article is a reproductive hazard. The determination of any risk to humans from the test article requires data on human exposure and is not part of hazard identification.

Five categories are used to differentiate the strength of the evidence for reproductive toxicity observed in each experiment: two categories for positive results (clear evidence and some evidence); one category for uncertain findings (equivocal evidence); one category for no observable effects (no evidence); and one category for experiments that cannot be evaluated because of major design or performance flaws (inadequate study). Application of these criteria requires professional judgment by individuals with ample experience and understanding of the animal models and study designs employed. For each study, the findings are evaluated to determine the appropriate level-of-evidence category and a conclusion statement is prepared that describes the findings supporting that category. Separate conclusion statements may be prepared for males and females. The level-of-evidence categories refer to the strength of the evidence of the experimental results and not to potency or mechanism.

Levels of Evidence for Evaluating Reproductive Toxicity

- Clear evidence of reproductive toxicity is demonstrated by data that indicate an exposure-related effect of the test article on fertility or fecundity, or by changes in multiple interrelated reproductive parameters of sufficient magnitude that by weight of evidence implies a compromise in reproductive function.
- Some evidence of reproductive toxicity is demonstrated by data that indicate exposure-related effects of the test article on reproductive parameters, the outcome of which is judged by weight of evidence to have potential to compromise reproductive function. Relative to clear evidence of reproductive toxicity, such effects would be characterized by greater uncertainties or weaker relationships with regard to dose of test article and/or the severity, magnitude, incidence, persistence, and/or decreased concordance among affected endpoints.
- Equivocal evidence of reproductive toxicity is demonstrated by marginal or discordant effects on reproductive parameters that may or may not be related to exposure to the test article.
- No evidence of reproductive toxicity is demonstrated by data from a study with appropriate experimental design and conduct that are interpreted as showing no biologically relevant effects on reproductive parameters related to exposure to the test article.
- Inadequate study of reproductive toxicity is demonstrated by a study that, because of major design or performance flaws, cannot be used to determine the occurrence of reproductive toxicity.

Note: The term exposure-related describes any exposure-response relationship, recognizing that the test article-related responses for some endpoints may be non-monotonic due to saturation of exposure or effect, overlapping exposure-response behaviors, changes in immunologic manifestations at different exposure levels, or other phenomena.

When the level-of-evidence category for a particular study is selected, consideration must be given to key factors that would support that selection. Such consideration should allow for incorporating scientific experience and current understanding of reproductive toxicity studies in laboratory animals, particularly with respect to interrelationships between endpoints, impact of changes on reproductive function, relative sensitivity of endpoints, normal background incidence, and specificity of the effect. For evaluations for which it is difficult to choose between adjacent level-of-evidence categories, the following factors should be considered to help inform decision-making:

- Increases in severity and/or prevalence (more individuals and/or more affected litters) as a function of dose of the test article generally strengthens the level of evidence, keeping in mind that the specific manifestation of effect may be different with increasing dose. For example, histological changes at a lower dose may reflect reductions in fertility at higher doses.
- In general, the more animals affected, the stronger the evidence; however, effects in a small number of animals across multiple, related endpoints should not be discounted, even in the absence of statistical significance. In addition, effects with low background incidence, when interpreted in the context of historical controls, may be biologically important.
- Consistency of effects across generations in a multigenerational study may support a higher level of evidence. However, special consideration should be given when decrements in reproductive outcomes are found in the F_1_ generation that were not seen in the F_0_ generation, as this may suggest both developmental and reproductive toxicity. Alternatively, if effects are observed in the F_1_ generation and not in in the F_2_ generation (or the effects occur at a lower frequency in the F_2_ generation), this outcome may be due to survivor selection for resistance to the effect (i.e., if the effect is incompatible with successful reproduction or development, then the affected individuals will not produce offspring).
- Transient changes (e.g., pup weight decrements) by themselves may be weaker indicators of an effect than persistent changes.
- Changes in single endpoints by themselves may be weaker indicators of an effect than concordant effects on multiple, interrelated endpoints.
- Marked changes in multiple reproductive tract endpoints without effects on integrated reproductive function (i.e., fertility and fecundity) may be sufficient to reach a conclusion of clear evidence of reproductive toxicity.
- Insights from supportive studies (e.g., toxicokinetics, computational models, structure-activity relationships, and studies of absorption, distribution, metabolism, and excretion) and reproductive findings from other in vivo animal studies (conducted by NTP or others) should be drawn upon when interpreting the biological plausibility of an effect.
- New assays or techniques need to be characterized appropriately to build confidence in their utility. Their usefulness as indicators of effect is increased if they are associated with changes in traditional endpoints.

For more information visit: https://ntp.niehs.nih.gov/go/10003.