# Peer Review

The National Toxicology Program (NTP) conducted a peer review of the draft NTP Developmental and Reproductive Toxicity Technical Report on the Modified One-Generation Study of Bisphenol AF (CASRN 1478-61-1) Administered in Feed to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats with Prenatal, Reproductive Performance, and Subchronic Assessments in F_1_ Offspring by letter in December 2021 and January 2022 by the experts listed below. Reviewer selection and document review followed established NTP practices. The reviewers were charged to:

1. Review and evaluate the scientific and technical elements of the study and its presentation.
2. Determine whether the study’s experimental design, conduct, and findings support NTP’s conclusions under the conditions of this study.

NTP carefully considered reviewer comments in finalizing this report.

## Peer Reviewers

- Susan Laffan, Ph.D.
  Senior Director, Head of Global Investigative Safety
  GlaxoSmithKline
  Berwyn, Pennsylvania, USA
- Linda Roberts, Ph.D., DABT
  Principal
  NapaTox Consulting LLC
  Napa, California, USA
- Daniel Spade, Ph.D.
  Assistant Professor, Department of Pathology and Laboratory
  Brown University
  Providence, Rhode Island, USA