# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Designed studies, evaluated and interpreted results, and reported findings
  V.L. Sutherland, Ph.D., Study Scientist
  S.A. Elmore, D.V.M., M.S., Study Pathologist
  C.R. Blystone, Ph.D.
  M.F. Cesta, D.V.M., Ph.D.
  B.J. Collins, M.S.P.H.
  M.C. Cora, D.V.M.
  H.C. Cunny, Ph.D.
  P.M.D. Foster, Ph.D. (Retired)
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D. (Retired)
  D.E. Malarkey, D.V.M., Ph.D. (Retired)
  B.S. McIntyre, Ph.D.
  G.K. Roberts, Ph.D.
  K.A. Shipkowski, Ph.D.
  K.R. Shockley, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Provided oversight for data management
  J.M. Fostel, Ph.D.
- RTI International, Research Triangle Park, North Carolina, USA
  Conducted studies and evaluated findings
  R.W. Tyl, Ph.D., Principal Investigator
  M. Marr, B.A.
  C.S. Sloan, M.S.
  K.J. Turner, Ph.D.
- Prepared and analyzed dose formulations
  J.C. Blake, B.A.
  R.A. Fernando, Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Conducted studies and evaluated pathology findings
  J.C. Seely, D.V.M.
- MRIGlobal, Kansas City, Missouri, USA
  Conducted prestart chemistry activities and dose formulation analyses
  J.W. Algaier, Ph.D., Principal Investigator
  K.L. Aillon, Ph.D.
  M. Kroenke, B.S.
  L. Siemann, B.S.
  W.R. Vandaveer, Ph.D.
- Charles River Laboratories, Inc., Durham, North Carolina, USA
  Provided pathology review
  C.L. Johnson, D.V.M.
- Coordinated NTP Pathology Working Groups on the modified one-generation study (January 15, 2019 and March 26, 2019)
  C.L. Johnson, D.V.M.
- Social & Scientific Systems, a DLH Company, Research Triangle Park, North Carolina, USA
  Provided statistical analyses
  S. McBride, Ph.D., Principal Investigator
  L.J. Betz, M.S.
- ASRC Federal, Research Triangle Park, North Carolina, USA
  Prepared data for report
  P. Brown, B.S.
  H. Gong, M.S.
  C. Martini, B.S.
  C. Myers, M.S.
  N. Sayers, B.S.
- ICF, Fairfax, Virginia, USA
  Contributed to technical writing and data integration and ensured report quality
  J. Luh, Ph.D.