# References

1 Choi YJ, Lee LS. Partitioning behavior of bisphenol alternatives BPS and BPAF compared to BPA. Environ Sci Technol. 2017; 51(7):3725–3732.28274112
2 U.S. Environmental Protection Agency (USEPA). CompTox Chemicals Dashboard: Bisphenol AF | 1478-61-1 | DTXSID7037717. U.S. Environmental Protection Agency; 2020. https://comptox.epa.gov/dashboard/dsstoxdb/results?search=DTXSID7037717
3 Mark V, Hedges CV. Fluorinated monophenols and diphenols and method for their preparation. General Electric Company; 1982. Patent Number 4,358,624. https://www.freepatentsonline.com/4358624.pdf
4 DuPont. Technical information: Bisphenol AF, 4,4’-(hexafluoroisopropylidene)diphenol Wilmington, DE: DuPont Performance Elastomers L.L.C; 2006.
5 Datta RN. Rubber curing systems. Rapra Technologies; 2001. Rapra Review Report, 144.
6 Honeywell. Bisphenol AF. No Date. http://www51.honeywell.com/sm/specialtychemicals/ofc/products-n2/bisphenol-af-n3/bisphenol-af.html?c=21
7 Environment Canada. Screening assessment for the challenge phosphonium, triphenyl(phenylmethyl)-, salt with 4,4'-[2,2,2-trifluoro-1-(trifluoromethyl)ethylidene]bis[phenol] (1:1). Chemical Abstracts Service Registry Number 75768-65-9. 2010.
8 Zhang H, Quan Q, Zhang M, Zhang N, Zhang W, Zhan M, Xu W, Lu L, Fan J, Wang Q. Occurrence of bisphenol A and its alternatives in paired urine and indoor dust from Chinese university students: Implications for human exposure. Chemosphere. 2020;247:125987.32069736
9 Yang Y, Guan J, Yin J, Shao B, Li H. Urinary levels of bisphenol analogues in residents living near a manufacturing plant in south China. Chemosphere. 2014;112:481–486.25048943
10 Ye X, Wong LY, Kramer J, Zhou X, Jia T, Calafat AM. Urinary concentrations of bisphenol A and three other bisphenols in convenience samples of U.S. adults during 2000-2014. Environ Sci Technol. 2015; 49(19):11834–11839.26360019
11 Husøy T, Andreassen M, Hjertholm H, Carlsen MH, Norberg N, Sprong C, Papadopoulou E, Sakhi AK, Sabaredzovic A, Dirven H. The Norwegian biomonitoring study from the EU project EuroMix: Levels of phenols and phthalates in 24-hour urine samples and exposure sources from food and personal care products. Environ Int. 2019;132:105103.31470218
12 Liu Y, Yan Z, Zhang Q, Song N, Cheng J, Torres OL, Chen J, Zhang S, Guo R. Urinary levels, composition profile and cumulative risk of bisphenols in preschool-aged children from Nanjing suburb, China. Ecotoxicol Environ Saf. 2019;172:444–450.30735977
13 Li A, Zhuang T, Shi W, Liang Y, Liao C, Song M, Jiang G. Serum concentration of bisphenol analogues in pregnant women in China. Sci Total Environ. 2020;707:136100.31863985
14 Pan Y, Deng M, Li J, Du B, Lan S, Liang X, Zeng L. Occurrence and maternal transfer of multiple bisphenols, including an emerging derivative with unexpectedly high soncentrations, in the human maternal-fetal-placental unit. Environ Sci Technol. 2020; 54(6):3476–3486.32092248
15 Jin H, Xie J, Mao L, Zhao M, Bai X, Wen J, Shen T, Wu P. Bisphenol analogue concentrations in human breast milk and their associations with postnatal infant growth. Environ Pollut. 2020;259:113779.31887597
16 Song S, Duan Y, Zhang T, Zhang B, Zhao Z, Bai X, Xie L, He Y, Ouyang JP, Huang X, et al. Serum concentrations of bisphenol A and its alternatives in elderly population living around e-waste recycling facilities in China: Associations with fasting blood glucose. Ecotoxicol Environ Saf. 2019;169:822–828.30597781
17 Code of Federal Regulations (CFR). 21(Part 177).
18 U.S. Food and Drug Administration (USFDA). Indirect additives used in food contact substances: Potassium 4,4'-(hexafluoroisopropylidene)diphenolate. 2019. https://www.accessdata.fda.gov/scripts/fdcc/index.cfm?set=IndirectAdditives&id=POTASSIUMHEXAFLUOROISOPROPYLIDENEDIPHENOLATE
19 Waidyanatha S, Mathews JM, Patel PR, Black SR, Snyder RW, Fennell TR. Disposition of bisphenol AF, a bisphenol A analogue, in hepatocytes in vitro and in male and female Harlan Sprague-Dawley rats and B6C3F1/N mice following oral and intravenous administration. Xenobiotica. 2015; 45(9):811–819.25923777
20 Waidyanatha S, Black SR, Aillon K, Collins B, Patel PR, Riordan F, Sutherland V, Robinson VG, Fernando R, Fennell TR. Toxicokinetics and bioavailability of bisphenol AF following oral administration in rodents: A dose, species, and sex comparison. Toxicol Appl Pharmacol. 2019;373:39–47.31022493
21 Li M, Yang Y, Yang Y, Yin J, Zhang J, Feng Y, Shao B. Biotransformation of bisphenol AF to its major glucuronide metabolite reduces estrogenic activity. PLoS One. 2013; 8(12):e83170.24349450
22 Waidyanatha S, Black SR, Croutch CR, Collins BJ, Silinski MAR, Kerns S, Sutherland V, Robinson VG, Aillon K, Fernando RA, et al. Comparative toxicokinetics of bisphenol S and bisphenol AF in male rats and mice following repeated exposure via feed. Xenobiotica. 2020. 10.1080/00498254.2020.1829171
23 Shi J, Yang Y, Zhang J, Feng Y, Shao B. Uptake, depuration and bioconcentration of bisphenol AF (BPAF) in whole-body and tissues of zebrafish (Danio rerio). Ecotoxicol Environ Saf. 2016;132:339–344.27362491
24 Matsushima A, Liu X, Okada H, Shimohigashi M, Shimohigashi Y. Bisphenol AF is a full agonist for the estrogen receptor ERalpha but a highly specific antagonist for ERbeta. Environ Health Perspect. 2010; 118(9):1267–1272.20427257
25 Li M, Guo J, Gao W, Yu J, Han X, Zhang J, Shao B. Bisphenol AF-induced endogenous transcription is mediated by ERα and ERK1/2 activation in human breast cancer cells. PLoS One. 2014; 9(4):e94725.24727858
26 Hashimoto Y, Moriguchi Y, Oshima H, Kawaguchi M, Miyazaki K, Nakamura M. Measurement of estrogenic activity of chemicals for the development of new dental polymers. Toxicol In Vitro. 2001; 15(4-5):421–425.11566573
27 Perez P, Pulgar R, Olea-Serrano F, Villalobos M, Rivas A, Metzler M, Pedraza V, Olea N. The estrogenicity of bisphenol A-related diphenylalkanes with various substituents at the central carbon and the hydroxy groups. Environ Health Perspect. 1998; 106(3):167–174.9449681
28 Yamasaki K, Takeyoshi M, Sawaki M, Imatanaka N, Shinoda K, Takatsuki M. Immature rat uterotrophic assay of 18 chemicals and Hershberger assay of 30 chemicals. Toxicology. 2003; 183(1):93–115.12504345
29 Umano T, Tanaka R, Yamasaki K. Endocrine-mediated effects of 4,4′-(hexafluoroisopropylidene)diphenol in SD rats, based on a subacute oral toxicity study. Arch Toxicol. 2012; 86(1):151–157.21713527
30 European Chemicals Agency (ECHA). Registration dossier: 4,4'-[2,2,2-trifluoro-1-(trifluoromethyl)ethylidene]diphenol; bisphenol AF (CAS number: 1478-61-1): Endpoint summary. 2020. https://echa.europa.eu/registration-dossier/-/registered-dossier/23236/7/9/1
31 Tucker DK, Hayes Bouknight S, Brar SS, Kissling GE, Fenton SE. Evaluation of prenatal exposure to bisphenol analogues on development and long-term health of the mammary gland in female mice. Environ Health Perspect. 2018; 126(8):087003.30102602
32 Li J, Sheng N, Cui R, Feng Y, Shao B, Guo X, Zhang H, Dai J. Gestational and lactational exposure to bisphenol AF in maternal rats increases testosterone levels in 23-day-old male offspring. Chemosphere. 2016;163:552–561.27567155
33 Halocarbon. Material safety data sheet: Bisphenol AF. 2007.
34 European Chemicals Agency (ECHA). Brief profile: 4,4'-[2,2,2-trifluoro-1-(trifluoromethyl)ethylidene]diphenol; bisphenol AF. 2020. https://echa.europa.eu/pt/brief-profile/-/briefprofile/100.014.579
35 Chen D, Kannan K, Tan H, Zheng Z, Feng YL, Wu Y, Widelka M. Bisphenol analogues other than BPA: Environmental occurrence, human exposure, and toxicity-A review. Environ Sci Technol. 2016; 50(11):5438–5453.27143250
36 Lee S, Liu X, Takeda S, Choi K. Genotoxic potentials and related mechanisms of bisphenol A and other bisphenol compounds: A comparison study employing chicken DT40 cells. Chemosphere. 2013; 93(2):434–440.23791112
37 Hercog K, Maisanaba S, Filipič M, Sollner-Dolenc M, Kač L, Žegura B. Genotoxic activity of bisphenol A and its analogues bisphenol S, bisphenol F and bisphenol AF and their mixtures in human hepatocellular carcinoma (HepG2) cells. Sci Total Environ. 2019;687:267–276.31207516
38 Mokra K, Kuźmińska-Surowaniec A, Woźniak K, Michałowicz J. Evaluation of DNA-damaging potential of bisphenol A and its selected analogs in human peripheral blood mononuclear cells (in vitro study). Food Chem Toxicol. 2017;100:62–69.27923681
39 Lei B, Xu J, Peng W, Wen Y, Zeng X, Yu Z, Wang Y, Chen T. In vitro profiling of toxicity and endocrine disrupting effects of bisphenol analogues by employing MCF-7 cells and two-hybrid yeast bioassay. Environ Toxicol. 2017; 32(1):278–289.26916392
40 Mokra K, Woźniak K, Bukowska B, Sicińska P, Michałowicz J. Low-concentration exposure to BPA, BPF and BPAF induces oxidative DNA bases lesions in human peripheral blood mononuclear cells. Chemosphere. 2018;201:119–126.29518729
41 Blystone CR, Kissling GE, Bishop JB, Chapin RE, Wolfe GW, Foster PM. Determination of the di-(2-ethylhexyl) phthalate NOAEL for reproductive development in the rat: Importance of the retention of extra animals to adulthood. Toxicol Sci. 2010; 116(2):640–646.20484383
42 U.S. Environmental Protection Agency (USEPA). Guidelines for developmental toxicity risk assessment. Washington, DC: U.S. Environmental Protection Agency, Risk Assessment Forum; 1991. EPA Document No. EPA/600/FR-91/001.
43 Makris SL, Solomon HM, Clark R, Shiota K, Barbellion S, Buschmann J, Ema M, Fujiwara M, Grote K, Hazelden KP. Terminology of developmental abnormalities in common laboratory mammals (version 2). Congenit Anom (Kyoto). 2009; 49(3):123–246.20002907
44 Waidyanatha S, Collins BJ, Cunny H, Aillon K, Riordan F, Turner K, McBride S, Betz L, Sutherland V. An investigation of systemic exposure to bisphenol AF during critical periods of development in the rat. Toxicol Appl Pharmacol. 2021;411:115369.33338515
45 Cora MC, Kooistra L, Travlos G. Vaginal cytology of the laboratory rat and mouse: Review and criteria for the staging of the estrous cycle using stained vaginal smears. Toxicol Pathol. 2015; 43(6):776–793.25739587
46 Staples RE. Detection of visceral alterations in mammalian fetuses. Teratology. 1974; 9(3):A37–A38.
47 Stuckhardt JL, Poppe SM. Fresh visceral examination of rat and rabbit fetuses used in teratogenicity testing. Teratog Carcinog Mutagen. 1984; 4(2):181–188.6145223
48 Thompson R. Foundations of Physiological Psychology. New York, NY: Harper and Row Publishers; 1967. Chapter 4, Basic neuroanatomy; p. 79–82.
49 Marr MC, Price CJ, Myers CB, Morrissey RE. Developmental stages of the CD® (Sprague-Dawley) rat skeleton after maternal exposure to ethylene glycol. Teratology. 1992; 46(2):169–181.1440420
50 Tyl RW. Commentary on the role of maternal toxicity on developmental toxicity. Birth Defects Res B Dev Reprod Toxicol. 2012; 95(3):262–266.22706915
51 Robb GW, Amann RP, Killian GJ. Daily sperm production and epididymal sperm reserves of pubertal and adult rats. J Reprod Fertil. 1978; 54(1):103–107.712697
52 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78.28094716
53 Boorman GA, Haseman JK, Waters MD, Hardisty JF, Sills RC. Quality review procedures necessary for rodent pathology databases and toxicogenomic studies: The National Toxicology Program experience. Toxicol Pathol. 2002; 30(1):88–92.11890481
54 Kupper LL, Portier C, Hogan MD, Yamamoto E. The impact of litter effects on dose-response modeling in teratology. Biometrics. 1986; 42(1):85–98.3719065
55 Rao JN, Scott AJ. A simple method for the analysis of clustered binary data. Biometrics. 1992; 48(2):577–585.1637980
56 Fung KY, Krewski D, Rao JN, Scott AJ. Tests for trend in developmental toxicity experiments with correlated binary data. Risk Anal. 1994; 14(4):639–648.7972964
57 Bailer AJ, Portier CJ. Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988; 44(2):417–431.3390507
58 Piegorsch W, Bailer A. Statistics for Environmental Biology and Toxicology: Section 6.3.2. London, UK: Chapman and Hall; 1997.
59 Portier CJ, Bailer AJ. Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989; 12(4):731–737.2744275
60 Bieler GS, Williams RL. Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993; 49(3):793–801.8241374
61 Nam JM. A simple approximation for calculating sample sizes for detecting linear trend in proportions. Biometrics. 1987; 43(3):701–705.3663825
62 Dixon W, Massey F. Introduction to Statistical Analysis. New York, NY: McGraw Hill Book Company Inc; 1957.
63 Tukey J. Exploratory Data Analysis. Reading, MA: Addison-Wesley; 1977. Easy summaries – numerical and graphical; p. 43–44.
64 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121.
65 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117.5547548
66 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531.5037867
67 Hsu JC. The factor analytic approach to simultaneous inference in the general linear model. J Comput Graph Stat. 1992; 1(2):151–168.
68 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389.884197
69 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186.3719054
70 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252.
71 Jonckheere A. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41:133–145.
72 Davison AC, Hinkley DV. Bootstrap Methods and their Application. Cambridge, UK: Cambridge University Press; 1997.
73 Datta S, Satten GA. Rank-sum tests for clustered data. J Am Stat Assoc. 2005; 100(471):908–915.
74 Hommel G. A stagewise rejective multiple test procedure based on a modified Bonferroni test. Biometrika. 1988; 75(2):383–386.
75 Hothorn LA. Statistical evaluation of toxicological bioassays – A review. Toxicol Res. 2014; 3(6):418–432.
76 Kalbfleisch JD, Lawless JF. The analysis of panel data under a Markov assumption. J Am Stat Assoc. 1985; 80(392):863–871.
77 Code of Federal Regulations (CFR). 21(Part 58).
78 Miller JA, Miller EC. Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH, Watson JD, Winsten JA, editors. Origins of Human Cancer. Spring Harbor, NY: Cold Spring Harbor Laboratory; 1977. p. 605–627.
79 Straus DS. Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981;67:233–241.7021938
80 Crawford BD. Perspectives on the somatic mutation model of carcinogenesis. In: Mehlman MA, Flamm WG, Lorentzen RJ, editors. Advances in Modern Environmental Toxicology Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton, NJ: Princeton Scientific Publishing Co. Inc; 1985. p. 13–59.
81 Ashby J, Tennant RW. Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the US NTP. Mutat Res. 1991; 257(3):229–306.1707500
82 Tennant RW, Margolin BH, Shelby MD, Zeiger E, Haseman JK, Spalding J, Caspary W, Resnick M, Stasiewicz S, Anderson B. Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987; 236(4804):933–941.3554512
83 Zeiger E, Haseman JK, Shelby MD, Margolin BH, Tennant RW, Holden H. Evaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: Confirmation of earlier results with 41 additional chemicals. Environ Mol Mutagen. 1990; 16 S18:1–14.
84 Schmid W. The micronucleus test. Mutat Res. 1975; 31(1):9–15.48190
85 Heddle JA, Hite M, Kirkhart B, Mavournin K, MacGregor JT, Newell GW, Salamone MF. The induction of micronuclei as a measure of genotoxicity: A report of the U.S. environmental protection agency Gene-Tox program. Mutat Res. 1983; 123(1):61–118.6888413
86 Shelby MD, Erexson GL, Hook GJ, Tice RR. Evaluation of a three-exposure mouse bone marrow micronucleus protocol: Results with 49 chemicals. Environ Mol Mutagen. 1993;21:160–179.8444144
87 Shelby MD, Witt KL. Comparison results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutagen. 1995;25:302–313.7607185
88 Witt KL, Knapton A, Wehr CM, Hook GJ, Mirsalis J, Shelby MD, MacGregor JT. Micronucleated erythrocyte frequency in peripheral blood of B6C3F1 mice from short-term, prechronic, and chronic studies of the NTP Carcinogenesis Bioassay Program. Environ Mol Mutagen. 2000; 36:163-194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P
89 National Toxicology Program (NTP). DART-08: Growth and clinical finding tables (I), pathology tables (PA), developmental and reproductive tables (R) from NTP modified one generation dose range finding study and modified one generation main study studies. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2020. 10.22427/NTP-DATA-DART-08
90 Tišler T, Krel A, Gerželj U, Erjavec B, Dolenc MS, Pintar A. Hazard identification and risk characterization of bisphenols A, F and AF to aquatic organisms. Environ Pollut. 2016;212:472–479.26957022
91 Moreman J, Lee O, Trznadel M, David A, Kudoh T, Tyler CR. Acute toxicity, teratogenic, and estrogenic effects of bisphenol A and its alternative replacements bisphenol S, bisphenol F, and bisphenol AF in zebrafish embryo-larvae. Environ Sci Technol. 2017; 51(21):12796–12805.29016128
92 Qiu W, Zhao Y, Yang M, Farajzadeh M, Pan C, Wayne NL. Actions of bisphenol A and bisphenol S on the reproductive neuroendocrine system during early development in zebrafish. Endocrinology. 2016; 157(2):636–647.26653335
93 Tang T, Yang Y, Chen Y, Tang W, Wang F, Diao X. Thyroid disruption in zebrafish larvae by short-term exposure to bisphenol AF. Int J Environ Res Public Health. 2015; 12(10):13069–13084.26501309
94 Yang X, Liu Y, Li J, Chen M, Peng D, Liang Y, Song M, Zhang J, Jiang G. Exposure to bisphenol AF disrupts sex hormone levels and vitellogenin expression in zebrafish. Environ Toxicol. 2016; 31(3):285–294.25213402
95 Shi J, Jiao Z, Zheng S, Li M, Zhang J, Feng Y, Yin J, Shao B. Long-term effects of bisphenol AF (BPAF) on hormonal balance and genes of hypothalamus-pituitary-gonad axis and liver of zebrafish (Danio rerio), and the impact on offspring. Chemosphere. 2015;128:252–257.25723718
96 Kitamura S, Suzuki T, Sanoh S, Kohta R, Jinno N, Sugihara K, Yoshihara Si, Fujimoto N, Watanabe H, Ohta S. Comparative study of the endocrine-disrupting activity of bisphenol A and 19 related compounds. Toxicol Sci. 2005; 84(2):249–259.15635150
97 Li Y, Burns KA, Arao Y, Luh CJ, Korach KS. Differential estrogenic actions of endocrine-disrupting chemicals bisphenol A, bisphenol AF, and zearalenone through estrogen receptor α and β in vitro. Environ Health Perspect. 2012; 120(7):1029–1035.22494775
98 Bermudez DS, Gray LE Jr, Wilson VS. Modeling the interaction of binary and ternary mixtures of estradiol with bisphenol A and bisphenol AF in an in vitro estrogen-mediated transcriptional activation assay (T47D-KBluc). Toxicol Sci. 2010; 116(2):477–487.20498000
99 Conley JM, Hannas BR, Furr JR, Wilson VS, Gray LE Jr. A demonstration of the uncertainty in predicting the estrogenic activity of individual chemicals and mixtures from an in vitro estrogen receptor transcriptional activation assay (T47D-KBluc) to the in vivo uterotrophic assay using oral exposure. Toxicol Sci. 2016; 153(2):382–395.27473340
100 Delfosse V, Grimaldi M, Pons JL, Boulahtouf A, le Maire A, Cavailles V, Labesse G, Bourguet W, Balaguer P. Structural and mechanistic insights into bisphenols action provide guidelines for risk assessment and discovery of bisphenol A substitutes. Proc Natl Acad Sci USA. 2012; 109(37):14930–14935.22927406
101 Teng C, Goodwin B, Shockley K, Xia M, Huang R, Norris J, Merrick BA, Jetten AM, Austin CP, Tice RR. Bisphenol A affects androgen receptor function via multiple mechanisms. Chem Biol Interact. 2013; 203(3):556–564.23562765
102 Pelch KE, Li Y, Perera L, Thayer KA, Korach KS. Characterization of estrogenic and androgenic activities for bisphenol A-like Chemicals (BPs): In vitro estrogen and androgen receptors transcriptional activation, gene regulation, and binding profiles. Toxicol Sci. 2019; 172(1):23–37.
103 Brown LM, Clegg DJ. Central effects of estradiol in the regulation of food intake, body weight, and adiposity. J Steroid Biochem Mol Biol. 2010; 122(1):65–73.20035866
104 Wallen WJ, Belanger MP, Wittnich C. Sex hormones and the selective estrogen receptor modulator tamoxifen modulate weekly body weights and food intakes in adolescent and adult rats. J Nutr. 2001; 131(9):2351–2357.11533278
105 Biegel LB, Flaws JA, Hirshfield AN, O’Connor JC, Elliott GS, Ladics GS, Silbergeld EK, Van Pelt CS, Hurtt ME, Cook JC, et al. 90-day feeding and one-generation reproduction study in Crl:CD BR rats with 17 beta-estradiol. Toxicol Sci. 1998; 44(2):116–142.9742652
106 Roepke TA. Oestrogen modulates hypothalamic control of energy homeostasis through multiple mechanisms. J Neuroendocrinol. 2009; 21(2):141–150.19076267
107 Delclos KB, Weis CC, Bucci TJ, Olson G, Mellick P, Sadovova N, Latendresse JR, Thorn B, Newbold RR. Overlapping but distinct effects of genistein and ethinyl estradiol (EE2) in female Sprague–Dawley rats in multigenerational reproductive and chronic toxicity studies. Reprod Toxicol. 2009; 27(2):117–132.19159674
108 National Toxicology Program (NTP). NTP technical report on the multigenerational reproductive toxicology study of genistein (CAS No. 446-72-0) in Sprague-Dawley rats (feed study). Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2008. NTP Technical Report No. 539. https://ntp.niehs.nih.gov/publications/reports/tr/500s/tr539/index.html?utm_source=direct&utm_medium=prod&utm_campaign=ntpgolinks&utm_term=tr539abs
109 National Toxicology Program (NTP). NTP technical report on the multigenerational reproductive toxicology study of ethinyl estradiol (CAS No. 57-63-6) in Sprague-Dawley rats (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2010. NTP Technical Report No. 547. https://ntp.niehs.nih.gov/publications/reports/tr/500s/tr547/index.html?utm_source=direct&utm_medium=prod&utm_campaign=ntpgolinks&utm_term=tr547abs
110 Asarian L, Geary N. Modulation of appetite by gonadal steroid hormones. Philos Trans R Soc Lond B Biol Sci. 2006; 361(1471):1251–1263.16815802
111 Barros RP, Gustafsson J. Estrogen receptors and the metabolic network. Cell Metab. 2011; 14(3):289–299.21907136
112 Perry R, Thompson CA, Earnhardt JN, Wright DJ, Bailey S, Komm B, Cukierski MA. Renal tumors in male rats following long-term administration of bazedoxifene, a tissue-selective estrogen receptor modulator. Toxicol Pathol. 2013; 41(7):1001–1010.23416963
113 Clapp MJ, Wade JD, Samuels DM. Control of nephrocalcinosis by manipulating the calcium:phosphorus ratio in commercial rodent diets. Lab Anim. 1982; 16(2):130–132.7078058
114 Ritskes-Hoitinga J, Beynen AC. Nephrocalcinosis in the rat: A literature review. Prog Food Nutr Sci. 1992; 16(1):85–124.1620876
115 Geary CP, Cousins FB. An oestrogen-linked nephrocalcinosis in rats. Br J Exp Pathol. 1969; 50(5):507–515.5348008
116 European Chemicals Agency (ECHA). Registration dossier: 4,4'-[2,2,2-trifluoro-1-(trifluoromethyl)ethylidene]diphenol; bisphenol AF (CASRN: 1478-61-1): Repeated dose oral toxicity: Oral: 001 Weight of evidence | Experimental result. 2020. https://echa.europa.eu/registration-dossier/-/registered-dossier/23236/7/6/2
117 Meng Z, Wang D, Yan S, Li R, Yan J, Teng M, Zhou Z, Zhu W. Effects of perinatal exposure to BPA and its alternatives (BPS, BPF and BPAF) on hepatic lipid and glucose homeostasis in female mice adolescent offspring. Chemosphere. 2018;212:297–306.30145421
118 Palmisano BT, Zhu L, Stafford JM. Role of estrogens in the regulation of liver lipid metabolism. Adv Exp Med Biol. 2017;1043:227–256.29224098
119 Everds NE, Snyder PW, Bailey KL, Bolon B, Creasy DM, Foley GL, Rosol TJ, Sellers T. Interpreting stress responses during routine toxicity studies: A review of the biology, impact, and assessment. Toxicol Pathol. 2013; 41(4):560–614.23475558
120 Luster MI, Boorman GA, Korach KS, Dieter MP, Hong L. Mechanisms of estrogen-induced myelotoxicity: Evidence of thymic regulation. Int J Immunopharmacol. 1984; 6(4):287–297.6480194
121 Maćczak A, Duchnowicz P, Sicińska P, Koter-Michalak M, Bukowska B, Michałowicz J. The in vitro comparative study of the effect of BPA, BPS, BPF and BPAF on human erythrocyte membrane; perturbations in membrane fluidity, alterations in conformational state and damage to proteins, changes in ATP level and Na(+)/K(+) ATPase and AChE activities. Food Chem Toxicol. 2017;110:351–359.29079494
122 Maćczak A, Cyrkler M, Bukowska B, Michałowicz J. Eryptosis-inducing activity of bisphenol A and its analogs in human red blood cells (in vitro study). J Hazard Mater. 2016;307:328–335.26799224
123 Phelps T, Snyder E, Rodriguez E, Child H, Harvey P. The influence of biological sex and sex hormones on bile acid synthesis and cholesterol homeostasis. Biol Sex Differ. 2019; 10(1):52.31775872
124 Murphy WG. The sex difference in haemoglobin levels in adults - Mechanisms, causes, and consequences. Blood Rev. 2014; 28(2):41–47.24491804
125 LabDiet. Advanced Protocol® Verified Casein Diet 10 IF. 2017. https://www.labdiet.com/cs/groups/lolweb/@labdiet/documents/web_content/mdrf/mdi4/~edisp/ducm04_028427.pdf
126 Zeiger E, Anderson B, Haworth S, Lawlor T, Mortelmans K. Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992; 19 Suppl 21:2–141.1541260
127 Witt KL, Livanos E, Kissling GE, Torous DK, Caspary W, Tice RR, Recio L. Comparison of flow cytometry- and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008; 649(1-2):101–113.17869571
128 Dertinger SD, Camphausen K, MacGregor JT, Bishop ME, Torous DK, Avlasevich S, Cairns S, Tometsko CR, Menard C, Muanza T. Three‐color labeling method for flow cytometric measurement of cytogenetic damage in rodent and human blood. Environ Mol Mutagen. 2004; 44(5):427–435.15517570
129 Kissling GE, Dertinger SD, Hayashi M, MacGregor JT. Sensitivity of the erythrocyte micronucleus assay: Dependence on number of cells scored and inter-animal variability. Mutat Res. 2007; 634(1-2):235–240.17851117
130 Igl BW, Bitsch A, Bringezu F, Chang S, Dammann M, Frötschl R, Harm V, Kellner R, Krzykalla V, Lott J, et al. The rat bone marrow micronucleus test: Statistical considerations on historical negative control data. Regul Toxicol Pharmacol. 2019;102:13–22.30572081