# Conclusions

Under the conditions of this modified one-generation (MOG) study, there was clear evidence of reproductive toxicity of bisphenol AF (BPAF) in Hsd:Sprague Dawley^®^ SD^®^ rats based on the increased disruption of estrous cyclicity, the inability of the F_1_ generation to reproduce, decreases in F_1_ pup survival, and a slight increase in gestation length for F_0_ females at the highest dietary exposure concentration and, at lower concentrations, decreases in the number of implants, corpora lutea, and live fetuses or litters.

Under the conditions of this MOG study, there was clear evidence of developmental toxicity of BPAF in Hsd:Sprague Dawley^®^ SD^®^ rats based on the presence of fetal malformations and abnormal histopathology of both the male and female reproductive tract in the F_1_ generation, impacts on developmental markers, including accelerated vaginal opening and delayed balanopreputial separation, and lower F_1_ and F_2_ mean body and organ weights.