# Discussion

The objective of the present study was to characterize the potential for bisphenol AF (BPAF), a fluorinated analog of bisphenol A (BPA) used in the production of polycarbonates, fluoroelastomers, and epoxy resins, to adversely affect any phase of rat development, maturation, or ability to successfully reproduce and/or to cause subchronic toxicity in the F_1_ generation.

Along with bisphenol S and bisphenol F, BPAF is considered a “next generation” bisphenol, although it is not currently approved in the United States as a replacement for BPA. A primary concern for this class of chemicals is the potential to act as an endocrine-active substance. Studies in zebrafish and rats indicate that BPA and BPA analogs may have similar toxicity profiles, effects, and estrogenic activity, underscoring potential concerns about health risks that warrant investigation and better toxicological characterization.^32; 90-95^

Mechanistic studies have shown that BPAF is an estrogen receptor alpha (ERα) agonist^24; 96; 97^ that can activate ER gene transcription^98^ as well as increase uterine size in adult ovariectomized Harlan Sprague Dawley rats when exposed via the oral route.^99^ Compared with endogenous estrogens, BPAF is a weak ERα agonist, although more potent than BPA.^99^ Additional studies suggest BPAF may also act as an estrogen receptor beta (ERβ) antagonist, specifically in HeLa cells,^24; 97; 100^ but not HepG2 cells,^97^ and as an androgen receptor antagonist.^96; 101; 102^ This information suggests that BPAF likely activates the ER and antagonizes the androgen receptor to varying degrees.

In this study, Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were exposed to BPAF in feed using the NTP modified one-generation (MOG) study design. To minimize the potential endocrine activity of phytoestrogens present in rodent diets, a low-phytoestrogen diet, 5K96, was used. Exposure concentration selection was informed by a dose range-finding study in which BPAF-related significant decreases in pup body weights during lactation were noted at concentrations ≥7,500 ppm. Therefore, 3,750 ppm BPAF was chosen as the high-exposure concentration in the MOG study, and exposure concentrations of 338 and 1,125 ppm were selected to aid in identifying potential exposure-response relationships and to avoid excessive overlap of the ingested doses due to increased feed consumption during pregnancy.

Exposure of F_0_ females to BPAF via the diet began on gestation day (GD) 6 (implantation). F_1_ offspring were exposed to BPAF at the same exposure concentration as their respective dams. Upon weaning, F_1_ offspring at each exposure concentration were randomly assigned to one of four cohorts: (1) a reproductive performance cohort (1/sex/litter), (2) a prenatal cohort (1/sex/litter), (3) a subchronic cohort (1/sex/litter from 10 litters), and (4) a biological sampling cohort. Upon sexual maturity, nonsibling F_1_ rats allocated to the prenatal and reproductive performance cohorts were paired for mating to evaluate reproductive performance and F_2_ prenatal and postnatal development.

In this study, BPAF exposure was associated with lower F_0_, F_1_, and F_2_ mean body weights. The lower F_0_ female mean body weights and body weight gains during gestation was associated with a significant exposure concentration-dependent decrease in postnatal day (PND) 1 F_1_ pup weights in the 1,125 and 3,750 ppm groups that continued through PND 98. Consequently, the F_1_ female mean body weights of both the reproductive performance and prenatal cohorts were lower for the BPAF-exposed groups at the time of cohabitation and through gestation (no pregnancies were observed for the 3,750 ppm group). A reduction in litter size and fetal or pup weights contributed to the overall lower mean body weights that occurred during gestation for the 1,125 ppm group. For the F_2_ pups in the reproductive performance cohort, there was a BPAF-related significant decrease in mean body weights of both 1,125 ppm male and female pups through weaning, but only female postweaning mean body weights were significantly decreased through PND 91 for both the 338 and 1,125 ppm groups.

Interestingly, the lower body weight gains in the F_1_ and F_2_ generations were not directly correlated with lower absolute feed consumption values (g/animal/day) as these values were variable; relative feed consumption (g/kg/day) was either similar to or significantly increased compared to that of control animals. Although the increases in feed consumption likely represent some feed wastage (palatability issues were noted in both the dose range-finding study and this study), the changes in absolute feed consumption are likely related to the size of the animals as both F_1_ and F_2_ pup mean body weights were lower at 1,125 (F_1_ and F_2_) and 3,750 (F_1_ only) ppm. It is also possible that the BPAF-related effects on mean body weight and feed consumption could be mediated through ER signaling. Several in vitro studies have demonstrated, through induction of luciferase expression, that BPAF has high estrogenic activity.^24; 96-98^ Natural and synthetic estrogens are known to reduce growth and body weight in rodents^103-105^ and have been shown to have effects on the regulation of food intake.^103; 106^ Multigenerational studies with genistein and ethinyl estradiol have also reported decreased body weights.^107-109^ Food intake, metabolism, and body fat distribution can all be modulated by estrogens,^103; 110; 111^ and they can act centrally to modulate orexigenic and anorexigenic hormones to increase or decrease appetite, respectively, and energy homeostasis.^103; 106^ This may provide a potential explanation for some of the mean body weight and feed consumption results observed.

BPAF-related changes in reproductive performance were observed at all exposure concentrations. For the 3,750 ppm group, a slight but significant increase in gestation length for F_0_ females, a significant decrease in F_1_ pup survival (PND 1–4), and a complete absence of pregnant females in the F_1_ generation were observed. Similar findings, although to a lesser extent, were observed at lower concentrations in the prenatal cohort and included a significant decrease in the number of F_1_ females with live fetuses or live litters, number of corpora lutea, and number of implantation sites in the 1,125 ppm group, which were associated with significant increases in pre- and postimplantation loss values. Significant decreases in the number of corpora lutea and implantation sites were noted for the prenatal cohort females in the 338 ppm group.

Additional BPAF-related changes consistent with both male and female developmental toxicity were observed in the F_1_ generation as indicated by changes in organ weights that were associated with gross and microscopic findings. There was a BPAF-related significant increase in relative weights of the lungs, adrenal glands, and thyroid gland and significant decreases in relative weights for the liver and kidney (left) for the 3,750 ppm F_1_ males in the subchronic cohort. For the kidney, microscopic findings (mineral lesions along the junction of the cortex and medulla) were observed in the 3,750 ppm group and are a common background finding in female rats,^112-114^ although they are less common in males and may signify a potential estrogenic effect on the males.^115^ There were lower male reproductive organ weights with microscopic findings, as well as impacts on andrology parameters, in F_1_ males. Most male reproductive tissue weights, except the preputial glands, were lower compared to the control group in F_2_ males in both the 338 and 1,125 ppm groups, with lower organ weights at 1,125 ppm correlating with a reduction in size, noted at necropsy. Most organ weight changes noted were more than the magnitude of the reductions in body weight. This finding, along with the F_1_ histopathological observations of hypoplasia, indicates a potential direct BPAF-mediated suppression of maturation of these tissues.

In F_1_ males, absolute weights were lower in the dorsolateral prostate, ventral prostate, and seminal vesicles with coagulating glands for the 1,125 and 3,750 ppm groups and in the Cowper’s glands and levator ani/bulbocavernosus muscle (LABC) in the 3,750 ppm group. The changes in the 3,750 ppm group correlated with gross observations of reduced size at necropsy and microscopic observations of hypoplasia for the majority of the animals in this group. F_2_ males exhibited similar findings in the same tissues as F_1_ males in the 338 and 1,125 ppm groups. Organ weight changes that appeared secondary to the effect of BPAF on body weight were noted in F_1_ males and included lower absolute weights of the testes, epididymides, and preputial glands in all three exposed groups, but the histopathological findings of germinal epithelium degeneration and Leydig cell atrophy could contribute to the lower testes weights and suggest a more direct effect of BPAF exposure. Relative testis weights were higher in the 3,750 ppm group, but relative epididymal weights were similar to the control animals. In F_2_ males, possible secondary effects of BPAF on body weight were observed as lower absolute weights of the testes and epididymides in the 338 and 1,125 ppm groups, as well as lower relative weights of the testis at 338 ppm and epididymides at 1,125 ppm. Histopathology was not performed on the F_2_ generation.

BPAF-related changes in andrology parameters for F_1_ males were limited to significant decreases in testes and cauda epididymal weights in the 1,125 and 3,750 ppm groups, as well as a significant decrease in cauda epididymal sperm concentration, and a significant increase in testis spermatid head concentration in the 3,750 ppm group. Microscopic findings in the testis at 3,750 ppm included germinal epithelium degeneration, Leydig cell atrophy, and seminiferous tubule spermatid retention, along with duct atrophy and/or duct exfoliated germ cell and duct hypospermia in the epididymis. BPAF-related changes in andrology parameters for F_2_ males were limited to significant decreases in cauda epididymal weight at both 338 and 1,125 ppm (histopathology of the organs was not evaluated for the F_2_ generation).

In the F_1_ females, reproductive toxicity included significant decreases in absolute ovarian weights in the 1,125 and 3,750 ppm groups; relative ovarian weights were also lower compared to the control group. Those observations correlated with gross observations of reduced size and an exposure concentration-related increase in the incidence of hypoplasia characterized by a lack of or reduction in numbers of corpora lutea and reduced numbers of antral and/or growing follicles in the 3,750 ppm group. A significant decrease in the absolute weight of the uterus/cervix/vagina was observed in the 1,125 and 3,750 ppm groups and was correlated with gross observations of reduced size and hypoplasia of the uterus in the 3,750 ppm group. Uterine hypoplasia was characterized microscopically by an overall smaller size, a thinning and less dense stroma of the endometrium, and a reduction in the number of endometrial glands. Other microscopic changes in the uterus included squamous metaplasia, cystic glandular dilation, and hyalinization of the stroma. Changes were also observed in the F_2_ females, which displayed significant decreases in absolute ovarian weights (338 and 1,125 ppm), with relative ovarian weights significantly decreased only in the 1,125 ppm group. The magnitude of the reduction in weights of the ovaries in the 1,125 ppm group was more than the magnitude of the reduction in body weight, suggesting a direct BPAF-mediated suppression of maturation of this tissue. However, there were no gross findings for the ovaries, and histopathological analysis was not conducted for the F_2_ females. In the subchronic cohort, significant increases in the relative weights of the thyroid gland and liver were noted in the 3,750 ppm F_1_ females. The decreases observed in select organ weights provide supporting evidence of the impacts of BPAF exposure on reproduction and development.

In addition, BPAF-related changes consistent with impaired development included lower mean body weights for all generations, including fetal or pup weights, and reduced litter sizes, as mentioned above, as well as impacts on fetal parameters and developmental markers.

Select developmental landmarks in both males and females were impacted by BPAF exposure. Vaginal opening (VO), testicular descent, balanopreputial separation (BPS), anogenital distance, and areolae and nipple retention were evaluated in both the F_1_ and F_2_ generations. The time to VO was significantly accelerated in all BPAF-exposed groups for both the F_1_ and F_2_ generations at all exposure concentrations. In the F_1_ generation, the mean day of achieving VO was significantly accelerated by 2, 8, and 8 days in the 338, 1,125, and 3,750 ppm groups, respectively, and by 3 and 10 days in the F_2_ females at 338 and 1,125 ppm, respectively. The mean day of testicular descent was not affected in the F_1_ generation, although one male in the 1,125 ppm group and 11 males in the 3,750 ppm group did not attain testicular descent by study termination; however, the mean day of testicular descent was significantly delayed by approximately 2 days for the F_2_ offspring in the 1,125 ppm group. In addition, 10 F_1_ males in the 3,750 ppm group did not attain BPS. The time to BPS was significantly delayed in both the F_1_ and F_2_ offspring by 4 and 32 days in the F_1_ 1,125 and 3,750 ppm groups, respectively, and by 6 days in the F_2_ 1,125 ppm group. There was no effect of BPAF exposure on mean anogenital distance on PND 1 for male and female F_1_ and F_2_ offspring or on retention of areolae or nipples on PND 13 in F_1_ and F_2_ male offspring.

Additional fetal parameters were impacted by BPAF exposure. Three F_1_ females in the 3,750 ppm group had malformations of the vagina; one had no apparent VO, and two had a misshapen vagina. Direct impacts on the reproductive tract were not limited to females as two F_1_ males had malformations of the penis in the 3,750 ppm group; one had the os penis visible at the glans, and the second had incomplete BPS. Both males also had reductions in the size of the dorsolateral prostate, ventral prostate, seminal vesicles, testes, and epididymides. Additional impacts on development were limited to an increase in the incidence of dilated and/or misshapen lateral ventricle (brain) in the 1,125 ppm group and increases in the incidences of rudimentary and full lumbar I (L1) ribs in the 338 ppm group and rudimentary L1 ribs in the 1,125 ppm group for the prenatal cohort. These effects on male and female reproductive tract development, pubertal development, and fetal development were considered clear evidence of developmental toxicity.

At study termination, several biochemical and hematological changes were observed in the F_1_ generation. Both male and female rats had significant decreases in serum cholesterol concentrations, while serum triglyceride concentrations were significantly increased in female rats and serum bile acid concentrations were significantly decreased in male rats. Bile acid concentrations in female rats, although not significant, were 45% of control animals in the high-dose group. Similar decreases in cholesterol concentrations were also reported in a 28-day BPAF study.^29; 116^ Additionally, triglyceride and total cholesterol content, as well as genes associated with triglyceride and fatty acid synthesis, were decreased in the livers of female mice exposed to BPAF in utero and during lactation.^117^ These effects are consistent with the reported ERα agonist activity of BPAF, as estrogen is an important regulator of liver lipid metabolism (including bile acid metabolism) and serum lipoprotein levels. Estrogen suppresses de novo liver lipogenesis, promotes liver secretion of cholesterol into bile, and plays a role in liver cholesterol uptake and reverse cholesterol transport (i.e., cholesterol removal from peripheral tissues and delivery to the feces).^118^ BPAF has also been shown to decrease liver PPAR-𝛾 expression. PPAR-𝛾 is an important regulator of lipid metabolism and can increase fatty acid storage while inhibiting fatty acid oxidation.^117^

In addition to the biochemical changes, hematological changes were observed in F_1_ female rats and included a significant decrease in erythrocyte count, hemoglobin concentration, and total white blood cell count for the 3,750 ppm group. These hematology changes may have indicated suppression or disruption of hematopoiesis due to chronic stress of exposure^119^ or may have been a direct effect of BPAF exposure, particularly as it relates to its purported estrogen receptor activity. Estrogen is a known suppressor of hematopoiesis in rodents, particularly erythropoiesis, through mechanisms that are not fully understood involving disruptions in both thymic and non-thymic hematopoietic regulatory pathways.^120^ BPAF has also been shown to cause perturbations in red blood cell membranes and to enhance eryptosis.^121; 122^ Eryptosis is a key process for the removal of damaged or aged erythrocytes from circulation. Xenobiotics that enhance eryptosis can cause an accelerated removal of erythrocytes from circulation that may lead to decreases in red blood cell counts or anemia and other disorders.^122^ Erythrocytes exposed to BPAF were shown to have increased cytosolic calcium ion levels, increased phosphotidylserine translocation to the external plasma membrane layer, and increased calpain and caspase-3 activities, all of which are triggers for eryptosis.^122^ Differences between the observed biochemical and hematological effects in male and female rats may be a result of the known sexual dimorphism in erythropoiesis and lipid and bile acid homeostasis as it relates to estrogen (estradiol) and its relatively high endogenous levels in females and lower circulating levels in males.^118; 123; 124^

Free (parent only) and total (combined parent and conjugated forms) BPAF concentrations were quantified in maternal plasma and fetuses at GD 18 and maternal and pup plasma at lactation day (LD) 4 and LD 28.^44^ In maternal plasma, free and total concentrations increased with exposure concentration; free BPAF concentrations were ≤1.61% those of total BPAF, demonstrating considerable first pass metabolism of BPAF following exposure via feed. In both GD 18 fetuses and PND 4 pups, the free BPAF concentrations were higher (130%–571%) than corresponding dam concentrations, demonstrating considerable gestational and lactational transfer of parent BPAF from the mother to offspring. Total BPAF concentrations in GD 18 fetuses and PND 4 pups were lower (1.71%–7.23%) than corresponding concentrations in dams, demonstrating either preferential transfer of free BPAF and/or inability of fetuses and pups to conjugate BPAF. Free BPAF concentrations were 11.7%–53.4% that of corresponding total BPAF concentrations in both GD 18 fetuses and PND 4 pup plasma, and the percentage was greater than that observed for dams (≤1.61%). Free and total concentrations in PND 28 pups were similar to LD 28 maternal concentrations, demonstrating direct exposure of pups via feed and indicating that conjugating enzymes are developed in PND 28 pups.^44^ Because the ontogeny of conjugating enzymes in humans is similar to that of rodents, the data from rodent BPAF studies could be useful in predicting human risk from exposure to BPAF.

The presence of free BPAF in fetuses and pups confirmed both gestational and lactational transfer of parent BPAF and highlighted the indirect impacts of BPAF on the developing system through multiple generations at almost every exposure examined in this study. Under similar exposure conditions, findings appear to be more notable in females than males, with the exception of organ weights (e.g., there were significant decreases in postweaning mean body weights for both the 338 and 1,125 ppm groups through study termination for F_2_ females but not F_2_ males).

In addition, select developmental markers (VO and BPS) were significantly impacted by exposure to BPAF in both F_1_ and F_2_ animals, with delays in BPS at 1,125 and 3,750 ppm for the F_1_ generation and at 1,125 ppm for the F_2_ generation. An acceleration in VO was observed at all exposure concentrations in both the F_1_ and F_2_ females, including at the lowest concentration tested (338 ppm). The largest impact was the delay in BPS in the 3,750 ppm group for the F_1_ generation (which included some animals that never achieved separation). Comparatively, the findings in the F_2_ generation were greater at the same exposure concentration of 1,125 ppm (e.g., acceleration of VO was more prominent and delays in BPS were longer). This may be due to lower body weights and suppression of maturation of select systems, multiple impacts on the reproductive system, or a combination of these factors. Overall, the impacts of dietary BPAF exposure were consistent with estrogenic action and included adverse impacts on body weights, organ weights, and both reproductive and developmental parameters.

Although several in vitro studies have shown BPAF capable of inducing DNA damage,^37; 38; 40^ other assays designed to measure the heritable effects of DNA damage induced by BPAF, such as the in vivo micronucleus and the bacterial mutation assays conducted by the National Toxicology Program (NTP), gave negative results. This contrast highlights the possible fates of the DNA damage identified in DNA damage assays: 1) the damage may be incorrectly repaired and transmitted as a mutation with the possibility of clonal expansion, 2) the damage may be rapidly repaired, as is often the case, or 3) the cell may be unable to repair the damage and the cell will die, thereby eliminating the DNA damage.