# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-DART-08.^89^

## Dose Range-finding Study

### Maternal Findings

#### Viability and Clinical Observations

All F_0_ rats in the 15,000 ppm group were euthanized on gestation day (GD) 10 or 11 due to body weight loss (Appendix E). Clinical observations of toxicity were limited to the 7,500 and 15,000 ppm groups and included eye and/or nasal discharge from GD 7 to GD 11 (Appendix E).

#### Body Weights and Feed Consumption

All F_0_ exposed groups exhibited significant decreases of mean body weights starting within the first few days of exposure to bisphenol AF (BPAF), and the decreases were maintained throughout most of gestation. Mean body weights of dams in the 3,750 and 7,500 ppm groups were significantly decreased on GD 21 by 12% and 24%, respectively, compared to the control group, whereas mean body weights of the 937.5 and 1,875 ppm groups were approximately 5% lower (Table 4; Figure 5). The mean body weight gains of dams in the 937.5, 1,875, 3,750, and 7,500 ppm groups over the gestation period (GD 6–21) were lower by 23%, 19%, 31%, and 82%, respectively, compared to the control group, with significant decreases observed in the 3,750 and 7,500 ppm groups (Table 4; Figure 5). These decreases were attributed to body weight losses over the first half of gestation for the ≤3,750 ppm groups and a continual loss over the entire gestation period for the 7,500 ppm group (Table 4).

Table 4 Summary of Mean Body Weights and Body Weight Gains of F_0_ Female Rats Exposed to Bisphenol AF in Feed during Gestation and Lactation (Dose Range-finding Study)

Parameter^a,b^ | 0 ppm | 937.5 ppm | 1,875 ppm | 3,750 ppm | 7,500 ppm | 15,000 ppm
Gestation Body Weight
Gestation Day
6 | 238.9 ± 3.3 (12) | 233 ± 5.0 (7) | 237.0 ± 4.1 (13) | 234.0 ± 4.2 (10) | 240.9 ± 4.0 (10) | 234.5 ± 3.4 (12)
9 | 251.2 ± 3.5** (12) | 238.7 ± 4.7 (7) | 239.2 ± 4.1* (13) | 234.2 ± 3.7** (10) | 230.1 ± 4.6** (10) | 216.1 ± 3.6** (12)
12 | 266.2 ± 4.1** (12) | 244.6 ± 5.5** (7) | 246.3 ± 3.9** (13) | 235.7 ± 2.8** (10) | 223.8 ± 5.1** (10) | –^c^
15 | 286.2 ± 5.1** (12) | 257.7 ± 6.1** (7) | 263.5 ± 3.9** (13) | 254.9 ± 4.0** (10) | 243.1 ± 4.6** (10) | –
18 | 321.3 ± 8.3** (12) | 293.4 ± 8.6* (7) | 297.5 ± 4.7** (13) | 287.5 ± 4.9** (10) | 260.7 ± 5.3** (10) | –
21^d^ | 347.0 ± 15.6** (9) | 326.7 ± 8.5 (4) | 329.3 ± 8.4 (10) | 306.3 ± 4.0* (7) | 263.0 ± 10.4** (7) | –
Gestation Weight Change
Gestation Day Interval
6–21^d^ | 110.9 ± 13.7** (9) | 84.9 ± 4.0 (4) | 90.1 ± 5.7 (10) | 76.6 ± 6.8* (7) | 19.6 ± 12.8** (7) | –
6–9 | 12.3 ± 1.0** (12) | 5.7 ± 1.4** (7) | 2.2 ± 0.7** (13) | 0.3 ± 1.4** (10) | −10.8 ± 2.3** (10) | −18.4 ± 2.1** (12)
9–12 | 15.0 ± 1.3** (12) | 5.9 ± 1.8** (7) | 7.1 ± 1.4** (13) | 1.5 ± 1.8** (10) | −6.4 ± 2.5** (10) | –
12–15 | 19.9 ± 1.6 (12) | 13.1 ± 2.1 (7) | 17.2 ± 1.3 (13) | 19.2 ± 1.7 (10) | 19.3 ± 3.1 (10) | –
15–18 | 35.1 ± 4.2** (12) | 35.6 ± 2.8 (7) | 34 ± 1.5 (13) | 32.6 ± 1.4 (10) | 17.7 ± 5.3** (10) | –
18–21 | 31.4 ± 5.7** (9) | 19.3 ± 2.1 (4) | 29.6 ± 3.2 (10) | 22.5 ± 3.2 (7) | 3.1 ± 9.6** (7) | –
Lactation Body Weight
Lactation Day
1 | 258.3 ± 8.1** (7)^e^ | 219.0 ± 2.3** (4) | 224.0 ± 5.5** (10) | 217.0 ± 7.9** (7) | 208.6 ± 7.2** (6)^e^ | –
4 | 279.3 ± 5.5** (7) | 240.7 ± 5.5** (4) | 240.2 ± 6.2** (10) | 233.7 ± 5.8** (7) | 217.8 ± 8.7** (6) | –
7 | 293.0 ± 5.6** (7) | 247.1 ± 9.5** (4) | 267.1 ± 5.6** (8)^f^ | 252.1 ± 6.5** (6)^f^ | 229.4 ± 8.7** (6) | –
14 | 301.1 ± 4.7** (7) | 275.4 ± 5.9* (4) | 280.9 ± 4.4** (8) | 272.8 ± 3.9** (6) | 241.0 ± 6.5** (6) | –
21 | 283.7 ± 6.2 (7) | 270.5 ± 7.4 (4) | 293.6 ± 5.9 (8) | 284.5 ± 5.2 (6) | 250.6 ± 7.6** (6) | –
Lactation Weight Change
Lactation Day Interval
1–28 | 9.3 ± 7.4* (7) | 50.4 ± 3.4** (4) | 42.8 ± 5.2** (8)^f^ | 56.6 ± 11.4** (6)^f^ | 41.8 ± 5.5* (5)^e,f^ | –
1–4 | 21.0 ± 3.4* (7) | 21.7 ± 5.0 (4) | 16.2 ± 2.4 (10) | 16.8 ± 2.8 (7) | 9.2 ± 4.3 (6) | –
4–7 | 13.7 ± 2.2 (7) | 6.4 ± 8.1 (4) | 20.4 ± 3.2 (8) | 18.0 ± 5.1 (6) | 11.6 ± 4.2 (6) | –
7–11 | 7.2 ± 2.9 (7) | 19.4 ± 11.3 (4) | 12.3 ± 1.3 (8) | 18.0 ± 2.5 (6) | 7.0 ± 2.5 (6) | –
11–14 | 0.9 ± 1.8 (7) | 8.9 ± 3.3 (4) | 1.5 ± 3.4 (8) | 2.7 ± 2.9 (6) | 4.6 ± 3.1 (6) | –
14–18 | −10.3 ± 4.5 (7) | 8.7 ± 2.5* (4) | 8.3 ± 4.9** (8) | 4.1 ± 2.0 (6) | 9.0 ± 3.4** (6) | –
18–21 | −7.0 ± 4.8 (7) | −13.6 ± 7.7 (4) | 4.5 ± 3.4 (8) | 7.7 ± 2.5 (6) | 0.6 ± 4.6 (6) | –
21–25 | −6.5 ± 2.4 (7) | 3.5 ± 2.2 (4) | −10.9 ± 3.1 (8) | −5.0 ± 3.8 (6) | −3.1 ± 5.9 (5) | –
25–28 | −9.6 ± 4.3 (7) | −4.6 ± 2.1 (4) | −12.0 ± 4.2 (8) | −6.7 ± 3.1 (6) | 4.1 ± 1.8 (5) | –

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error (n); body weight data are presented in grams.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ The 15,000 ppm group was removed on gestation day (GD) 10 or 11 due to excessive body weight loss.

^d^ Decreased number of dams at GD 21 reflects animals removed at GD 18 for biological sample collection.

^e^ Dams not delivering with evidence of pregnancy were removed on GD 24 (two dams in the vehicle control group and one dam in the 7,500 ppm group).

^f^ Dams with whole litter loss were removed on lactation day (LD) 4 for biological sample collection (two dams in the 1,875 ppm group, one dam in the 3,750 ppm group) and LD 21 (one dam in the 7,500 ppm group).

Figure 5

Growth Curves for F_0_ Female Rats Exposed to Bisphenol AF in Feed during Gestation and Lactation (Dose Range-finding Study)

Growth curves are shown for (A) gestation and (B) lactation. Information for statistical significance in maternal weights is provided in Table 4.

Mean body weights during lactation were significantly decreased in all exposed groups, relative to the control group, at the beginning of the lactation period. By lactation day (LD) 21, mean body weights of the 937.5, 1,875, and 3,750 ppm groups had recovered to near control group values. Mean body weights during lactation of the 7,500 ppm group were significantly decreased by 12% relative to that of the control group on LD 21 (Table 4; Figure 5).

Feed consumption during gestation by the exposed groups was highly variable compared to that of the control group, and it is likely that feed wastage (dams digging and spilling feed that could not be measured) contributed to the fluctuating levels across feed measurement intervals and decreased confidence in the accuracy of the respective BPAF feed consumption data (Table 5). The high level of feed wastage across the groups exposed to ≥1,875 ppm BPAF suggests that the feed was not very palatable, and a period of adjustment was required before the animals would consume the feed. BPAF intakes in the 937.5, 1,875, 3,750, and 7,500 ppm groups, based on measured feed consumption and dietary concentrations for GD 6–21, were approximately 56, 144, 368, and 618 mg BPAF/kg body weight/day (mg/kg/day), respectively (Table 5).

Table 5 Summary of Feed and Test Article Consumption of F_0_ Female Rats Exposed to Bisphenol AF in Feed during Gestation and Lactation (Dose Range-finding Study)

Parameter^a,b,c^ | 0 ppm | 937.5 ppm | 1,875 ppm | 3,750 ppm | 7,500 ppm | 15,000 ppm
Feed Consumption (g/animal/day)^d^
Gestation Day Interval
6–21 | 20.0 ± 0.6* (9) | 16.2 ± 0.7 (4) | 20.8 ± 1.2 (10) | 25.0 ± 1.4* (7) | 20.3 ± 2.3 (7) | –^e^
6–9 | 18.2 ± 0.4** (12) | 14.5 ± 1.1 (7) | 29.1 ± 3.9 (11) | 38.6 ± 3.7** (9) | 39.8 ± 2.2** (7) | 32.2 ± 4.5** (8)
9–12 | 19.1 ± 0.5** (12) | 14.9 ± 0.9** (7) | 14.5 ± 0.6** (13) | 13.5 ± 0.7** (9) | 10.7 ± 1.4** (10) | –
12–15 | 19.7 ± 0.5 (12) | 15.4 ± 0.6* (5) | 20.1 ± 3.2 (8) | 34.4 ± 1.0 (2) | 25.6 ± 8.0 (2) | –
15–18 | 22.4 ± 0.8** (12) | 19.8 ± 0.6** (7) | 18.4 ± 0.6** (13) | 19.8 ± 1.0** (10) | 14.3 ± 1.2** (10) | –
18–21^f^ | 20.6 ± 1.0 (9) | 16.0 ± 1.3 (4) | 18.7 ± 1.5 (9) | 19.3 ± 0.9 (5) | 30.3 ± 2.2 (4) | –
Lactation Day Interval
1–14 | 49.7 ± 1.4 (7)^g^ | 35.5 ± 7.5 (4) | 48.4 ± 3.6 (8)^h^ | 51.8 ± 4.1 (6)^h^ | 35.6 ± 5.1 (6)^g^ | –
1–4 | 34.0 ± 1.0 (7) | 22.5 ± 7.8 (2) | 26.8 ± 3.0 (3) | 43.6 ± 1.6 (2) | 34.0 ± 4.3 (5) | –
4–7 | 46.4 ± 1.3* (7) | 30.6 ± 3.4 (4) | 41.3 ± 5.1 (8) | 42.5 ± 6.8 (5) | 24.8 ± 1.6** (4) | –
7–11 | 53.7 ± 1.5 (7) | 56.5 ± 0.1 (2) | 54.2 ± 4.1 (7) | 60.0 ± 3.8 (6) | 39.5 ± 6.0 (5) | –
11–14 | 63.1 ± 2.8** (7) | 39.7 ± 11.7 (4) | 55.3 ± 1.8 (8) | 49.9 ± 5.4 (6) | 28.1 ± 4.3** (6) | –
Chemical Intake (mg/kg/day)^i,j^
GD 6–21 | 0.0 ± 0.0 (9) | 56.2 ± 3.2 (4) | 144.3 ± 7.0 (10) | 367.8 ± 19.6 (7) | 617.5 ± 69.1 (7) | –
LD 1–14 | 0.0 ± 0.0 (7) | 133.1 ± 27.6 (4) | 347.7 ± 23.6 (8) | 777.5 ± 54.8 (6) | 1,203.8 ± 206.7 (6) | –

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

GD = gestation day; LD = lactation day.

^a^ Data are presented as mean ± standard error (n), where n = the number of dams. Feed consumption is not reported for nonpregnant animals during the gestation or lactation phase.

^b^ Changes in n are the result of excluded feed consumption values due to excessive spillage. Additional animal feed consumption values removed as outliers include: GD 9–12 (one value in the 3,750 ppm group), GD 18–21 (one value in the 3,750 ppm group), LD 4–7 (one value in the 7,500 ppm group), and LD 7–11 (one value in the 937.5 ppm group).

^c^ For each dam, calculation of consumption values for the GD 6–21 and LD 1–14 intervals was performed using all valid data for the animal, even if data were unavailable for some of the subintervals.

^d^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^e^ The 15,000 ppm group was removed on GD 10 or 11 due to excessive body weight loss.

^f^ Three dams were removed in each group on GD 18 for biological sample collection.

^g^ Dams not delivering with evidence of pregnancy were removed on GD 24 (two dams in the vehicle control group and one dam in 7,500 ppm group).

^h^ Dams with whole litter loss were removed on LD 4 for biological sample collection (two dams in the 1,875 ppm group, one dam in the 3,750 ppm group).

^i^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^j^ No statistical analysis performed on the chemical intake data.

Feed wastage also was observed during the lactation period but to a lesser extent (Table 5). BPAF intake in the 937.5, 1,875, 3,750, and 7,500 ppm groups, based on measured feed consumption and dietary concentrations for LD 1–14, was approximately 133, 348, 778, and 1,204 mg/kg/day, respectively (Table 5).

#### Maternal Reproductive Performance

Twenty-six out of 90 time-mated F_0_ females were not pregnant: three in the control group, eight in the 937.5 ppm group (leaving four litters with uneven litter sizes for this group, which might have influenced the litter results), two in the 1,875 ppm group, five each in the 3,750 and 7,500 ppm groups, and three in the 15,000 ppm group (Table 6). There was no effect of BPAF exposure on the proportion of dams that produced viable litters, on gestation length, or on sex ratio. There was a negative trend in the BPAF-exposed groups for initial mean pups per litter (Appendix E), and LD 1 pup mean body weights were significantly decreased in the 937.5, 3,750, and 7,500 ppm groups compared to those of the control group.

Table 6 Summary of the Reproductive Performance of F_0_ Female Rats Exposed to Bisphenol AF in Feed during Gestation (Dose Range-finding Study)

Parameter^a^ | 0 ppm | 937.5 ppm | 1,875 ppm | 3,750 ppm | 7,500 ppm | 15,000 ppm
Time-mated Females (GD 6) | 15 | 15 | 15 | 15 | 15 | 15
Females Pregnant (%) | 12 (80.0) | 7 (46.7) | 13 (86.7) | 10 (66.7) | 10 (66.7) | 12 (80.0)
Females Not Pregnant (%) | 3 (20.0) | 8 (53.3) | 2 (13.3) | 5 (33.3) | 5 (33.3) | 3 (20.0)
Dams Removed on GD 18^b^ | 3 | 3 | 3 | 3 | 3 | –^c^
Dams Not Delivering with Evidence of Pregnancy (%) | 2 (22.2) | 0 (0.0) | 0 (0.0) | 0 (0.0) | 1 (14.3) | 12 (100.0)
Dams with Litters on LD 0 (%)^d^ | 7 (77.8) | 4 (100.0) | 10 (100.0) | 7 (100.0) | 6 (85.7) | 0 (0.0)
Gestation Length (days)^e,f,g^ | 22 ± 0.0 (7) | 22.3 ± 0.3 (4) | 22.3 ± 0.2 (10) | 22.1 ± 0.1 (7) | 22 ± 0.4 (6) | –
Live Litter Size on LD 0^e,g^ | 13.3 ± 0.4 (7) | 10.3 ± 1.7 (4) | 12.5 ± 0.8 (8)^h^ | 11.3 ± 0.9 (7) | 9.8 ± 1.5 (6) | –
LD 1 Pup Weight^g,i,j^ | 6.84 ± 0.19** 93 (7) | 5.31 ± 0.40** 33 (4) | 6.23 ± 0.15 98 (8) | 5.77 ± 0.21* 70 (6)^h^ | 4.61 ± 0.38** 40 (6) | –
Percent Live Male Pups per Litter^e,g^ | 56.13 ± 5.86 (7) | 60.26 ± 4.85 (4) | 49.36 ± 3.19 (8) | 51.70 ± 6.05 (7) | 56.16 ± 10.27 (6) | –

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

GD = gestation day; LD = lactation day.

^a^ Animals removed from the study between mating and littering were excluded from calculations of % littered females.

^b^ Dams removed on GD 18 for biological sample collection.

^c^ The 15,000 ppm group was removed on GD 10 or 11 due to excessive body weight loss.

^d^ Percentage is the number of littered females/pregnant females. Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^e^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^f^ Gestation length calculated for time-mated females that delivered a litter.

^g^ Data are displayed as mean ± standard error (n).

^h^ Changes in n are the result of removing litters with no surviving pups by: LD 0 (two litters in the 1,875 ppm group) and LD 1 (one litter in the 3,750 ppm group).

^i^ n = the number of pups examined (number of litters).

^j^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

### F_1_ Offspring Findings

#### Pup Viability and Body Weights

BPAF exposure was associated with lower mean number of live pups per litter for all BPAF-exposed groups relative to the control group (Table 7; Appendix E). The number of dead pups during the lactation period (postnatal day [PND] 1–28) was 4, 20, 15, 26, and 34 for the control, 937.5, 1,875, 3,750, and 7,500 ppm groups, respectively (Table 7). Male pup mean body weight gains over the PND 1–28 interval in all exposed groups were significantly decreased (13%–58%) relative to the control pups, whereas female pup mean body weight gains were only significantly decreased compared to the control pups for the 3,750 and 7,500 ppm groups (14%–66%) (Table 8; Figure 6, Figure 7). Adverse F_1_ pup clinical observations in all BPAF-exposed groups were consistent with the effects of BPAF exposure on pup survival (Appendix E). Findings included observations of pups found dead, cannibalized, missing, no milk band, dehydrated, bruised, stained fur, pale, cold to touch, or emaciated. There were no notable gross findings in the limited number of F_1_ offspring that received a necropsy. Necropsy findings for pups found dead on or after PND 1 were limited to the absence of milk/feed in the stomach and one animal in the 1,875 ppm group with a distended ureter (Appendix E).

Table 7 Summary of F_1_ Litter Size and Pup Survival Following Perinatal Exposure to Bisphenol AF (Dose Range-finding Study)

Postnatal Day | 0 ppm | 937.5 ppm | 1,875 ppm | 3,750 ppm | 7,500 ppm
No. of Live Pups (Litters)^a^
0 | 93 (7) | 41 (4) | 100 (10) | 79 (7) | 59 (6)
Total Litter Size^b,c^
0 | 13.6 ± 0.4* (7) | 12.5 ± 0.5 (4) | 11.7 ± 1.0 (10) | 11.7 ± 0.8 (7) | 10.5 ± 1.4 (6)
Live Litter Size^b,c^
0 | 13.3 ± 0.4 (7) | 10.3 ± 1.7 (4) | 12.5 ± 0.8 (8)^d^ | 11.3 ± 0.9 (7) | 9.8 ± 1.5 (6)
1 | 13.3 ± 0.4 (7) | 8.3 ± 2.9 (4) | 12.3 ± 1.0 (8) | 11.7 ± 1.0 (6)^d^ | 6.7 ± 2.3 (6)
4 | 13.1 ± 0.5* (7) | 7.5 ± 3.0 (4) | 11.6 ± 1.0 (8) | 11.5 ± 0.9 (6) | 6.2 ± 2.2* (6)
7 | 12.0 ± 0.4* (7) | 6.8 ± 2.8 (4) | 10.3 ± 0.7 (8) | 9.5 ± 1.1 (6) | 6.2 ± 2.2* (6)
14 | 11.9 ± 0.5** (7) | 5.3 ± 2.7* (4) | 9.9 ± 0.6* (8) | 7.8 ± 1.1** (6) | 4.7 ± 1.6** (6)
21 | 11.9 ± 0.5** (7) | 5.3 ± 2.7* (4) | 9.9 ± 0.6* (8) | 7.8 ± 1.1** (6) | 5.0 ± 1.6** (5)^d^
28 | 11.9 ± 0.5** (7) | 5.3 ± 2.7* (4) | 9.9 ± 0.6* (8) | 7.8 ± 1.1** (6) | 5.0 ± 1.6** (5)
No. of Dead Pups (Litters)^a^
0 | 2 (1) | 9 (2) | 17 (5) | 3 (3) | 4 (1)
1–4 | 1 (1) | 11 (3) | 7 (3) | 10 (2) | 22 (6)
5–28 | 3 (2) | 9 (2) | 8 (5) | 16 (5) | 12 (3)
1–28 | 4 (2) | 20 (4) | 15 (7) | 26 (6) | 34 (6)
Dead/Litter^b,c^
0 | 0.29 ± 0.29 (7) | 2.25 ± 1.31 (4) | 1.70 ± 0.83 (10) | 0.43 ± 0.20 (7) | 0.67 ± 0.67 (6)
1–4 | 0.14 ± 0.14* (7) | 2.75 ± 1.31 (4) | 0.88 ± 0.61 (8)^d^ | 1.43 ± 1.27 (7) | 3.67 ± 1.31** (6)
5–28 | 0.43 ± 0.30 (7) | 2.25 ± 1.44 (4) | 1.00 ± 0.38 (8) | 2.67 ± 0.95 (6)^d^ | 2.00 ± 1.18 (6)
1–28 | 0.57 ± 0.43** (7) | 5.00 ± 1.47* (4) | 1.88 ± 0.67* (8) | 3.71 ± 1.25* (7) | 5.67 ± 1.23** (6)
Survival Ratio^b,c^
0 | 0.98 ± 0.02 (7) | 0.81 ± 0.11 (4) | 0.77 ± 0.13 (10) | 0.96 ± 0.02 (7) | 0.94 ± 0.06 (6)
1–4 | 0.99 ± 0.01* (7) | 0.63 ± 0.20 (4) | 0.93 ± 0.04 (8)^d^ | 0.85 ± 0.14 (7) | 0.56 ± 0.15** (6)
5–28 | 0.96 ± 0.03 (7) | 0.70 ± 0.18 (4) | 0.92 ± 0.03 (8) | 0.74 ± 0.10 (6)^d^ | 0.68 ± 0.17 (6)
1–28 | 0.95 ± 0.04** (7) | 0.43 ± 0.19* (4) | 0.86 ± 0.05* (8) | 0.65 ± 0.13* (7) | 0.4 ± 0.11** (6)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

The 15,000 ppm group was removed on gestation day 10 or 11 due to excessive body weight loss.

^a^ n = the number of pups (number of litters). For No. of Dead Pups, n is the number of litters contributing dead pups.

^b^ Data are displayed as mean ± standard error of the litter means (n), where n = number of litters.

^c^ F_1_ litter size and survival endpoints were analyzed using the Jonckheere (trend) and Shirley or Dunn (pairwise) tests. All calculations are based on the last litter observation of the day.

^d^ Changes in n for live litter size calculations are the result of removing litters with no surviving pups by: postnatal day (PND) 0 (two litters in the 1,875 ppm group), PND 1 (one litter in the 3,750 ppm group), and PND 17 (one litter in the 7,500 ppm group).

Table 8 Summary of F_1_ Male and Female Pup Mean Body Weights and Body Weight Gains Following Perinatal Exposure to Bisphenol AF (Dose Range-finding Study)^a,b^

Postnatal Day^c^ | 0 ppm | 937.5 ppm | 1,875 ppm | 3,750 ppm | 7,500 ppm
Male
1 | 7.06 ± 0.21** 52 (7)^d^ | 5.62 ± 0.37** 18 (3) | 6.32 ± 0.16* 49 (8) | 5.81 ± 0.20** 39 (6) | 4.82 ± 0.24** 22 (5)
4 | 9.87 ± 0.37** 51 (7) | 6.22 ± 1.37** 17 (3) | 8.33 ± 0.35 47 (8) | 7.79 ± 0.49* 38 (6) | 6.60 ± 0.36** 21 (5)
7 | 14.29 ± 0.60** 46 (7) | 8.26 ± 2.09** 15 (3) | 12.00 ± 0.60 43 (8) | 11.02 ± 0.66* 29 (6) | 9.22 ± 0.51** 21 (5)
14 | 28.11 ± 0.99** 46 (7) | 19.38 ± 2.79** 11 (3) | 24.20 ± 0.71* 43 (8) | 22.68 ± 0.84** 22 (6) | 13.52 ± 1.87** 18 (5)
21 | 39.67 ± 0.95** 46 (7) | 34.14 ± 2.16 11 (3) | 36.39 ± 1.88 43 (8) | 34.57 ± 1.34 22 (6) | 22.36 ± 1.93** 16 (4)
28 | 73.19 ± 1.66** 46 (7) | 59.35 ± 4.02* 11 (3) | 63.74 ± 2.63* 43 (8) | 60.92 ± 1.81** 22 (6) | 32.74 ± 3.04** 16 (4)
1–28^e^ | 66.09 ± 1.50** 46 (7) | 53.69 ± 3.63* 11 (3) | 57.43 ± 2.56* 43 (8) | 55.11 ± 1.94** 22 (6) | 28.04 ± 2.94** 16 (4)
Female
1 | 6.56 ± 0.16** 41 (7) | 5.41 ± 0.30* 15 (4) | 6.14 ± 0.17 49 (8) | 5.71 ± 0.27* 31 (6) | 4.38 ± 0.36** 18 (4)
4 | 9.30 ± 0.25** 41 (7) | 6.34 ± 0.88* 13 (4) | 8.13 ± 0.40 46 (8) | 7.49 ± 0.61 31 (6) | 5.57 ± 1.03** 16 (4)
7 | 13.30 ± 0.39** 38 (7) | 8.73 ± 1.75* 12 (3) | 11.71 ± 0.66 39 (8) | 10.90 ± 0.76 28 (6) | 7.10 ± 1.60** 16 (4)
14 | 26.27 ± 0.68** 37 (7) | 19.37 ± 3.84* 10 (3) | 23.89 ± 0.74 36 (8) | 21.67 ± 1.43* 25 (6) | 11.63 ± 1.96** 10 (4)
21 | 37.00 ± 0.83** 37 (7) | 32.56 ± 4.86 10 (3) | 36.60 ± 1.55 36 (8) | 33.07 ± 1.47 25 (6) | 17.82 ± 3.28** 9 (4)
28 | 66.93 ± 0.99** 37 (7) | 57.37 ± 5.26 10 (3) | 61.59 ± 1.85 36 (8) | 57.58 ± 1.94** 25 (6) | 24.36 ± 4.58** 9 (4)
1–28^e^ | 60.34 ± 0.93** 37 (7) | 51.98 ± 4.73 10 (3) | 55.43 ± 1.77 36 (8) | 51.92 ± 2.06** 25(6) | 20.33 ± 4.27** 9 (4)
Male and Female
1 | 6.84 ± 0.19** 93 (7) | 5.31 ± 0.40** 33 (4) | 6.23 ± 0.15 98 (8) | 5.77 ± 0.21* 70 (6) | 4.61 ± 0.38** 40 (6)
4 | 9.64 ± 0.31** 92 (7) | 5.95 ± 1.02** 30 (4) | 8.23 ± 0.36 93 (8) | 7.64 ± 0.54* 69 (6) | 6.04 ± 0.85** 37 (6)
7 | 13.89 ± 0.49** 84 (7) | 7.44 ± 1.71** 27 (4) | 11.84 ± 0.61 82 (8) | 10.90 ± 0.71 57 (6) | 8.23 ± 1.42** 37 (6)
14 | 27.33 ± 0.89** 83 (7) | 17.42 ± 3.38** 21 (4) | 24.04 ± 0.62 79 (8) | 21.81 ± 1.28* 47 (6) | 12.69 ± 2.43** 28 (6)
21 | 38.55 ± 0.99** 83 (7) | 31.19 ± 4.16 21 (4) | 36.46 ± 1.62 79 (8) | 33.31 ± 1.35 47 (6) | 19.69 ± 3.92** 25 (5)
28 | 70.60 ± 1.63** 83 (7) | 55.54 ± 5.22* 21 (4) | 62.72 ± 2.08 79 (8) | 58.61 ± 1.92* 47 (6) | 28.48 ± 6.48** 25 (5)
1–28^e^ | 63.72 ± 1.49** 83 (7) | 50.28 ± 4.75* 21 (4) | 56.49 ± 2.02 79 (8) | 52.87 ± 2.05* 47 (6) | 24.20 ± 6.05** 25 (5)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

The 15,000 ppm group was removed on gestation day 10 or 11 due to excessive body weight loss.

^a^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^b^ Data are displayed as mean ± standard error of the litter means. Body weight data are presented in grams. Changes in n are the result of removing litters with no surviving pups by: postnatal day (PND) 1 (one litter with no surviving male pups in the 937.5 ppm group and one litter with no surviving female pups in the 7,500 ppm group), PND 7 (one litter with no surviving female pups in the 937.5 ppm group), and PND 17 (one litter with no surviving male or female pups in the 7,500 ppm group).

^c^ As litters were not standardized, pup weights throughout the entire postnatal period were adjusted using the total live litter size on PND 1.

^d^ n = the number of pups examined (number of litters).

^e^ Body weight gain (data are presented in grams).

Figure 6

Lactation Growth Curves for F_1_ Male Pups Following Perinatal Exposure to Bisphenol AF (Dose Range-finding Study)

Information for statistical significance in male pup weights is provided in Table 8.

Figure 7

Lactation Growth Curves for F_1_ Female Pups Following Perinatal Exposure to Bisphenol AF (Dose Range-finding Study)

Information for statistical significance in female pup weights is provided in Table 8.

### Exposure Concentration Selection Rationale for the Modified One-Generation Study of Bisphenol AF

The selection of 3,750 ppm BPAF as the high-exposure concentration was based on maternal and pup toxicity (significantly decreased body weights) observed at 7,500 ppm. Exposure concentration spacing (338, 1,125, and 3,750 ppm) was selected to achieve a no-observed-adverse-effect level and to avoid excessive overlap of the ingested doses due to increased feed consumption during pregnancy.

## Modified One-Generation Study

### F_0_ Generation: Maternal Findings

Maternal effects were evaluated from GD 6 through LD 28, as shown in Figure 8. Viability, clinical observations, gestation and lactation mean body weights, feed consumption, and reproductive performance results are presented below.

Figure 8

Design of the Modified One-Generation Study – F_0_ Generation

GD = gestation day; LD = lactation day; PND = postnatal day.

#### F_0_ Viability and Clinical Observations

BPAF exposure did not affect survival of the F_0_ females (Appendix E). No clinical observations were attributed to BPAF exposure during gestation or lactation (Appendix E).

#### F_0_ Gestation Body Weights and Feed Consumption

F_0_ females exposed to 3,750 ppm BPAF displayed biologically and statistically significantly decreased gestation body weights, and females exposed to 1,125 and 3,750 ppm showed significantly decreased body weight gains over the GD 6–21 interval (Table 9; Figure 9). On GD 21, the 3,750 ppm female mean body weights were significantly decreased by 13% relative to the control animals, and mean body weight gain over the GD 6–21 interval for the 1,125 and 3,750 ppm BPAF groups were significantly decreased by 21 and 40%, respectively, compared to the weight gain of the control group (Table 9). Consistent with observations in the dose range-finding study, there was a significant decrease in body weight gain at the beginning of the study at the higher exposure concentrations (1,125 and 3,750 ppm) and likely reflects lower palatability of the dosed feed. The significant decreases in mean body weight gain were sustained throughout most of gestation (GD 6–21) for both the 1,125 and 3,750 ppm groups. There were no effects of BPAF exposure on F_0_ female body weights during gestation in the 338 ppm group. There was no reduction in litter size on LD 0 in the BPAF-exposed groups; however, there was a significant decrease of LD 1 pup weights of 9% and 15% for the 1,125 and 3,750 ppm groups, respectively (Appendix E). This observation suggests that the lower relative maternal mean body weights could be due to an effect on the collective weight of the uterine contents.

Table 9 Summary of Mean Body Weights and Body Weight Gains of F_0_ Female Rats Exposed to Bisphenol AF in Feed during Gestation

Parameter^a,b^ | 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
Gestation Body Weight
Gestation Day
6 | 238.2 ± 1.9 (30) | 239.3 ± 2.5 (32) | 237.1 ± 2.1 (33) | 237.6 ± 2.1 (29)
9 | 250.8 ± 2.2** (30) | 250.2 ± 2.6 (32) | 240.4 ± 2.0** (33) | 233.8 ± 2.2** (29)
12 | 264.8 ± 2.5** (30) | 265.0 ± 2.9 (32) | 250.6 ± 2.2** (33) | 240.9 ± 2.4** (29)
15 | 283.0 ± 3.2** (30) | 282.9 ± 3.3 (32) | 266.7 ± 2.4** (33) | 251.8 ± 2.8** (29)
18 | 318.6 ± 5.1** (30) | 320.6 ± 4.4 (32) | 303.4 ± 2.9** (33) | 284.3 ± 3.5** (29)
21^c^ | 356.8 ± 7.6** (27) | 359.7 ± 5.9 (29) | 333.2 ± 3.8** (30) | 309.9 ± 4.4** (26)
Gestation Weight Change
Gestation Day Interval
6–21^c^ | 119.3 ± 7.0** (27) | 120.6 ± 4.2 (29) | 94.8 ± 2.9** (30) | 71.9 ± 4.1** (26)
3–6 | 13.4 ± 0.8 (30) | 15.0 ± 1.0 (32) | 15.6 ± 1.0 (33) | 13.7 ± 0.9 (29)
6–9 | 12.6 ± 0.5** (30) | 10.9 ± 0.8 (32) | 3.3 ± 0.8** (33) | −3.8 ± 0.9** (29)
9–12 | 14.0 ± 0.8** (30) | 14.8 ± 0.8 (32) | 10.1 ± 0.9** (33) | 7.1 ± 1.5** (29)
12–15 | 18.2 ± 1.4** (30) | 17.9 ± 1.0 (32) | 16.1 ± 0.9 (33) | 11.0 ± 1.0** (29)
15–18 | 35.6 ± 2.5** (30) | 37.7 ± 1.5 (32) | 36.7 ± 1.3 (33) | 32.5 ± 1.7 (29)
18–21 | 40.1 ± 2.7** (27) | 39.3 ± 1.8 (29) | 29.2 ± 1.6** (30) | 26.3 ± 1.6** (26)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

^a^ Data are displayed as mean ± standard error (n); body weight data are presented in grams.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Three dams were removed in each group on gestation day 18 for biological sample collection.

Figure 9

Growth Curves for F_0_ Female Rats Exposed to Bisphenol AF in Feed during Gestation

Information for statistical significance in maternal weights is provided in Table 9.

Significant variability in feed consumption was observed across the intervals in the 1,125 and 3,750 ppm groups (Table 10). Although the higher feed consumption values likely represented feed wastage, there was a negative trend for feed consumption for select intervals by the 1,125 and 3,750 ppm groups that corresponds with similar intervals showing significant decreases in mean body weight gain. BPAF intakes for F_0_ females in the 338, 1,125, and 3,750 ppm groups, based on feed consumption and dietary concentrations for GD 6–21, were approximately 24, 81, and 279 mg/kg/day, respectively.

Table 10 Summary of Feed and Test Article Consumption of F_0_ Female Rats Exposed to Bisphenol AF in Feed during Gestation

Gestation Day Interval^a,b^ | 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
Feed Consumption (g/animal/day)^c,d^
6–21 | 20.0 ± 0.3* (27) | 20.5 ± 0.4 (29) | 19.5 ± 0.7 (30) | 19.2 ± 0.5 (26)
3–6 | 17.7 ± 0.2 (30) | 18.2 ± 0.3 (32) | 18.2 ± 0.3 (33) | 17.7 ± 0.3 (29)
6–9 | 18.1 ± 0.3* (30) | 18.1 ± 0.3 (31) | 15.2 ± 0.7** (27) | 20.6 ± 2.9 (7)
9–12 | 18.8 ± 0.3** (29) | 18.8 ± 0.3 (32) | 16.4 ± 0.7** (32) | 15.5 ± 1.1** (29)
12–15 | 19.5 ± 0.3 (30) | 19.9 ± 0.5 (32) | 23.9 ± 1.6 (29) | 26.8 ± 5.3 (3)
15–18 | 22.4 ± 0.6** (30) | 23.1 ± 0.4 (32) | 20.6 ± 0.5** (33) | 18.6 ± 0.6** (26)
18–21^e^ | 22.0 ± 0.5 (27) | 22.1 ± 0.5 (29) | 19.1 ± 0.6** (30) | 23.5 ± 1.1 (18)
Chemical Intake (mg/kg/day)^f,g^
6–21 | 0.0 ± 0.0 (27) | 24.3 ± 0.3 (29) | 80.9 ± 2.6 (30) | 278.7 ± 7.8 (26)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are displayed as mean ± standard error (n), where n = the number of dams. Feed consumption is not reported for nonpregnant animals during the gestation phase.

^b^ For each dam, calculation of consumption values for the GD 6–21 interval was performed using all valid data for the animal, even if data were unavailable for some of the subintervals.

^c^ Feed consumption values were excluded when excessive spillage was recorded. One value was removed as an outlier for gestation day (GD) 12–15 from the 1,125 ppm group.

^d^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^e^ Three dams were removed in each group on GD 18 for biological sample collection.

^f^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^g^ No statistical analysis performed on the chemical intake data.

#### Maternal Reproductive Performance

Across all exposure groups, 16 out of 140 time-mated female rats were not pregnant: 5 in the control group, 3 in the 338 ppm group, 2 in the 1,125 ppm group, and 6 in the 3,750 ppm group (Table 11). There was no effect of BPAF exposure on the proportion of dams that produced viable litters; however, there was a slight but significant increase in gestation length for F_0_ dams in the 3,750 ppm group. There was no effect of BPAF exposure on initial mean litter size or sex ratio; however, LD 1 pup mean body weights were lower by 9% and 15% when compared to the control pups for the 1,125 and 3,750 ppm groups, respectively (Table 11).

Table 11 Summary of the Reproductive Performance of F_0_ Female Rats Exposed to Bisphenol AF in Feed during Gestation

Parameter^a^ | 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
Time-mated Females (GD 6) | 35 | 35 | 35 | 35
Females Pregnant (%) | 30 (85.7) | 32 (91.4) | 33 (94.3) | 29 (82.9)
Females Not Pregnant (%) | 5 (14.3) | 3 (8.6) | 2 (5.7) | 6 (17.1)
Dams Removed on GD 18^b^ | 3 | 3 | 3 | 3
Dams Not Delivering with Evidence of Pregnancy (%) | 2 (7.41) | 1 (3.44) | 1 (3.33) | 1 (3.85)
Dams with Litters on LD 0 (%)^c^ | 25 (92.6) | 28 (96.6) | 29 (96.7) | 25 (96.2)
Gestation Length (days)^d,e,f^ | 22.1 ± 0.1** (25) | 22.2 ± 0.1 (28) | 22.1 ± 0.1 (29) | 22.4 ± 0.1** (25)
Live Litter Size on LD 0^d,f^ | 13.2 ± 0.4 (24)^g^ | 11.9 ± 0.6 (28) | 12.9 ± 0.4 (28)^g^ | 12.5 ± 0.5 (24)^g^
LD 1 Pup Weight^f,h,i^ | 6.68 ± 0.07** 314 (24) | 6.40 ± 0.16 319 (28) | 6.06 ± 0.11** 354 (28) | 5.65 ± 0.16** 263 (23)^g^
Percent Live Male Pups per Litter^d,f^ | 43.01 ± 2.58 (24) | 50.64 ± 3.01 (28) | 49.27 ± 2.78 (28) | 50.58 ± 3.20 (24)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

GD = gestation day; LD = lactation day.

^a^ Animals removed from the study between mating and littering were excluded from calculations of % littered females.

^b^ Dams were removed on GD 18 for biological sample collection.

^c^ Percentage is the number of littered females/pregnant females. Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^d^ Statistical analysis was performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^e^ Gestation length calculated for sperm-positive females that delivered a litter.

^f^ Data are displayed as mean ± standard error (n).

^g^ Changes in n are the result of removing litters with no surviving pups by: LD 0 (one litter in the vehicle control group, one litter in the 1,125 ppm group, and one litter in the 3,750 ppm group) and LD 1 (one litter in the 3,750 ppm group).

^h^ n = the number of pups examined (number of litters).

^i^ Statistical analysis performed using mixed models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

#### Lactation Body Weights and Feed Consumption

F_0_ females in the 1,125 and 3,750 ppm BPAF groups displayed significant exposure concentration-dependent decreases in mean body weights during most of the lactation period (Table 12; Figure 10). There were no effects of BPAF exposure on F_0_ female body weights during lactation in the 338 ppm group.

Table 12 Summary of Mean Body Weights, Body Weight Gains, and Feed and Test Article Consumption of F_0_ Female Rats Exposed to Bisphenol AF in Feed during Lactation^a^

Lactation Day | 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
Body Weight (g)^b^
1 | 258.2 ± 3.1** (24) | 257.8 ± 3.8 (28) | 225.5 ± 2.9** (28) | 213.9 ± 3.0** (24)
10 | 298.0 ± 2.8** (23)^c^ | 294.0 ± 4.0 (24)^c,d^ | 272.3 ± 3.4** (25)^d^ | 253.6 ± 3.0** (23)^c^
13 | 306.5 ± 2.3** (23) | 304.1 ± 3.7 (24) | 275.6 ± 3.4** (25) | 255.3 ± 2.5** (22)^c^
16 | 306.5 ± 2.5** (23) | 303.1 ± 3.7 (24) | 282.8 ± 3.0** (25) | 267.7 ± 2.8** (22)
28 | 279.9 ± 3.3 (23) | 273.7 ± 3.1 (24) | 270.3 ± 3.0 (25) | 274.4 ± 3.0 (22)
Body Weight Gain (g)^b^
4–28 | 1.7 ± 2.5** (23) | –1.6 ± 2.6 (24) | 25.4 ± 2.5** (25) | 41.6 ± 2.8** (22)
Feed Consumption^e^
1–13 (g/animal/day) | 49.0 ± 0.7 (23) | 47.6 ± 1.1 (24) | 50.7 ± 1.4 (25) | 54.4 ± 2.3 (22)
1–13 (g/kg/day) | 172.5 ± 2.6** (23) | 168.7 ± 3.8 (24) | 198.3 ± 5.3** (25) | 227.3 ± 9.2** (22)
Chemical Intake (mg/kg/day)^f,g^
1–13 | 0.0 ± 0.0 (23) | 57.0 ± 1.3 (24) | 223.1 ± 6.0 (25) | 852.3 ± 34.5 (22)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

^a^ Data are displayed as mean ± standard error (n), where n = the number of dams. Feed consumption values were excluded when excessive spillage was recorded.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Dams with whole litter loss were removed on lactation day (LD) 1 (one dam in the 3,750 ppm group), LD 4 (one dam in the vehicle control group and one dam in the 338 ppm group), and LD 10 (one dam in the 3,750 ppm group).

^d^ Three dams were removed on LD 4 from the 338 and 1,125 ppm groups for biological sample collection.

^e^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^f^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^g^ No statistical analysis performed on the chemical intake data.

Figure 10

Growth Curves for F_0_ Female Rats Exposed to Bisphenol AF in Feed during Lactation

Information for statistical significance in maternal weights is provided in Table 12.

Feed consumption during the LD 1–13 interval was higher for both mean absolute (g/animal/day) and relative (g/kg/day) feed consumption by the 1,125 and 3,750 ppm groups, compared to the control group, with relative consumption significantly increased. Maternal feed consumption during lactation by the 338 ppm group was similar to the control group. BPAF intakes by F_0_ females, based on feed consumption and dietary concentrations for LD 1–13, were 57, 223, and 852 mg/kg/day for the 338, 1,125, and 3,750 ppm groups, respectively (Table 12).

### F_1_ Generation: Preweaning

F_1_ male and female rats were evaluated during the preweaning period from PND 0 through PND 28, as shown in Figure 11. Viability, clinical observations, and mean body weight results are presented below.

Figure 11

Design of the Modified One-Generation Study – F_1_ Generation: Preweaning

GD = gestation day; LD = lactation day; PND = postnatal day.

#### F_1_ Viability and Clinical Observations

There was a significant decrease in pup survival in the 3,750 ppm group over the PND 1–4 interval only; all other intervals were unaffected by BPAF exposure relative to the control group (Table 13; Appendix E). The mean number of live pups per litter was significantly decreased in the 3,750 ppm group on PNDs 4 (prestandardization) and 7 relative to the control group. Mean live litter size on PNDs 1 and 4 was lower by approximately two pups, with the total number of dead pups per litter significantly increased over the PND 1–4 interval in the 3,750 ppm group relative to the control group. Of note, one control female had a litter that did not survive through PND 4, and three females in the 3,750 ppm group had no live pups on PND 1 or low pup viability, resulting in their removal by PND 4. There was no effect of BPAF exposure on mean sex ratio (Table 11).

Table 13 Summary of F_1_ Litter Size and Pup Survival Following Perinatal Exposure to Bisphenol AF

Postnatal Day | 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
No. of Live Pups (Litters)^a^
0 | 316 (25) | 333 (28) | 361 (29) | 301 (25)
Total Litter Size^b,c^
0 | 13.2 ± 0.7 (25) | 13.2 ± 0.6 (28) | 13.4 ± 0.3 (29) | 13.2 ± 0.4 (25)
Live Litter Size^b,c^
0 | 13.2 ± 0.4 (24)^d^ | 11.9 ± 0.6 (28) | 12.9 ± 0.4 (28)^d^ | 12.5 ± 0.5 (24)^d^
1 | 13.0 ± 0.4 (24) | 11.4 ± 0.7 (28) | 12.6 ± 0.4 (28) | 11.4 ± 0.7 (23)^d^
4 (prestandardization) | 13.1 ± 0.4* (23)^d^ | 11.6 ± 0.6 (27)^d^ | 12.4 ± 0.4 (28) | 10.6 ± 0.8** (23)
4 (poststandardization) | 9.8 ± 0.2 (23) | 9.5 ± 0.3 (24)^e^ | 10.0 ± 0.0 (25)^e^ | 9.0 ± 0.5 (23)
7 | 9.8 ± 0.2* (23) | 9.4 ± 0.3 (24) | 9.7 ± 0.1 (25) | 8.8 ± 0.5* (23)
13 | 9.7 ± 0.2* (23) | 9.2 ± 0.4 (24) | 9.3 ± 0.3 (25) | 8.8 ± 0.4 (22)^d^
21 | 9.7 ± 0.2 (23) | 9.1 ± 0.4 (24) | 9.3 ± 0.3 (25) | 8.6 ± 0.4 (22)
28 | 9.7 ± 0.2 (23) | 9.0 ± 0.4 (24) | 9.2 ± 0.3 (25) | 8.6 ± 0.4 (22)
No. of Dead Pups (Litters)^a^
0 | 13 (12) | 37 (10) | 27 (12) | 29 (14)
1–4 | 15 (3) | 20 (9) | 13 (8) | 58 (12)
5–28 | 3 (3) | 9 (3) | 16 (7) | 16 (9)
Dead/Litter^b,c^
0 | 0.52 ± 0.12 (25) | 1.32 ± 0.58 (28) | 0.93 ± 0.36 (29) | 1.16 ± 0.48 (25)
1–4 | 0.63 ± 0.50* (24)^d^ | 0.71 ± 0.29 (28) | 0.46 ± 0.17 (28)^d^ | 2.42 ± 0.88* (24)^d^
5–28 | 0.13 ± 0.07* (23)^d^ | 0.38 ± 0.29 (24)^d,e^ | 0.64 ± 0.26 (25)^e^ | 0.70 ± 0.22 (23)^d^
Survival Ratio^b,c^
0 | 0.92 ± 0.04 (25) | 0.92 ± 0.03 (28) | 0.92 ± 0.04 (29) | 0.91 ± 0.04 (25)
1–4 | 0.95 ± 0.04* (24)^d^ | 0.92 ± 0.04 (28) | 0.96 ± 0.01 (28)^d^ | 0.82 ± 0.06* (24)^d^
5–28 | 0.99 ± 0.01* (23)^d^ | 0.96 ± 0.03 (24)^d,e^ | 0.94 ± 0.03 (25)^e^ | 0.88 ± 0.05 (23)^d^

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ n = the number of pups examined (number of litters). For no. of dead pups, n is the number of litters contributing dead pups.

^b^ Data are displayed as mean ± standard error of the litter means (n), where n = the number of litters. For F_1_ pups, data are displayed as the mean of litter values ± standard error (n) of litter values (number of litters produced by F_0_ dams).

^c^ F_1_ litter size and survival endpoints were analyzed using the Jonckheere (trend) and Shirley or Dunn tests (pairwise comparisons). All calculations were based on the last litter observation of the day.

^d^ Changes in n are the result of removing litters with no surviving pups by: postnatal day (PND) 0 (one litter in the vehicle control group, one litter in the 1,125 ppm group, and one litter in the 3,750 ppm group), PND 1 (one litter in the 3,750 ppm group), PND 2 (one litter in the 338 ppm group), PND 4 (one litter in the vehicle control group), and PND 10 (one litter in the 3,750 ppm group).

^e^ Decreased number of litters at PND 4 in the 338 and 1,125 ppm groups reflects the animals removed for biological sample collection.

Clinical observations associated with BPAF exposure occurred in the 3,750 ppm group and were limited to yellow stained fur, which was observed in nine individual female pups across five litters from PND 21 through PND 28. Clinical observations noted in individual pups from all exposure groups, including the control group, were typically indicative of an individual pup not thriving (e.g., no milk in stomach, cold to touch). Other findings observed, including sores, swelling, alopecia, tail damage, and nasal discharge, were limited to a few pups or were only observed in the control group.

#### F_1_ Body Weights

##### Male Pups

Male pup mean body weights were significantly decreased throughout the lactation period, with weights 12% and 30% less than the control group on PND 28 for the 1,125 and 3,750 ppm groups, respectively (Table 14; Figure 12).

Table 14 Summary of F_1_ Male and Female Pup Mean Body Weights and Body Weight Gains Following Perinatal Exposure to Bisphenol AF^a,b^

Postnatal Day | 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
Male
1 | 6.82 ± 0.07** 135 (24)^c^ | 6.58 ± 0.17 168 (28) | 6.18 ± 0.12** 178 (28) | 5.84 ± 0.19** 136 (23)
4^d^ | 9.65 ± 0.23** 135 (24) | 9.70 ± 0.20 164 (27)^e^ | 8.53 ± 0.18** 175 (28) | 7.74 ± 0.32** 125 (23)
7 | 14.43 ± 0.32** 104 (23)^e^ | 14.38 ± 0.41 118 (24)^f^ | 12.48 ± 0.35** 117 (25)^f^ | 11.93 ± 0.46** 106 (23)
13 | 27.57 ± 0.47** 102 (23) | 26.77 ± 0.73 115 (24) | 24.08 ± 0.56** 111 (25) | 21.55 ± 0.56** 104 (22)^e^
28 | 77.54 ± 1.30** 102 (23) | 76.34 ± 1.38 113 (24) | 68.49 ± 1.31** 111 (25) | 53.94 ± 1.48** 102 (22)
4–28^g^ | 67.77 ± 1.16** 102 (23) | 66.60 ± 1.29 113 (24) | 59.79 ± 1.18** 111 (25) | 45.82 ± 1.32** 102 (22)
Female
1 | 6.57 ± 0.07** 179 (24) | 6.34 ± 0.12 151 (27)^e^ | 5.98 ± 0.11** 176 (28) | 5.56 ± 0.12** 127 (22)^e^
4^d^ | 9.17 ± 0.22** 177 (24) | 9.15 ± 0.19 149 (27) | 8.40 ± 0.19* 173 (28) | 7.57 ± 0.19** 118 (22)
7 | 13.79 ± 0.29** 121 (23)^e^ | 13.52 ± 0.39 108 (24)^f^ | 12.46 ± 0.35* 125 (25)^f^ | 11.28 ± 0.41** 96 (22)
13 | 26.18 ± 0.53** 121 (23) | 25.70 ± 0.63 105 (24) | 23.49 ± 0.52** 122 (25) | 20.75 ± 0.53** 90 (22)
28 | 71.32 ± 1.34** 120 (23) | 69.14 ± 1.13 104 (24) | 64.65 ± 1.31** 119 (25) | 51.92 ± 1.33** 88 (22)
4–28^g^ | 62.05 ± 1.21** 120 (23) | 59.93 ± 1.00 104 (24) | 56.09 ± 1.18** 119 (25) | 44.15 ± 1.18** 88 (22)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons. Pup weights were adjusted for covariate litter size: total live on postnatal day (PND) 1 for day 1 through day 4 and number of live pups poststandardization for later days.

^b^ Data are displayed as mean ± standard error of the litter means. Body weights are presented in grams.

^c^ n = the number of pups examined (number of litters).

^d^ PND 4 weights are prestandardization.

^e^ Changes in n are the result of removing litters with no surviving pups by: PND 1 (one litter with no surviving female pups in the 338 ppm group and one litter with no surviving female pups in the 3,750 ppm group), PND 2 (one litter with no surviving male pups in the 338 ppm group), PND 4 (one litter in the vehicle control group, after pups were weighed on PND 4), and PND 10 (one litter with no surviving male pups in the 3,750 ppm group).

^f^ Decreased number of litters at PND 7 in the 338 and 1,125 ppm groups reflects the animals removed at PND 4 for biological sample collection.

^g^ Body weight gain (data are presented in grams).

Figure 12

Lactation Growth Curves for F_1_ Male Pups Following Perinatal Exposure to Bisphenol AF

Information for statistical significance in male pup weights is provided in Table 14.

##### Female Pups

Female pup mean body weights were also significantly decreased for both the 1,125 and 3,750 ppm groups throughout the lactation period compared to the control group. Pup weights were 9% and 27% less than the control group on PND 28 for the 1,125 and 3,750 ppm groups, respectively (Table 14; Figure 13).

Figure 13

Lactation Growth Curves for F_1_ Female Pups Following Perinatal Exposure to Bisphenol AF

Information for statistical significance in female pup weights is provided in Table 14.

#### F_0_ Necropsy

F_0_ dams were necropsied on LD 28 following pup weaning, when the F_0_ dams were approximately 19 weeks of age. There were no BPAF-related gross or microscopic findings in the F_0_ females. Gross findings in the dams at scheduled necropsy were limited to singular incidences or were not exposure related (e.g., one control female with an ovarian cyst, two females at 338 ppm with a hepatodiaphragmatic nodule, and one female at 3,750 ppm with a thickened uterus) (Appendix E). Microscopic findings were limited to confirmation of gross findings.

### F_1_ Generation: Postweaning through Sexual Maturity

F_1_ male and female rats were evaluated from postweaning through sexual maturity, as shown in Figure 14. Viability, clinical observations, mean body weights, feed consumption, and developmental endpoint results are presented below.

Figure 14

Design of the Modified One-Generation Study – F_1_ Generation: Postweaning

GD = gestation day; LD = lactation day; PND = postnatal day.

#### F_1_ Viability and Clinical Observations

There was no effect of BPAF exposure on the survival of F_1_ males or females, with the exception of two females in the 3,750 ppm group that were euthanized due to malformations of the vagina (no apparent vaginal opening) (Appendix E). Three additional unscheduled deaths were recorded but were not deemed related to BPAF exposure (one pup in the 3,750 ppm group sustained tail damage during a cage change, one pup in the control group was found moribund, and one pup in the 338 ppm group was found dead with necropsy findings of nodules on the liver and spleen and diagnosed as having malignant leukemia).

Clinical observations of small testis or missing testis was noted in 26 and 17 male pups, respectively, in the 3,750 ppm group. No BPAF-related clinical observations were noted in the F_1_ female pups. All other clinical observations noted were across all exposure groups, including the control groups, on a sporadic basis (Appendix E).

#### F_1_ Body Weights and Feed Consumption

##### Males (Postweaning)

Mean body weights between PND 28 and PND 98 were significantly decreased in males in the 1,175 and 3,750 ppm groups (Table 15; Figure 15). Male mean body weights for the 1,125 and 3,750 ppm groups were lower by 11% and 30% relative to the control group, respectively, on PND 28 and lower by 13% and 38% relative to the control group, respectively, on PND 98. Mean body weights for F_1_ males in the 338 ppm group were ≥95% of the control group from PND 28 through PND 98.

Table 15 Summary of Postweaning Mean Body Weights, Body Weight Gains, and Feed and Test Article Consumption of All F_1_ Male Rats Exposed to Bisphenol AF in Feed

Postnatal Day^a^ | 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
Body Weight (g)^b,c^
28 | 76.3 ± 1.4** 54 (22) | 75.5 ± 1.5 55 (24) | 67.6 ± 1.4** 53 (22) | 53.6 ± 1.6** 50 (20)
91 | 376.0 ± 3.9** 54 (22) | 362.4 ± 4.8 54 (24) | 325.4 ± 4.8** 53 (22) | 231.2 ± 4.4** 50 (20)
98 | 386.3 ± 4.4** 54 (22) | 373.7 ± 5.2 54 (24) | 334.4 ± 5.0** 53 (22) | 238.3 ± 4.6** 50 (20)
105 | 397.0 ± 4.0** 54 (22) | 383.0 ± 5.3 54 (24) | 344.0 ± 5.0** 53 (22) | 245.0 ± 4.4** 50 (20)
Body Weight Gain (g)^b,c^
28–91 | 299.7 ± 3.0** 54 (22) | 286.9 ± 4.4 54 (24) | 257.8 ± 4.1** 53 (22) | 177.5 ± 4.0** 50 (20)
Postweaning Feed Consumption^d,e^
28–98 (g/animal/day) | 21.8 ± 0.2** (25) | 21.3 ± 0.4 (26) | 19.8 ± 0.3** (24) | 18.5 ± 0.3** (25)
28–98 (g/kg/day) | 80.3 ± 0.5** (25) | 81.9 ± 0.9 (26) | 86.7 ± 1.4** (24) | 109.5 ± 2.2** (25)
Chemical Intake (mg/kg/day)^e,f,g^
28–98 | 0.0 ± 0.0 (25) | 27.7 ± 0.3 (26) | 97.5 ± 1.5 (24) | 410.6 ± 8.2 (25)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

^a^ Data are displayed as mean ± standard error (n). Feed consumption values were excluded when excessive spillage was recorded.

^b^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple comparisons.

^c^ n = the number of pups examined (number of litters).

^d^ Statistical analysis performed using the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^e^ n = number of cages.

^f^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^g^ No statistical analysis performed on the chemical intake data.

Figure 15

Postweaning Growth Curves for All F_1_ Male Rats Exposed to Bisphenol AF in Feed

Information for statistical significance in F_1_ male rat weights is provided in Table 15.

There was a significant decrease in absolute feed consumption (g/animal/day) over the PND 28–98 interval by the F_1_ males in the 1,125 and 3,750 ppm groups (Table 15); however, this might have resulted from the reduced size of the pups in these groups given that relative feed consumption values (g/kg/day) were similar to—or significantly increased compared to—the control group. Feed consumption by F_1_ males in the 338 ppm group was similar to the control group—although significant decreases in absolute feed consumption were observed for some time intervals, overall feed consumption during the postweaning period was similar to the control group (Appendix E).

BPAF intakes by F_1_ males, based on feed consumption and dietary concentrations for PND 28–98, were 28, 98, and 411 mg/kg/day at 338, 1,125, and 3,750 ppm, respectively.

##### Females (Postweaning)

Female F_1_ mean body weights between PND 28 and PND 98 were significantly decreased in the 1,125 and 3,750 ppm groups (Table 16; Figure 16). On PND 28, mean body weights for the 1,125 and 3,750 ppm groups were lower by 9% and 26% relative to the control group, respectively, and by PND 98, mean body weights were lower by 15% and 29% relative to the control group, respectively. Mean body weights of F_1_ females in the 338 ppm group were significantly decreased by approximately 6% compared to the control animals on PND 98.

Table 16 Summary of Postweaning Mean Body Weights, Body Weight Gains, and Feed and Test Article Consumption of All F_1_ Female Rats Exposed to Bisphenol AF in Feed

Postnatal Day^a^ | 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
Body Weight (g)^b,c^
28 | 69.5 ± 1.4** 66 (22) | 69.3 ± 1.3 66 (24) | 63.5 ± 1.6** 58 (22) | 51.5 ± 1.4** 58 (22)
91 | 238.3 ± 3.3** 53 (22) | 223.8 ± 3.6** 55 (24) | 202.2 ± 2.3** 53 (22) | 169.9 ± 2.2** 48 (22)
98 | 242.9 ± 3.4** 53 (22) | 227.2 ± 3.7** 55 (24) | 206.0 ± 2.3** 53 (22) | 172.6 ± 2.3** 48 (22)
Body Weight Gain (g)^b,c^
28–98 | 173.3 ± 2.9** 53 (22) | 157.8 ± 3.1** 55 (24) | 142.6 ± 2.1** 53 (22) | 121.2 ± 1.7** 48 (22)
Postweaning Feed Consumption^d,e^
28–98 (g/animal/day) | 15.6 ± 0.2** (25) | 16.3 ± 0.4 (26) | 15.6 ± 0.4 (24) | 14.5 ± 0.4* (24)
28–98 (g/kg/day) | 86.7 ± 1.1** (25) | 94.4 ± 1.7** (26) | 100.5 ± 2.1** (24) | 109.5 ± 1.9** (24)
Chemical Intake (mg/kg/day)^e,f,g^
28–98 | 0.0 ± 0.0 (25) | 31.9 ± 0.6 (26) | 113.0 ± 2.3 (24) | 410.8 ± 7.2 (24)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are displayed as mean ± standard error (n). Feed consumption values were excluded when excessive spillage was recorded.

^b^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple comparisons.

^c^ n = the number of pups examined (number of litters).

^d^ Statistical analysis performed using the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^e^ n = number of cages.

^f^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^g^ No statistical analysis performed on the chemical intake data.

Figure 16

Postweaning Growth Curves for All F_1_ Female Rats Exposed to Bisphenol AF in Feed

Information for statistical significance in F_1_ female rat weights is provided in Table 16.

Similar to the F_1_ male pups, a significant decrease in absolute feed consumption (g/animal/day) by the F_1_ females in the 3,750 ppm group was observed for the PND 28–98 interval (Table 16), but relative feed consumption values (g/kg/day) were significantly increased compared to the control group. This finding is likely due to the reduced size of these pups. Absolute feed consumption by F_1_ females in the 338 and 1,125 ppm groups was similar to that of the control group, although a significant increase in relative feed consumption was observed, resulting in a 9% and 16% increase in overall consumption, respectively, compared to the control females.

BPAF intakes for F_1_ females, based on feed consumption and dietary concentrations for PND 28–98, were 32, 113, and 411 mg/kg/day at 338, 1,125, and 3,750 ppm, respectively.

### Developmental Endpoints

#### Anogenital Distance

F_1_ and F_2_ male and female offspring exposed to BPAF did not display any pairwise significant alterations in anogenital distance (AGD) or in PND 1 mean body weight-adjusted AGD; however, a positive trend in body weight-adjusted AGD with exposure concentration was noted for the F_1_ females (Table 17).

Table 17 Summary of Anogenital Distance of F_1_ and F_2_ Male and Female Rats Exposed to Bisphenol AF in Feed

Parameter^a^ | 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
F_1_ Males
No. Examined^b^ | 135 (24) | 168 (28) | 178 (28) | 136 (23)
Adjusted AGD (mm)^c,d^ | 2.22 ± 0.03 | 2.19 ± 0.03 | 2.20 ± 0.03 | 2.22 ± 0.04
F_2_ Males
No. Examined | 79 (17) | 108 (19) | 32 (7) | –^e^
Adjusted AGD (mm) | 2.12 ± 0.03 | 2.22 ± 0.03 | 2.14 ± 0.04 | –
F_1_ Females
No. Examined | 179 (24) | 151 (27) | 176 (28) | 127 (22)
Adjusted AGD (mm) | 1.10 ± 0.02* | 1.11 ± 0.02 | 1.09 ± 0.02 | 1.17 ± 0.03
F_2_ Females
No. Examined | 118 (18) | 102 (19) | 26 (7) | –
Adjusted AGD (mm) | 1.14 ± 0.03 | 1.10 ± 0.03 | 1.07 ± 0.02 | –

Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

PND = postnatal day; AGD = anogenital distance.

^a^ Data are displayed as mean ± standard error unless otherwise noted; values are based on litter means, not individual pup values. Animals found dead, cannibalized, or missing (presumed dead) were excluded from analysis.

^b^ No. Examined = number of pups examined (number of litters represented).

^c^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^d^ Adjusted AGD calculated using the formula: adjusted AGD = raw AGD – (slope*[body weight for that animal – overall body weight mean]), where the slope is the regression slope of AGD versus body weight.

^e^ No F_1_ females were confirmed pregnant for the 3,750 ppm group in either the prenatal or reproductive performance cohorts.

#### Areolae/Nipple Retention on PND 13

F_1_ and F_2_ male offspring exposed to BPAF did not display any signs of areolae/nipple retention (Appendix E).

#### Testicular Descent

There was no acceleration or delay in day of testicular descent for F_1_ males; however, there was one male in the 1,125 ppm group and 11 males out of 7 litters in the 3,750 ppm group that did not attain testicular descent (Table 18; Figure 17). F_2_ males exhibited a significant delay in testicular descent of approximately 2 days in the 1,125 ppm group compared to the control group.

Table 18 Summary of Testicular Descent of F_1_ and F_2_ Male Rats Exposed to Bisphenol AF in Feed

Parameter^a^ | 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
F_1_ Males
No. Examined^b^ | 102 (23) | 113 (24) | 111 (25) | 102 (22)
No. Removed^c^ | 0 | 0 | 0 | 1 (1)
No. Not Attaining^d^ | 0 | 0 | 1 (1) | 11 (7)
Mean (Day of Descent)^e,f^ | 18.0 ± 0.2 | 17.9 ± 0.2 | 17.7 ± 0.3 | 18.1 ± 0.5
Proportional Hazards Model, p value^g^ | <0.001 | 0.999 | 0.999 | 0.005
F_2_ Males
No. Examined | 52 (17) | 70 (19) | 27 (7) | –^h^
No. Removed | 0 | 0 | 0 | –
No. Not Attaining | 1 (1) | 0 | 0 | –
Mean (Day of Descent) | 15.8 ± 0.4** | 16.4 ± 0.3 | 17.7 ± 0.3* | –
Proportional Hazards Model, p value | 0.006 | 0.476 | 0.059 | –

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are displayed as mean ± standard error unless otherwise noted; values are based on litter means, not individual pup values.

^b^ No. Examined = number of pups examined (number of litters).

^c^ No. Removed = number of pups (number of litters) that died or were removed prior to the end of the observation period and did not attain. These animals were excluded from all analyses.

^d^ No. Not Attaining = number of pups (number of litters) that survived to the end of the observation period without attaining testicular descent.

^e^ Summary statistics and mixed model results are presented for animals that attained during the observation period.

^f^ Statistical analysis performed using mixed models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^g^ p values for trend and pairwise comparisons for the proportional hazards analysis were calculated from a Cox proportional hazards model with random effect for litter and a Hommel adjustment for multiple comparisons.

^h^ No F_1_ females were confirmed pregnant for the 3,750 ppm group in either the prenatal or reproductive performance cohorts.

Figure 17

Time to Testicular Descent of F_1_ and F_2_ Male Offspring Exposed to Bisphenol AF in Feed

Cumulative response curves are shown for (A) F_1_ and (B) F_2_ males.

#### Vaginal Opening

All BPAF-exposed females in both the F_1_ and F_2_ generations exhibited a significant acceleration in litter mean day of vaginal opening (VO) and litter mean day of VO when adjusted for body weight at weaning, relative to the control groups (Table 19). For F_1_ and F_2_ females, Figure 18 and Figure 19, respectively, show litter and adjusted litter cumulative response (%), or cumulative probability of attainment, plotted against PND for each exposure group. The litter cumulative response curves display an exposure concentration-related shift to the left for unadjusted values. For the F_1_ generation, when weaning body weight was used to adjust day of VO attainment, the shift was slightly less pronounced, at approximately 2, 8, and 8 days in the 338, 1,125, and 3,750 ppm groups, respectively. For the F_2_ generation, the shift was approximately 3 and 10 days for the 338 and 1,125 ppm groups, respectively (there were no F_2_ pups in the 3,750 ppm group).

Table 19 Summary of Vaginal Opening of F_1_ and F_2_ Female Rats Exposed to Bisphenol AF in Feed

Parameter^a^ | 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
F_1_ Females
No. Examined^b^ | 66 (22) | 67 (24) | 65 (22) | 60 (22)
No. Not Attaining^c^ | 0 | 0 | 0 | 0
Day of VO
Litter mean^d,e^ | 34.6 ± 0.3** | 32.8 ± 0.4* | 27.8 ± 0.4** | 30.0 ± 0.8**
Adjusted litter mean^d,e,f^ | 35.8 ± 0.3** | 33.8 ± 0.3** | 27.8 ± 0.3** | 27.9 ± 0.7**
Mean Body Weight at Acquisition (g)^g^ | 103.2 ± 1.7** | 90.9 ± 1.6** | 63.2 ± 1.4** | 60.5 ± 2.6**
Mean Body Weight at Weaning (g)^g^ | 71.4 ± 1.6** | 70.3 ± 1.3 | 64.9 ± 1.7** | 53.0 ± 1.4**
F_2_ Females
No. Examined | 78 (18) | 77 (19) | 20 (7) | –^h^
No. Not Attaining | 0 | 0 | 0 | –
Day of VO
Litter mean | 34.3 ± 0.3** | 31.6 ± 0.6** | 25.8 ± 0.5** | –
Adjusted litter mean | 34.7 ± 0.3** | 31.3 ± 0.6** | 25.1 ± 0.5** | –
Mean Body Weight at Acquisition (g) | 113.8 ± 1.8** | 94.3 ± 2.5** | 65.9 ± 2.2** | –
Mean Body Weight at Weaning (g) | 82.3 ± 1.7* | 77.8 ± 1.2 | 75.2 ± 1.8* | –

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

VO = vaginal opening.

^a^ Data are displayed as mean ± standard error unless otherwise noted; values are based on litter means, not individual pup values.

^b^ No. Examined = the number of pups examined (number of litters).

^c^ No. Not Attaining = number of pups that survived to the end of the observation period without attaining VO.

^d^ Summary statistics and mixed model results are presented for animals that attained during the observation period.

^e^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^f^ Adjusted based on body weight at weaning. Associated mixed model results reflect inclusion of weaning weight as a covariate.

^g^ Analysis of body weight at acquisition and body weight at weaning for both linear trend and pairwise comparisons performed using mixed effects models with litter as a random effect and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^h^ No F_1_ females were confirmed pregnant for the 3,750 ppm group in either the prenatal or reproductive performance cohorts.

Figure 18

Time to Vaginal Opening of F_1_ Female Offspring Exposed to Bisphenol AF in Feed

Cumulative response curves are shown for (A) litter response and (B) litter response adjusted for body weight at weaning.

Figure 19

Time to Vaginal Opening of F_2_ Female Offspring Exposed to Bisphenol AF in Feed

Cumulative response curves are shown for (A) litter response and (B) litter response adjusted for body weight at weaning.

#### Balanopreputial Separation

F_1_ and F_2_ male rats in the 1,125 and 3,750 (F_1_ only) ppm groups displayed a significant delay in litter mean day of attaining balanopreputial separation (BPS) and litter mean day of BPS when adjusted for body weight at weaning, relative to the control groups (Table 20). Figure 20 and Figure 21 show litter and adjusted litter cumulative response (%), or cumulative probability of attainment, plotted against PND for each exposure for F_1_ and F_2_ males, respectively. The litter cumulative response curves for these exposure groups display an exposure concentration-related shift to the right for unadjusted values. When weaning body weight was used to adjust day of BPS attainment, the shift was approximately 4 and 32 days in the 1,125 and 3,750 ppm groups, respectively, for the F_1_ generation. The shift was approximately 6 days for the F_2_ generation at 1,125 ppm (there were no F_2_ pups in the 3,750 ppm group). Ten F_1_ males from nine litters in the 3,750 ppm group did not achieve BPS as of PND 98, when checks for this marker stopped.

Table 20 Summary of Balanopreputial Separation of F_1_ and F_2_ Male Rats Exposed to Bisphenol AF in Feed

Parameter^a^ | 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
F_1_ Males
No. Examined^b^ | 54 (22) | 55 (24) | 53 (22) | 50 (20)
No. Not Attaining^c^ | 0 | 0 | 0 | 10 (9)
Day of BPS
Litter mean^d,e^ | 45.6 ± 0.3** | 45.3 ± 0.4 | 51.1 ± 0.7** | 80.0 ± 2.1**
Adjusted litter mean^d,e,f^ | 46.4 ± 0.2** | 46 ± 0.3 | 50.8 ± 0.7** | 78.3 ± 2.1**
Proportional hazards analysis model, p value^g^ | <0.001 | 0.115 | <0.001 | <0.001
Mean Body Weight at Acquisition (g)^h^ | 200.4 ± 1.8** | 188.0 ± 2.1** | 195.1 ± 3.5 | 217.9 ± 3.6**
Mean Body Weight at Weaning (g)^h^ | 77.5 ± 1.3** | 77.0 ± 1.6 | 68.6 ± 1.5** | 55.4 ± 1.7**
F_2_ Males
No. Examined | 52 (17) | 70 (19) | 27 (7) | –^i^
No. Not Attaining | 0 | 0 | 0 | –
Day of BPS
Litter mean | 45.7 ± 0.7** | 44.8 ± 0.3 | 53.3 ± 1.3** | –
Adjusted litter mean | 46.5 ± 0.7** | 45.0 ± 0.4 | 52.1 ± 1.1** | –
Mean Body Weight at Acquisition (g) | 209.5 ± 4.4 | 195.1 ± 2.6* | 222.1 ± 7.4 | –
Mean Body Weight at Weaning (g) | 89.4 ± 2.4* | 86.8 ± 1.5 | 79.9 ± 4.2 | –

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BPS = balanopreputial separation.

^a^ Data are displayed as mean ± standard error unless otherwise noted; values are based on litter means, not individual pup values.

^b^ No. Examined = the number of pups examined (number of litters).

^c^ No. Not Attaining = number of pups (number of litters) that survived to the end of the observation period without attaining BPS.

^d^ Summary statistics and mixed model results are presented for animals that attained during the observation period.

^e^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^f^ Adjusted based on body weight at weaning. Associated mixed model results reflect inclusion of weaning weight as a covariate.

^g^ p values for trend and pairwise comparisons for the proportional hazards analysis were calculated from a Cox proportional hazards model with exposure concentration and weaning weight as covariates and a random effect for litter and a Hommel adjustment for multiple comparisons.

^h^ Analysis of body weight at acquisition and body weight at weaning for both linear trend and pairwise comparisons performed using mixed effects models with litter as a random effect and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^i^ No F_1_ females were confirmed pregnant for the 3,750 ppm group in either the prenatal or reproductive performance cohorts.

Figure 20

Time to Balanopreputial Separation of F_1_ Male Offspring Exposed to Bisphenol AF in Feed

Cumulative response curves are shown for (A) litter response and (B) litter response adjusted for body weight at weaning.

Figure 21

Time to Balanopreputial Separation of F_2_ Male Offspring Exposed to Bisphenol AF in Feed

Cumulative response curves are shown for (A) litter response and (B) litter response adjusted for body weight at weaning.

## F_1_ Cohort Data

### Prenatal and Reproductive Performance Cohorts: Mating and Fertility

F_1_ male and female rats from the prenatal and reproductive performance cohorts were mated and evaluated for reproductive endpoints, as shown in Figure 22. Viability, clinical observations, vaginal estrous cyclicity, fertility, andrology, mean body weights, and feed consumption results are presented below.

Figure 22

Design of the Modified One-Generation Study – Prenatal and Reproductive Performance Cohorts

GD = gestation day; LD = lactation day; PND = postnatal day.

#### Viability and Clinical Observations

There were no exposure-related deaths. Clinical observations associated with BPAF exposure were limited to small testis or missing testis in the 3,750 ppm group males and no apparent vaginal opening for one female in the 3,750 ppm group. A second female in the 3,750 ppm group with no vaginal opening was found in the biological sampling cohort (Appendix E). All other clinical observations were singular incidences found across all groups, including the control group.

#### Selection and Mating

One male and one female rat (1:1) from each litter were allocated to the prenatal and reproductive performance cohorts, avoiding sibling mating. Vaginal lavage samples were collected for approximately 2 weeks until evidence of mating or until the cohabitation period was completed.

#### Vaginal Cytology

Estrous cyclicity was assessed in F_1_ females allocated to the prenatal, reproductive performance, and subchronic cohorts, and analysis was performed on combined F_1_ cohorts. For the F_1_ cohorts, estrous cycle length was significantly longer than the control group in the 1,125 ppm group (Table 21). There were no exposure-related changes in number of cycles for the animals that were cycling. In the 3,750 ppm group, 42 out of 47 animals were not cycling and in persistent estrus (Appendix E). Model-based estimates of stage lengths for the 3,750 ppm group were significantly different from the control group for length of estrus (approximately 12 days longer than the control group, p < 0.01), proestrus (approximately one-third of a day longer than the control group, p < 0.01), and diestrus (approximately 2 days shorter than the control group, p < 0.01) (Table 21; Figure 23). For the F_2_ cohort, estrous cycle length was significantly longer than the control group in the 338 and 1,125 ppm groups (Table 21). Model-based estimates of stage lengths for the 338 ppm group were significantly different from the control group for length of proestrus (approximately 0.1 days shorter than the control group, p < 0.01) and estrus (approximately 0.2 days shorter than the control group, p < 0.05) (Table 21; Figure 24). There were no 3,750 ppm F_2_ females due to no pregnancies in F_1_ females mated at 3,750 ppm.

Table 21 Summary of Estrous Cycle Data and Markov Model Estimates of Estrous Stage Length and 95% Confidence Intervals for All F_1_ and F_2_ Female Rats Exposed to Bisphenol AF in Feed

| 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
F_1_ Females
No. of Regular Cycling Females^a^ | 46 (22) | 48 (23) | 46 (22) | 5 (4)
Estrous Cycle Length (days)^b^ | 4.97 ± 0.26 | 5.06 ± 0.18 | 5.40 ± 0.18* | –^c^
Estrous Stage Length^d,e^
Diestrus | 2.7 (2.4, 3.2) | 2.8 (2.4, 3.2) | 3.3 (3.0, 3.7) | 0.5** (0.3, 0.7)
Proestrus | 0.4 (0.3, 0.4) | 0.3 (0.2, 0.4) | 0.4 (0.3, 0.5) | 0.7** (0.4, 1.0)
Estrus | 1.4 (1.3, 1.5) | 1.3 (1.2, 1.4) | 1.4 (1.1, 1.7) | 13.1** (7.8, 23.5)
Metestrus^f^ | 0.1 | 0.1 | 0.1 | 0.1
F_2_ Females
No. of Regular Cycling Females | 71 (18) | 71 (19) | 20 (7) | –^g^
Estrous Cycle Length (days) | 4.88 ± 0.21 | 5.11 ± 0.19* | 5.22 ± 0.17* | –^g^
Estrous Stage Length
Diestrus | 2.1 (1.9, 2.4) | 2.2 (2.0, 2.5) | 2.4 (2.0, 2.9) | –^g^
Proestrus | 0.2 (0.2, 0.3) | 0.1** (0.0, 0.1) | 0.1 (0.1, 0.2) | –^g^
Estrus | 1.5 (1.4, 1.6) | 1.3* (1.2, 1.4) | 1.4 (1.1, 1.7) | –^g^
Metestrus | 0.2 | 0.2 | 0.2 | –^g^

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. *Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ No. of Regular Cycling Females = number of animals cycling (number of litters).

^b^ Estrous cycle length data are presented as mean ± standard error. Animals not cycling were excluded from the cycle length calculation. Pairwise tests performed using the Datta-Satten modified Wilcoxon test with a Hommel adjustment for multiple comparisons.

^c^ Cycle length and number of cycles were not calculated for the 3,750 ppm group due to the large number of animals that were not cycling.

^d^ Estrous stage length data are presented as days (95% confidence interval).

^e^ Pairwise tests are performed using a permutation null hypothesis testing method and have been adjusted for multiple comparisons using a Hommel correction within each stage.

^f^ Due to a very low number of observations of metestrus, stage lengths were estimated using a profile likelihood approach. As a result, confidence intervals are not available for the metestrus stage length estimate.

^g^ No F_1_ females were confirmed pregnant for the 3,750 ppm group in either the prenatal or reproductive performance cohorts.

Figure 23

Markov Model Estimates of Stage Lengths and 95% Confidence Intervals for F_1_ Female Rats Exposed to Bisphenol AF in Feed

Dots = estimated stage lengths; bars = 95% confidence intervals; low = 338 ppm; mid = 1,250 ppm; high = 3,750 ppm. Metestrus estimates are not shown here due to very low numbers of observations of this stage. Y-axis scales differ for each stage.

Figure 24

Markov Model Estimates of Stage Lengths and 95% Confidence Intervals for F_2_ Female Rats Exposed to Bisphenol AF in Feed

Dots = estimated stage lengths; bars = 95% confidence intervals; low = 338 ppm; mid = 1,250 ppm. Metestrus estimates are not shown here due to very low numbers of observations of this stage. There were no results for the high-exposure concentration (3,750 ppm) group due to a lack of pregnant F_1_ females in that group. Y-axis scales differ for each stage.

#### Fertility

There were no pregnant F_1_ females in the 3,750 ppm group for either the prenatal or reproductive performance cohorts, indicating that F_1_ male and/or female fertility was affected by BPAF exposure in the 3,750 ppm group. For both the prenatal and reproductive performance cohorts, there was a negative trend with exposure concentration for the percentage of paired females that mated, with significant decreases in the 3,750 ppm groups. A significant decrease was also noted in the reproductive performance cohort at 1,125 ppm but not in the prenatal cohort; this result is possibly due to the differences in control group values. For the reproductive performance cohort, there was a negative trend with exposure concentration for the percentage of mated females that became pregnant and the percentage of mated females that littered; however, no trend was observed for percentage of mated females that became pregnant in the prenatal cohort (Table 22).

Table 22 Summary of Mating and Fertility Performance of F_1_ Male and Female Rats Exposed to Bisphenol AF in Feed

Parameter | 0 ppm | | 338 ppm | | 1,125 ppm | | 3,750 ppm
Parameter | RPC | PC | RPC | PC | RPC | PC | RPC | PC
No. Mating Pairs | 22 | 21 | 23 | 21 | 21 | 22 | 19 | 19
No. Mated | 22 | 17 | 23 | 20 | 16 | 19 | 1 | 0
No. Females Pregnant | 18 | 17 | 22 | 20 | 12 | 18 | 0 | 0
Percent of Mated Females/Paired^a,b^ | 100.0** | 81.0** | 100.0 | 95.2 | 76.2* | 86.4 | 5.3** | 0.0**
Percent of Pregnant Females/Mated^a,b^ | 81.8* | 100.0 | 95.7 | 100.0 | 75.0 | 94.7 | 0.0 | –^c^
Percent of Littered Females/Mated^a,b^ | 81.8** | –^d^ | 87.0 | – | 56.3 | – | 0.0 | –
Precoital Interval^e,f^ | 6.4 ± 0.7* (20) | 4.1 ± 0.9 (16) | 5.3 ± 0.9 (20) | 4.0 ± 0.7 (20) | 4.1 ± 1.2 (13) | 3.9 ± 0.7 (16) | 1.0 ± 0.0 (1) | (0)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; ** p ≤ 0.01.

RPC = reproductive performance cohort; PC = prenatal cohort.

^a^ Statistical analysis performed using the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^b^ Animals removed from the study between mating and littering were excluded from calculations of % littered females.

^c^ Percent of pregnant females/mated was not calculated for the 3,750 ppm prenatal females because there were no mated females.

^d^ F_1_ prenatal females were sectioned prior to littering, so endpoints involving number of females littering were not calculated.

^e^ Statistical analysis performed using the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^f^ Precoital interval in days is calculated for sperm-positive females; data are displayed as mean ± standard error (n).

#### F_1_ Reproductive Performance Cohort Andrology

There were no BPAF-related effects on motile sperm or progressively motile sperm, but there was a significant increase of 23% above the control group in testis spermatid head concentration (per gram testis) in the 3,750 ppm group (Table 23). Males in the 1,125 and 3,750 ppm groups displayed significant exposure concentration-dependent decreases in cauda epididymal sperm counts (approximately 19% and 58% less than the control group, respectively), epididymis weights (approximately 11% and 40% less than the control group, respectively), and testis weights (approximately 8% and 28% less than the control group, respectively) (Table 23). These findings were associated with histopathological changes in both the testis and epididymis (Appendix E).

Table 23 Summary of Reproductive System Parameters of F_1_ Male Rats in the Reproductive Performance Cohort Exposed to Bisphenol AF in Feed

Parameter^a^ | 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
No. Examined on PND 152–154^b^ | 21 (21) | 23 (23) | 21 (21) | 20 (20)
Weights (g)^c,d^
Left cauda epididymis | 0.262 ± 0.004** | 0.249 ± 0.004 | 0.222 ± 0.006** | 0.130 ± 0.007**
Left epididymis | 0.673 ± 0.009** | 0.648 ± 0.010 | 0.602 ± 0.013** | 0.405 ± 0.020**
Left testis | 2.039 ± 0.026** | 1.965 ± 0.028 | 1.876 ± 0.047** | 1.469 ± 0.057**
Spermatid Measurements^e^
Spermatid heads (10^6^/g testis) | 120.9 ± 3.9** | 128.5 ± 3.5 | 128.0 ± 3.9 | 148.8 ± 6.3**
Spermatid heads (10^6^/testis) | 246.4 ± 8.5* | 252.6 ± 8.1 | 237.9 ± 7.2 | 216.4 ± 9.6
Epididymal Spermatozoal Measurements^e^
Sperm motility (%) | 65.0 ± 3.6 | 64.4 ± 2.9 | 57.5 ± 3.5 | 63.4 ± 3.8
Sperm progressive motility (%) | 53.0 ± 3.1 | 50.3 ± 2.1 | 45.7 ± 3.2 | 50.7 ± 3.3
Sperm (10^6^/g cauda epididymis) | 843.4 ± 27.3** | 835.2 ± 26.3 | 796.9 ± 38.3 | 704.1 ± 27.1**
Cauda epididymis sperm count (10^6^/cauda epididymis) | 221.5 ± 8.3** | 207.5 ± 6.5 | 179.9 ± 11.4** | 94.0 ± 8.1**

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

PND = postnatal day.

^a^ Data are presented as mean ± standard error.

^b^ No. Examined on PND 152–154 = the number of pups examined (number of litters). Spermatid head concentration for one animal in the 1,125 ppm group was excluded as an outlier.

^c^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^d^ If there was a lesion in the left organ, the contralateral tissue was taken.

^e^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

#### F_1_ Gestation Body Weights

As previously noted, F_1_ female rats exposed to BPAF displayed both lower preweaning and postweaning mean body weights. Consequently, the F_1_ female mean body weights of the 338 and 1,125 ppm groups in both the prenatal and reproductive performance cohorts at the time of cohabitation were lower relative to control females and were 4%–7% and 15%–17% lower at GD 0, respectively (no pregnancies occurred in the 3,750 ppm group for either the prenatal or reproductive performance cohorts) (Figure 25, Figure 26). Both cohorts exposed to 338 or 1,125 ppm displayed significantly decreased mean body weight gains throughout the gestational period (approximately 15%–16% and 40%–47%, respectively) relative to their respective control groups (Table 24) and were 9%–10% and 25%–29% lower, respectively, on GD 21. This difference in mean body weight gain during pregnancy for the 1,125 ppm group might be the result of a significant decrease in litter size of approximately five fewer fetuses/pups in this group than in the control group (Appendix E); a decrease in litter size was not observed in the 338 ppm group.

Figure 25

Gestation Growth Curves for F_1_ Female Rats in the Reproductive Performance Cohort Exposed to Bisphenol AF in Feed

Information for statistical significance in F_1_ female rat weights is provided in Table 24.

Figure 26

Gestation Growth Curves for F_1_ Female Rats in the Prenatal Cohort Exposed to Bisphenol AF in Feed

Information for statistical significance in F_1_ female rat weights is provided in Table 24.

Table 24 Summary of Gestation Mean Body Weights and Body Weight Gains for F_1_ Female Rats Exposed to Bisphenol AF in Feed^a,b^

Parameter | 0 ppm | | 338 ppm | | 1,125 ppm | | 3,750 ppm
Parameter | RPC | PC | RPC | PC | RPC | PC | RPC | PC
Gestation Day
0 | 249.0 ± 4.5** (16) | 246.7 ± 3.7** (16) | 239.2 ± 5.1 (19) | 229.4 ± 4.1** (20) | 210.7 ± 4.9** (9) | 203.9 ± 4.8** (15) | –^c^ | –
21 | 407.0 ± 7.5** (16) | 415.9 ± 4.9** (16) | 372.0 ± 7.6** (19) | 373.3 ± 6.6** (20) | 305.9 ± 13.3** (9) | 294.4 ± 9.2** (15) | – | –
Gestation Day Interval
0–21 | 158.0 ± 6.1** (16) | 169.2 ± 2.7** (16) | 132.8 ± 6.8* (19) | 143.9 ± 4.4** (20) | 95.3 ± 10.7** (9) | 90.4 ± 9.1** (15) | – | –
0–3 | 18.9 ± 1.5** (16) | 16.4 ± 1.4* (16) | 14.4 ± 1.0* (19) | 13.4 ± 0.7 (20) | 11.9 ± 1.6** (9) | 13.4 ± 1.0 (15) | – | –
3–6 | 11.6 ± 1.0** (16) | 12.2 ± 1.0** (16) | 9.2 ± 0.9* (19) | 8.9 ± 0.9* (20) | 6.3 ± 0.6** (9) | 7.1 ± 1.2** (15) | – | –
6–9 | 9.7 ± 0.7 (16) | 11.1 ± 1.0* (16) | 9.5 ± 1.1 (19) | 9.1 ± 0.9 (20) | 6.9 ± 1.4 (9) | 6.8 ± 1.1* (15) | – | –
9–12 | 11.5 ± 0.9* (16) | 13.5 ± 0.9** (16) | 9.4 ± 0.9 (19) | 12.2 ± 0.6 (20) | 6.9 ± 1.6* (9) | 6.9 ± 1.0** (15) | – | –
12–15 | 19.8 ± 1.0** (16) | 20.8 ± 0.9** (16) | 17.0 ± 1.4 (19) | 16.5 ± 1.0* (20) | 10.9 ± 2.0** (9) | 10.8 ± 1.9** (15) | – | –
15–18 | 40.4 ± 2.2* (16) | 45.9 ± 1.5** (16) | 35.0 ± 2.9 (19) | 41.0 ± 1.9 (20) | 24.4 ± 5.1** (9) | 19.4 ± 3.4** (15) | – | –
18–21 | 46.0 ± 2.7** (16) | 49.4 ± 1.8** (16) | 38.3 ± 3.3 (19) | 42.7 ± 1.5* (20) | 27.9 ± 2.8** (9) | 26.0 ± 3.1** (15) | – | –

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

RPC = reproductive performance cohort; PC = prenatal cohort.

^a^ Data are displayed as mean ± standard error (n), where n = number of animals. Body weight data are reported in grams.

^b^ Statistical analysis performed using the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ No females were confirmed pregnant for the 3,750 ppm group.

#### F_1_ Gestation Feed Consumption

Absolute (g/animal/day) feed consumption over the GD 0–21 interval was lower in the 338 ppm group (approximately 5% below the control group for both the prenatal and reproductive performance cohorts) and significantly decreased in the 1,125 ppm group (13% and 14% below the control group for the prenatal and reproductive performance cohorts, respectively). Relative feed consumption (g/kg/day) over the GD 0–21 interval was similar to the control group for the 338 ppm group in both cohorts. In the 1,125 ppm group, relative feed consumption was significantly increased and higher in the prenatal and reproductive performance cohorts, respectively, indicating that the lower feed consumption values were relative to the body weight of the animals during gestation (Table 25). BPAF intakes for F_1_ females in both cohorts during gestation, based on feed consumption and dietary concentrations for GD 0–21, were approximately 26 and 92 mg/kg/day at 338 and 1,125 ppm, respectively (Table 25), slightly higher than the exposure during the F_0_ gestation (24 and 81 mg/kg/day, respectively).

Table 25 Summary of Gestation Feed and Test Article Consumption for F_1_ Female Rats Exposed to Bisphenol AF in Feed^a,b^

GD Interval | 0 ppm | | 338 ppm | | 1,125 ppm | | 3,750 ppm
GD Interval | RPC | PC | RPC | PC | RPC | PC | RPC | PC
Feed Consumption (g/animal/day)^c,d^
0–21 | 23.5 ± 0.4** (16) | 22.7 ± 0.3** (16) | 22.3 ± 0.7 (19) | 21.6 ± 0.5 (20) | 20.1 ± 1.0** (9) | 19.7 ± 0.5** (15) | –^e^ | –
0–3 | 21.9 ± 0.6 (16) | 19.7 ± 0.3 (16) | 21.4 ± 1.0 (18) | 20.3 ± 0.9 (15) | 20.7 ± 2.0 (7) | 22.4 ± 1.4 (10) | – | –
3–6 | 21.7 ± 0.4** (15) | 20.8 ± 0.4** (16) | 20.4 ± 0.7 (19) | 18.4 ± 0.5** (20) | 17.2 ± 0.4** (8) | 16.4 ± 0.5** (14) | – | –
6–9 | 22.3 ± 0.4 (16) | 21.2 ± 0.3 (16) | 22.8 ± 1.3 (17) | 21.9 ± 1.1 (17) | 22.5 ± 1.7 (8) | 21.5 ± 1.8 (10) | – | –
9–12 | 21.3 ± 0.4** (16) | 20.8 ± 0.4** (16) | 20.1 ± 0.6 (18) | 19.0 ± 0.4** (19) | 16.0 ± 0.4** (9) | 16.0 ± 0.6** (15) | – | –
12–15 | 24.0 ± 0.6 (16) | 23.2 ± 0.5 (16) | 22.8 ± 0.8 (19) | 22.8 ± 1.1 (19) | 25.2 ± 2.8 (8) | 24.6 ± 1.2 (13) | – | –
15–18 | 25.2 ± 0.5** (16) | 25.8 ± 0.5** (16) | 23.6 ± 0.5* (18) | 23.3 ± 0.6** (20) | 19.0 ± 0.9** (9) | 18.7 ± 0.7** (15) | – | –
18–21 | 27.7 ± 0.6** (15) | 27.0 ± 0.6** (16) | 24.7 ± 0.9** (19) | 24.4 ± 0.8** (20) | 21.9 ± 0.9** (7) | 22.8 ± 1.0** (9) | – | –
Feed Consumption (g/kg/day)^c,d^
0–21 | 76.4 ± 1.2 (16) | 73.8 ± 0.8* (16) | 77.6 ± 1.7 (19) | 77.3 ± 1.7 (20) | 81.4 ± 3.3 (9) | 82.4 ± 2.9* (15) | – | –
0–3 | 84.7 ± 2.5 (16) | 77.4 ± 1.6** (16) | 87.1 ± 3.5 (18) | 86.1 ± 4.1 (15) | 94.9 ± 7.4 (7) | 106.1 ± 7.2** (10) | – | –
3–6 | 79.9 ± 1.9 (15) | 77.2 ± 1.5 (16) | 79.0 ± 2.1 (19) | 74.3 ± 1.5 (20) | 75.9 ± 1.5 (8) | 75.2 ± 2.6 (14) | – | –
6–9 | 78.8 ± 1.3 (16) | 75.8 ± 1.1 (16) | 85.4 ± 4.1 (17) | 84.9 ± 4.1 (17) | 96.7 ± 8.0 (8) | 94.9 ± 9.1 (10) | – | –
9–12 | 72.3 ± 1.2 (16) | 70.9 ± 1.1 (16) | 72.3 ± 1.4 (18) | 71.1 ± 1.2 (19) | 67.1 ± 1.7 (9) | 68.0 ± 2.1 (15) | – | –
12–15 | 77.2 ± 1.6 (16) | 74.9 ± 1.3** (16) | 78.6 ± 2.1 (19) | 81.7 ± 4.0 (19) | 101.0 ± 10.7* (8) | 102.5 ± 5.8** (13) | – | –
15–18 | 74.4 ± 1.0 (16) | 75.5 ± 1.3 (16) | 75.4 ± 1.2 (18) | 75.4 ± 1.4 (20) | 71.6 ± 2.6 (9) | 72.2 ± 1.9 (15) | – | –
18–21 | 72.6 ± 1.3 (15) | 69.0 ± 1.3 (16) | 70.1 ± 2.4 (19) | 69.4 ± 2.3 (20) | 76.2 ± 4.4 (7) | 76.6 ± 4.6 (9) | – | –
Chemical Intake (mg/kg/day)^f,g^
0–21 | 0.0 ± 0.0 (16) | 0.0 ± 0.0 (16) | 26.2 ± 0.6 (19) | 26.1 ± 0.6 (20) | 91.6 ± 3.8 (9) | 92.7 ± 3.3 (15) | – | –

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

GD = gestation day; RPC = reproductive performance cohort; PC = prenatal cohort.

^a^ Data are displayed as mean ± standard error (n), where n = number of animals. Consumption is not reported for the nonpregnant animals during gestation.

^b^ For each dam, calculation of consumption values for the GD 0–21 interval was performed using all valid data for the animal, even if data were unavailable for some of the subintervals.

^c^ Changes in n are the result of excluded feed consumption values due to excessive spillage. Additional animal feed consumption values removed as outliers include: GD 3–6 (one RPC female in the 1,125 ppm group) and GD 9–12 (one PC female in the 338 ppm group).

^d^ Statistical analysis performed using the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^e^ No females were confirmed pregnant for the 3,750 ppm group.

^f^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^g^ No statistical analysis performed on the chemical intake data.

### Prenatal Cohort Findings

F_1_ rats and F_2_ fetuses from the prenatal cohort were evaluated for maternal reproductive performance and fetal findings, respectively, as shown in Figure 27.

Figure 27

Design of the Modified One-Generation Study – Prenatal Cohort

GD = gestation day; LD = lactation day; PND = postnatal day.

#### Maternal Reproductive Performance and Uterine Data

In the prenatal cohort, females were between 123 and 137 days of age at the time of necropsy. Pregnant females exposed to 338 or 1,125 ppm BPAF displayed lower gravid uterine weights (13% and 56%, respectively, significant only at 1,125 ppm), and the number of uterine implantations significantly decreased in both exposed groups (there were no pregnant females in the 3,750 ppm group) (Table 26). A significant increase in pre- and postimplantation loss and fewer live fetuses (approximately seven fewer per litter) were observed in the 1,125 ppm group. These findings correlated with significant decreases in the mean number of corpora lutea (approximately four fewer per litter at 1,125 ppm) relative to the control group and are consistent with the significant decreases in live litter size and mean live fetal weights (significantly decreased by 25% compared to the control animals) (Table 26). Dams exposed to BPAF did not display any significant changes in fetal sex ratio.

Table 26 Summary of Uterine Content Data for F_1_ Females in the Prenatal Cohort Exposed to Bisphenol AF in Feed

| 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
Pregnancy Summary^a^
Paired Females | 21 | 21 | 22 | 19
Mated Females | 17** | 20 | 19 | 0**
Pregnant Females^b^ | 17 | 20 | 18 | 0
Pregnant Females Examined on GD 21 | 16 | 20 | 15 | 0
Preimplantation Loss^c,d^
Mean No. of Corpora Lutea/Female | 15.82 ± 0.44** (17) | 14.20 ± 0.47** (20) | 11.89 ± 0.52** (18) | –^e^
Implantations/Female | 15.00 ± 0.37** (16) | 13.85 ± 0.39* (20) | 8.73 ± 0.69** (15) | –
Preimplantation Loss (%) | 5.40 ± 2.06** (16) | 3.77 ± 1.47 (20) | 24.44 ± 4.97** (15) | –
Intrauterine Deaths^d^
Postimplantation Loss (%)^c^ | 2.26 ± 1.52** (16) | 4.51 ± 2.26 (20) | 25.87 ± 8.78* (15) | –
Total Resorptions per Litter^c^ | 0.38 ± 0.26* (16) | 0.60 ± 0.31 (20) | 1.87 ± 0.62* (15) | –
Early Resorptions per Litter^c^ | 0.38 ± 0.26* (16) | 0.60 ± 0.31 (20) | 1.87 ± 0.62* (15) | –
Late Resorptions per Litter^c^ | 0.00 ± 0.00 (16) | 0.00 ± 0.00 (20) | 0.00 ± 0.00 (15) | –
Dead Fetuses per Litter^c^ | 0.00 ± 0.00 (16) | 0.00 ± 0.00 (20) | 0.07 ± 0.07 (15) | –
No. of Early Resorptions | 6 | 12 | 28 | –
No. of Late Resorptions | 0 | 0 | 0 | –
No. of Whole Litter Resorptions^a^ | 0 | 0 | 1 | –
No. of Dead Fetuses | 0 | 0 | 1 | –
Live Fetuses^d^
No. of Live Fetuses | 234 | 265 | 102 | –
Live Fetuses per Litter^c^ | 14.63 ± 0.34 (16) | 13.25 ± 0.52 (20) | 7.29 ± 1.06** (14) | –
Live Male Fetuses per Litter^c^ | 7.81 ± 0.44 (16) | 7.35 ± 0.47 (20) | 3.92 ± 0.73** (13) | –
Live Female Fetuses per Litter^c^ | 6.81 ± 0.21 (16) | 5.90 ± 0.34 (20) | 3.64 ± 0.61** (14) | –
Live Male Fetuses per Litter (%)^c^ | 52.95 ± 1.94 (16) | 54.93 ± 2.62 (20) | 44.88 ± 6.42 (14) | –
Fetal Weight (g)^c,f,g^
Fetal Weight per Litter | 5.09 ± 0.07** (16) | 4.98 ± 0.06 (19) | 3.81 ± 0.35** (14) | –
Male Fetal Weight per Litter | 5.20 ± 0.08** (16) | 5.09 ± 0.07 (19) | 3.96 ± 0.38** (13) | –
Female Fetal Weight per Litter | 4.96 ± 0.06** (16) | 4.83 ± 0.06 (19) | 3.80 ± 0.34** (14) | –
Gravid Uterine Weight (g)^c,f^
Gravid Uterine Weight | 104.01 ± 2.97** (16) | 90.93 ± 3.70 (20) | 45.73 ± 8.01** (15) | –
Terminal Body Weight | 415.7 ± 4.9** (16) | 373.8 ± 6.5** (20) | 295.3 ± 9.1** (15) | –
Adjusted Body Weight^h^ | 311.74 ± 3.31** (16) | 282.82 ± 4.41** (20) | 249.53 ± 5.28** (15) | –

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

GD = gestation day.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^b^ Includes animals that had any evidence of pregnancy but were removed from the study before GD 21.

^c^ Data are reported per litter as mean ± standard error (n) and do not include nonmated, nonpregnant, or unexamined animals or those that did not survive to the end of the study. One litter in the 338 ppm group was excluded from fetal weight analysis as an outlier, one litter in the 1,125 ppm group had no live fetuses, and one litter in the 1,125 ppm group had no live male fetuses.

^d^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^e^ No females were confirmed pregnant for the 3,750 ppm group.

^f^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^g^ Because a positive trend in fetal weight with litter size was seen in all exposure groups, only unadjusted fetal weights are presented here.

^h^ Body weight adjusted for gravid uterus weight.

#### Fetal Findings

##### Placental Morphology

There was no effect of BPAF exposure on the incidence of gross placental abnormalities (Appendix E). Retained placentae was noted for a single litter of an F_0_ female in the 3,750 ppm group.

##### External

There was no effect of BPAF exposure on the incidence of fetal external abnormalities (Appendix E), which were limited to a single fetus in the 338 ppm group that displayed a clubbed hind limb.

##### Visceral

There was no effect of BPAF exposure on the incidence of fetal visceral abnormalities. Distended ureter (a variation found in 7%, 11%, and 12% of fetuses and 44%, 45%, and 43% of litters for the control, 338, and 1,125 ppm groups, respectively) and hydroureter (a malformation found in 0.4%, 1%, and 2% of fetuses and 6%, 10%, and 7% of litters for the control, 338, and 1,125 ppm groups, respectively) were noted in several animals. There is a relatively high background incidence of abnormalities associated with the kidney and ureter in this strain of rat, however, and these values were not outside of NTP historical control data (distended ureter—4.83% to 15.36% for fetuses and 43.75% to 68.18% for litters; hydroureter—0.17% to 2.83% for fetuses and 2.27% to 21.05% for litters) (Appendix E).

Other visceral findings (i.e., dilated renal pelvis, agenesis of the innominate artery, and hydronephrosis) were limited to one or two occurrences or were found in the control group and, therefore, were not considered exposure related.

##### Head

Fetal head abnormalities noted in the 1,125 ppm group were attributed to BPAF exposure. Four pups from four litters had dilated lateral ventricles (variation), and one pup also presented with a misshapen lateral ventricle (variation) in the brain (Table 27). NTP has not recorded either finding in its previous studies and, therefore, these abnormalities are outside of NTP’s historical control range. No other findings were noted.

Table 27 Summary of Head Findings in Fetuses Exposed to Bisphenol AF in Feed

| 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
No. Litters Examined | 16 | 19 | 13 | –^a^
No. Fetuses Examined | 117 | 127 | 48 | –
Head^b,c^
Dilated lateral ventricle, bilateral – [V]^d^
Fetuses | 0 (0.00) | 0 (0.00) | 4 (8.33) | –
Litters | 0 (0.00) | 0 (0.00) | 4 (30.77) | –
Misshapen lateral ventricle, left – [V]^d^
Fetuses | 0 (0.00) | 0 (0.00) | 1 (2.08) | –
Litters | 0 (0.00) | 0 (0.00) | 1 (7.69) | –

[V] = variation.

^a^ No females were confirmed pregnant for the 3,750 ppm group.

^b^ Upper row denotes number of affected fetuses (%) and lower row the number of affected litters (%).

^c^ Statistical analysis for fetal data including litter effects was performed using a Rao-Scott modification to the Cochran-Armitage test where the litter was the random effect for both trend and pairwise analyses.

^d^ Historical control incidence for all routes: fetuses – 0/691 (0.00%); litters – 0/97 (0.00%).

##### Skeletal

There was a slight increase in the incidence of rudimentary lumbar I ribs in fetuses in the 338 and 1,125 ppm groups and in the incidence of full lumbar I ribs in the 338 ppm fetuses compared to the control group (Table 28). Skeletal abnormalities in exposed groups were limited to the lumbar rib (rudimentary and full) findings, incomplete ossification of the sternebrae, and bipartite and dumbbell ossification of the thoracic centrum. With the exception of the lumbar rib observations, findings were observed only in a single fetus. Rudimentary ribs (variation) were defined as ribs that were shorter than half the length of the 13th rib. Ribs that were longer than half the length of the 13th rib were considered full (malformation). The incidences of rudimentary lumbar ribs and full lumbar ribs (Table 28) were slightly outside of NTP historical control data (Table 28). While these findings might have been related to BPAF exposure, the lack of an exposure-related response for rudimentary ribs in litters and the absence of full lumbar ribs in the 1,125 ppm group impede the evaluation. These issues could be due to the low number of fetuses in the 1,125 ppm group (102 fetuses compared to 234 and 265 fetuses in the control group and 338 ppm group, respectively).

Table 28 Summary of Select Skeletal Findings in Fetuses Exposed to Bisphenol AF in Feed

| 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
No. Litters Examined | 16 | 20 | 14 | –^a^
No. Fetuses Examined | 234 | 265 | 102 | –
Ribs^b,c^
Lumbar I, rudimentary, total – [V]^d^
Fetuses | 11 (4.70) | 19 (7.17) | 14 (13.73) | –
Litters | 6 (37.50) | 10 (50.00) | 4 (28.57) | –
Lumbar I, full, total – [M]^e^
Fetuses | 0 (0.00) | 4 (1.51) | 0 (0.00) | –
Litters | 0 (0.00) | 3 (15.00) | 0 (0.00) | –

[V] = variation; [M] = malformation.

^a^ No females were confirmed pregnant for the 3,750 ppm group.

^b^ Upper row denotes number of affected fetuses (%) and lower row the number of affected litters (%).

^c^ Statistical analysis for fetal data including litter effects was performed using a Rao-Scott modification to the Cochran-Armitage test where the litter was the random effect for both trend and pairwise analyses.

^d^ Historical control incidence: fetuses – 114/1,385 (8.23%), range 3.35%–13.69%; litters – 53/97 (54.64%), range 26.32%–65.91%.

^e^ Historical control incidence: fetuses – 4/1,385 (0.29%), range 0.00%–0.67%; litters – 4/97 (4.12%), range 0.00%–9.09%.

### Reproductive Performance Cohort Findings

F_1_ and F_2_ rats from the reproductive performance cohort were evaluated for maternal reproductive performance and offspring effects, respectively, as shown in Figure 28. Littering, mean body weights, and feed consumption results from the F_1_ rats as well as viability, clinical observations, mean body weights, and gross pathology results from the F_2_ rats are presented below.

Figure 28

Design of the Modified One-Generation Study – Reproductive Performance Cohort

GD = gestation day; LD = lactation day; PND = postnatal day.

#### Reproductive Performance and Littering

Reproductive performance and littering parameters for the reproductive performance cohort are presented in Table 29. Gestation length was similar for dams in the 338 and 1,125 ppm groups and the control group (no 3,750 ppm F_2_ generation was produced for either the prenatal or reproductive performance cohorts). Significant exposure-related decreases in mean live litter size on LD 0 (by approximately five pups) were observed in the 1,125 ppm group (Appendix E). This decrease continued after litter standardization on LD 4 (with a difference of approximately two pups) through LD 28 (Appendix E). These findings were consistent with the significant decreases in the mean number of live fetuses per litter (decrease of approximately seven pups) that were observed in the prenatal cohort (Table 26).

Table 29 Summary of Reproductive Parameters of F_1_ Female Rats in the Reproductive Performance Cohort Exposed to Bisphenol AF in Feed

| 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
No. Females Paired | 22 | 23 | 21 | 19
No. Females Mated | 22 | 23 | 16 | 1
No. Pregnant Females | 18 | 22 | 12 | 0
No. Females Littering | 18 | 20 | 9 | 0
Percent of Mated Females/Paired^a,b^ | 100.0** | 100.0 | 76.2* | 5.3**
Percent of Littered Females/Paired^a,b^ | 81.8** | 87.0 | 42.9* | 0.0**
Percent of Pregnant Females/Mated^a,b^ | 81.8* | 95.7 | 75.0 | 0.0
Percent of Littered Females/Mated^a,b^ | 81.8** | 87.0 | 56.3 | 0.0
Precoital Interval (days)^c,d,e^ | 6.4 ± 0.7* (20) | 5.3 ± 0.9 (20) | 4.1 ± 1.2 (13) | 1.0 ± 0.0 (1)
Gestation Length (days)^c,d,f^ | 22.6 ± 0.1 (16) | 22.7 ± 0.1 (17) | 23.3 ± 0.6 (7) | –^g^

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Statistical analysis performed using the Cochran-Armitage (trend) and Fisher’s exact (pairwise) test comparisons.

^b^ Animals removed from the study between mating and littering were excluded from calculations of % littered females.

^c^ Statistical analysis performed using the Jonckheere (trend) and the Shirley or Dunn (pairwise) tests.

^d^ Data are displayed as mean ± standard error (n).

^e^ Precoital interval calculated for sperm-positive females.

^f^ Gestation length calculated for sperm-positive females that delivered a litter.

^g^ No females were confirmed pregnant for the 3,750 ppm group.

#### Lactation Body Weights and Feed Consumption

Consistent with their premating and gestation weights, F_1_ female mean body weights during lactation were significantly decreased in both the 338 and 1,125 ppm groups relative to the control group (Table 30; Figure 29). For the 338 ppm group, on LDs 1 and 28, female mean body weights were significantly decreased by 10% and 8%, respectively, compared to the control group; for the 1,125 ppm group, female mean body weights were significantly decreased by 21% and 13% on LDs 1 and 28, respectively. Mean body weight gain over the LD 4–28 interval in the 1,125 ppm group was significantly increased relative to the control group. In general, relative feed consumption values (g/kg/day) during lactation in the groups exposed to BPAF were similar to the control group (Table 30). BPAF intakes during lactation in the 338 and 1,125 ppm groups, based on feed consumption and dietary concentrations for LD 1–13, were approximately 53 and 162 mg/kg/day, respectively (Table 30).

Table 30 Summary of Mean Body Weights, Body Weight Gains, and Feed and Test Article Consumption of F_1_ Female Rats in the Reproductive Performance Cohort Exposed to Bisphenol AF in Feed during Lactation

Lactation Day^a^ | 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
Body Weight (g)^b^
1 | 307.6 ± 5.0** (18) | 276.6 ± 5.6** (19) | 243.0 ± 7.7** (9) | –^c^
13 | 326.7 ± 4.6** (18) | 299.6 ± 4.8** (19) | 269.8 ± 5.6** (9) | –
28 | 305.4 ± 3.7** (18) | 281.1 ± 3.8** (19) | 264.6 ± 6.9** (9) | –
Body Weight Gain (g)^b^
4–28 | −8.5 ± 2.8** (18) | −7.7 ± 2.3 (19) | 16.1 ± 4.8** (9) | –
Feed Consumption^b^
1–13 (g/animal/day) | 44.9 ± 1.6 (18) | 45.8 ± 0.9 (19) | 37.0 ± 4.0 (9) | –
1–13 (g/kg/day) | 142.2 ± 5.4 (18) | 158.1 ± 3.4 (19) | 144.3 ± 16.0 (9) | –
Chemical Intake (mg/kg/day)^d,e^
1–13 | 0.0 ± 0.0 (18) | 53.4 ± 1.2 (19) | 162.4 ± 18.0 (9) | –

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

^a^ Data are displayed as mean ± standard error (n), where n = number of animals. Feed consumption values were excluded when excessive spillage was recorded. Changes in n are the result of removing litters with no surviving pups by lactation day 26 (one dam in the 338 ppm group).

^b^ Statistical analysis performed using the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ No females were confirmed pregnant for the 3,750 ppm group.

^d^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^e^ No statistical analysis performed on the chemical intake data.

Figure 29

Lactation Growth Curves for F_1_ Female Rats in the Reproductive Performance Cohort Exposed to Bisphenol AF in Feed

Information for statistical significance in maternal weights is provided in Table 30.

#### F_2_ Viability and Clinical Observations

There was no effect of BPAF exposure on pup survival (Table 31). There were no clinical observations in the F_2_ pups attributed to BPAF exposure. Clinical observations noted in individual pups in all exposure groups, including the control group, were typically indicative of an individual pup not thriving (e.g., cold to touch, no milk in stomach) (Appendix E).

Table 31 Summary of F_2_ Litter Size and Pup Survival Following Perinatal Exposure to Bisphenol AF

Postnatal Day | 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
No. of Live Pups (Litters)^a^
0 | 201 (18) | 211 (20) | 58 (9) | –^b^
Total Litter Size^c,d^
0 | 11.7 ± 1.1 (18) | 12.0 ± 0.7 (20) | 7.4 ± 1.6 (9) | –
Live Litter Size^c,d^
0 | 11.2 ± 1.0* (18) | 10.6 ± 0.8 (20) | 6.4 ± 1.4* (9) | –
1 | 10.9 ± 1.0* (18) | 11.1 ± 0.6 (19)^e^ | 6.4 ± 1.4* (9) | –
4 (prestandardization) | 10.9 ± 1.0* (18) | 11.1 ± 0.6 (19) | 6.4 ± 1.4* (9) | –
4 (poststandardization) | 7.3 ± 0.4 (18) | 7.9 ± 0.1 (19) | 5.7 ± 1.1 (9) | –
7 | 7.3 ± 0.4 (18) | 7.8 ± 0.1 (19) | 5.7 ± 1.1 (9) | –
13 | 7.2 ± 0.4 (18) | 7.7 ± 0.1 (19) | 5.2 ± 1.1 (9) | –
21 | 7.2 ± 0.4 (18) | 7.7 ± 0.1 (19) | 5.2 ± 1.1 (9) | –
28 | 7.2 ± 0.4 (18) | 7.7 ± 0.1 (19) | 5.2 ± 1.1 (9) | –
No. of Dead Pups (Litters)^a^
0 | 10 (7) | 28 (15) | 9 (4) | –
1–4 | 4 (3) | 1 (1) | 0 (0) | –
5–28 | 1 (1) | 3 (2) | 4 (1) | –
Dead/Litter^c,d^
0 | 0.56 ± 0.20 (18) | 1.40 ± 0.29* (20) | 1.00 ± 0.47 (9) | –
1–4 | 0.22 ± 0.13 (18) | 0.05 ± 0.05 (20) | 0.00 ± 0.00 (9) | –
5–28 | 0.06 ± 0.06 (18) | 0.16 ± 0.12 (19)^e^ | 0.44 ± 0.44 (9) | –
Survival Ratio^c,d^
0 | 0.96 ± 0.02 (18) | 0.87 ± 0.04* (20) | 0.87 ± 0.06 (9) | –
1–4 | 0.97 ± 0.02 (18) | 0.95 ± 0.05 (20) | 1.00 ± 0.00 (9) | –
5–28 | 0.99 ± 0.01 (18) | 0.98 ± 0.01 (19)^e^ | 0.94 ± 0.06 (9) | –

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

^a^ n = the number of pups examined (number of F_1_ litters). For no. of dead pups, n is the number of litters contributing dead pups.

^b^ No females were confirmed pregnant for the 3,750 ppm group.

^c^ Data are displayed as the mean of litter values ± standard error of litter values (n = number of litters contributing).

^d^ Statistical analysis performed using the Jonckheere (trend) and Shirley or Dunn (pairwise) tests. All calculations were based on the last litter observation of the day.

^e^ Changes in n are the result of removing litters with no surviving pups by postnatal day 1 (one F_1_ litter in the 338 ppm group).

#### F_2_ Body Weights and Feed Consumption

##### Male Pups

Male pups exposed to 1,125 ppm BPAF had significantly decreased preweaning mean body weights (litter means) over time compared to the control group (Table 32; Figure 30; Appendix E). On PND 28, male pup mean body weights per litter in the 1,125 ppm group were significantly decreased by approximately 12% relative to the control group. Significant decreases in pup mean body weights occurred at select time points throughout the postnatal period (PNDs 4, 16, 21, 25, and 28) with most occurring toward the end of the weaning period (Appendix E). The magnitude of effect is consistent with what was observed in the F_1_ generation (12% decrease in preweaning mean body weight on PND 28). Pup mean body weights of the 338 ppm group were within 5%–6% below the control values at all time points between PND 1 and PND 28 (Appendix E).

Table 32 Summary of F_2_ Male and Female Pup Mean Body Weights and Body Weight Gains Following Perinatal Exposure to Bisphenol AF^a,b^

Postnatal Day | 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
Male
Body Weight
1 | 7.32 ± 0.15 79 (17)^c^ | 7.00 ± 0.16 108 (19) | 6.80 ± 0.25 32 (7) | –^d^
4 | 11.13 ± 0.24** 79 (17) | 10.47 ± 0.29 108 (19) | 9.41 ± 0.67* 32 (7) | –
21 | 53.41 ± 1.42* 52 (17) | 52.93 ± 0.98 70 (19) | 47.03 ± 2.54* 27 (7) | –
28 | 88.86 ± 2.01** 52 (17) | 86.96 ± 1.49 70 (19) | 77.82 ± 4.07* 27 (7) | –
Body Weight Gain^e^
4–28 | 77.63 ± 1.64** 52 (17) | 76.12 ± 1.20 70 (19) | 67.07 ± 3.63** 27 (7) | –
Female
Body Weight
1 | 7.15 ± 0.15** 118 (18) | 6.79 ± 0.14 102 (19) | 6.28 ± 0.32* 26 (7) | –
4 | 10.77 ± 0.24** 118 (18) | 10.06 ± 0.24 102 (19) | 8.54 ± 0.67** 26 (7) | –
21 | 51.36 ± 1.11** 78 (18) | 50.35 ± 0.79 77 (19) | 44.84 ± 2.28** 20 (7) | –
28 | 81.62 ± 1.31** 78 (18) | 78.23 ± 1.15 77 (19) | 71.69 ± 2.52** 20 (7) | –
Body Weight Gain^e^
4–28 | 70.82 ± 1.09** 78 (18) | 67.83 ± 0.94 77 (19) | 62.17 ± 1.98** 20 (7) | –

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are displayed as mean ± standard error of the litter means. Body weights are presented in grams.

^b^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons. Pup weights were adjusted for covariate litter size: total live on postnatal day 1 for day 1 to the day of standardization and number of live pups poststandardization for later days.

^c^ n = number of pups examined (number of F_1_ litters). One litter in the vehicle control group had no male pups.

^d^ No females were confirmed pregnant for the 3,750 ppm group.

^e^ Body weight gain (data are presented in grams).

Figure 30

Lactation Growth Curves for F_2_ Male Pups Following Perinatal Exposure to Bisphenol AF

Information for statistical significance in F_2_ male rat weights is provided in Table 32.

Postweaning F_2_ male mean body weights were lower compared to the control group from PND 28 through PND 91 in the 1,125 ppm group (Table 33; Figure 31). The lower body weights were associated with a significant decrease in absolute, but not relative, feed consumption, suggesting that changes in absolute feed consumption may be related to the size of the animals. BPAF intakes by F_2_ males, based on feed consumption and dietary concentrations for PND 28–91, were 28 and 94 mg/kg/day at 338 and 1,125 ppm, respectively.

Table 33 Summary of Postweaning Mean Body Weights, Body Weight Gains, and Feed and Test Article Consumption of All F_2_ Male and Female Rats Exposed to Bisphenol AF in Feed

Postnatal Day^a^ | 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
Male
Body Weight (g)^b,c^
28 | 87.5 ± 2.5* 52 (17) | 85.8 ± 1.6 70 (19) | 78.6 ± 4.1 27 (7) | –^d^
91 | 387.9 ± 6.7* 52 (17) | 372.4 ± 5.3 70 (19) | 360.2 ± 9.8 27 (7) | –
Body Weight Gain (g)^b,c^
28–91 | 300.4 ± 5.8 52 (17) | 286.6 ± 4.5 70 (19) | 281.6 ± 7.3 27 (7) | –
Postweaning Feed Consumption^e,f^
28–91 (g/animal/day) | 22.0 ± 0.2** (24) | 21.5 ± 0.2 (34) | 20.7 ± 0.4** (13) | –
28–91 (g/kg/day) | 83.9 ± 1.2 (24) | 83.1 ± 0.7 (34) | 83.8 ± 1.3 (13) | –
Chemical Intake (mg/kg/day)^f,g,h^
28–91 | 0.0 ± 0.0 (24) | 28.1 ± 0.2 (34) | 94.2 ± 1.4 (13) | –
Female
Body Weight (g)
28 | 81.1 ± 1.7** 78 (18) | 76.8 ± 1.2 77 (19) | 73.9 ± 1.9* 20 (7) | –
91 | 240.3 ± 4.2** 78 (18) | 217.6 ± 4.0** 77 (19) | 203.9 ± 5.9** 20 (7) | –
Body Weight Gain (g)
28–91 | 159.2 ± 3.6** 78 (18) | 140.8 ± 3.9** 77 (19) | 130.0 ± 5.9** 20 (7) | –
Postweaning Feed Consumption
28–91 (g/animal/day) | 16.0 ± 0.2* (37) | 15.4 ± 0.3 (37) | 14.8 ± 0.6 (10) | –
28–91 (g/kg/day) | 88.7 ± 0.7** (37) | 94.1 ± 1.4** (37) | 96.4 ± 2.9* (10) | –
Chemical Intake (mg/kg/day)
28–91 | 0.0 ± 0.0 (37) | 31.8 ± 0.5 (37) | 108.4 ± 3.2 (10) | –

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are displayed as mean ± standard error (n). Feed consumption values were excluded when excessive spillage was recorded.

^b^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^c^ n = number of pups examined (number of F_1_ litters). One litter in the vehicle control group had no male pups.

^d^ No females were confirmed pregnant for the 3,750 ppm group.

^e^ Statistical analysis performed using the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^f^ n = number of cages.

^g^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^h^ No statistical analysis performed on the chemical intake data.

Figure 31

Postweaning Growth Curves for All F_2_ Male Rats Exposed to Bisphenol AF in Feed

Information for statistical significance in F_2_ male rat weights is provided in Table 33.

##### Female Pups

Female pups exposed to 1,125 ppm BPAF also displayed significantly decreased preweaning mean body weights (litter means) relative to the control group (Table 32; Figure 32; Appendix E). On PND 28, female pup mean body weights per litter in the 1,125 ppm group were significantly decreased by approximately 12%. This effect is consistent with what was observed in the F_1_ generation, although the difference from the control group was greater for the F_2_ generation early in the postnatal period. Pup mean body weights of the 338 ppm group were no more than 7% below the control values for all time points between PND 1 and PND 28 (Appendix E).

Figure 32

Lactation Growth Curves for F_2_ Female Pups Following Perinatal Exposure to Bisphenol AF

Information for statistical significance in F_2_ female rat weights is provided in Table 32.

Significant decreases in postweaning F_2_ female mean body weights continued through PND 91 in the 1,125 ppm group (Table 33; Figure 33). The decreased body weights were associated with lower absolute, but significantly increased relative, feed consumption, suggesting that changes in absolute feed consumption may be related to the size of the animals. BPAF intakes by F_2_ females, based on feed consumption and dietary concentrations for PND 28–91, were 32 and 108 mg/kg/day at 338 and 1,125 ppm, respectively.

Figure 33

Postweaning Growth Curves for All F_2_ Female Rats Exposed to Bisphenol AF in Feed

Information for statistical significance in F_2_ female rat weights is provided in Table 33.

### F_1_ Necropsies: Prenatal, Reproductive Performance, and Subchronic Cohorts

#### Male Necropsies

The F_1_ males in the reproductive performance cohort were euthanized at 152–154 days of age, following completion of littering of the F_2_ generation. F_1_ males in the prenatal and subchronic cohorts were euthanized following completion of pairing at 119–121 and 115–119 days of age, respectively. There were BPAF-related gross findings, including two F_1_ males with malformations of the penis in the 3,750 ppm group: one male with the os penis visible at the glans and a second male with incomplete BPS (Table 34, Table 35). Both males also had a reduced size of the dorsolateral prostate, ventral prostate, seminal vesicles, testes, and epididymides. Terminal body (necropsy) weights of male rats exposed to 1,125 and 3,750 ppm BPAF for the three cohorts were significantly decreased by 13%–14% and 34%–40%, respectively, relative to the control males (Table 36, Table 37).

Table 34 Summary of Gross Necropsy Findings in Adult F_1_ Male Rats in the Subchronic Cohort Exposed to Bisphenol AF in Feed^a^

| 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
No. of Animals Examined^b^ | 10 (10) | 10 (10) | 10 (10) | 10 (10)
Prostate Gland
Reduced^c^ | 0** | 0 | 0 | 10 (10)**
Seminal Vesicles
Reduced
Bilateral | 0** | 0 | 0 | 10 (10)**
Phallus
Deformity | 0 | 0 | 0 | 1 (1)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

^a^ Statistical analysis performed using the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^b^ Number of animals (number of litters) examined for gross lesions.

^c^ Number of animals (number of litters) with lesion.

Table 35 Summary of Gross Necropsy Findings in Adult F_1_ Male Rats in the Prenatal and Reproductive Performance Cohorts Exposed to Bisphenol AF in Feed^a,b^

| 0 ppm | | 338 ppm | | 1,125 ppm | | 3,750 ppm
| RPC | PC | RPC | PC | RPC | PC | RPC | PC
No. of Animals Examined^c^ | 22 (22) | 22 (22) | 24 (24) | 21 (21) | 21 (21) | 22 (22) | 20 (20) | 20 (20)
Cowper’s Gland
Missing
Left^d^ | 0 | 0 | 0 | 0 | 0 | 1 (1) | 0 | 0
Bilateral | 0* | 0* | 0 | 0 | 0 | 0 | 2 (2) | 2 (2)
Total | 0* | 0 | 0 | 0 | 0 | 1 (1) | 2 (2) | 2 (2)
Reduced
Left | 0 | 0 | 1 (1) | 0 | 0 | 0 | 0 | 0
Bilateral | 0** | 0** | 1 (1) | 0 | 0 | 0 | 14 (14)** | 14 (14)**
Total | 0** | 0** | 2 (2) | 0 | 0 | 0 | 14 (14)** | 14 (14)**
Levator Ani/bulbocavernosus Muscle Complex
Reduced | 0** | 0** | 0 | 0 | 0 | 0 | 16 (16)** | 18 (18)**
Dorsolateral Prostate Gland^e^
Reduced | 0** | – | 0 | – | 0 | – | 18 (18)** | –
Ventral Prostate Gland
Reduced | 0** | – | 0 | – | 0 | – | 18 (18)** | –
Prostate Gland
Reduced | – | 0** | – | 0 | – | 0 | – | 20 (20)**
Seminal Vesicles
Reduced
Left | 0 | 0 | 0 | 0 | 0 | 1 (1) | 0 | 0
Right | 0 | 0 | 0 | 1 (1) | 0 | 0 | 0 | 0
Bilateral | 0** | 0** | 0 | 0 | 0 | 0 | 18 (18)** | 20 (20)**
Total | 0** | 0** | 0 | 1 (1) | 0 | 1 (1) | 18 (18)** | 20 (20)**
Phallus
Misshapen | 0 | 0 | 0 | 0 | 0 | 0 | 1 (1) | 0

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; ** p ≤ 0.01.

RPC = reproductive performance cohort; PC = prenatal cohort.

^a^ Data for the RPC and PC are also presented separately by cohort in Appendix E.

^b^ Statistical analysis performed using the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^c^ Number of animals (number of litters) examined for gross lesions.

^d^ Number of animals (number of litters) with lesion.

^e^ RPC necropsy findings for the prostate gland are distinguished between dorsalateral and ventral prostate gland. PC necropsy findings are presented for the prostate gland overall, without distinction.

Table 36 Summary of Organ Weights of Adult F_1_ Male Rats in the Subchronic Cohort Exposed to Bisphenol AF in Feed^a,b^

| 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
No. of Litters Examined | 10 | 10 | 10 | 10
Necropsy Body Wt. (g) | 399.6 ± 7.1** | 409.6 ± 12.6 | 347.7 ± 8.6** | 263.6 ± 6.8**
Adrenal Glands
Absolute (g) | 0.0633 ± 0.0044 | 0.0537 ± 0.0050 | 0.0531 ± 0.0041 | 0.0605 ± 0.0033
Relative (mg/g)^c^ | 0.16 ± 0.01** | 0.13 ± 0.01 | 0.15 ± 0.01 | 0.23 ± 0.01**
Thyroid Gland
Absolute (g) | 0.0171 ± 0.0008 | 0.0199 ± 0.0014 | 0.0175 ± 0.0015 | 0.0162 ± 0.0009
Relative (mg/g) | 0.04 ± 0.00** | 0.05 ± 0.00 | 0.05 ± 0.00 | 0.06 ± 0.00**
Lung
Absolute (g) | 2.13 ± 0.06** | 2.25 ± 0.10 | 1.89 ± 0.09 | 1.69 ± 0.08**
Relative (mg/g) | 5.33 ± 0.15* | 5.50 ± 0.20 | 5.44 ± 0.18 | 6.44 ± 0.30**
Liver
Absolute (g) | 16.03 ± 0.26** | 16.42 ± 0.87 | 13.59 ± 0.49** | 9.90 ± 0.33**
Relative (mg/g) | 40.15 ± 0.41** | 39.90 ± 1.18 | 39.01 ± 0.55 | 37.53 ± 0.71*
Right Kidney
Absolute (g) | 1.43 ± 0.02** | 1.47 ± 0.05 | 1.22 ± 0.04** | 0.91 ± 0.03**
Relative (mg/g) | 3.60 ± 0.04 | 3.58 ± 0.07 | 3.52 ± 0.06 | 3.45 ± 0.07
Left Kidney
Absolute (g) | 1.43 ± 0.02** | 1.46 ± 0.04 | 1.19 ± 0.04** | 0.88 ± 0.03**
Relative (mg/g) | 3.59 ± 0.05** | 3.56 ± 0.05 | 3.42 ± 0.07 | 3.33 ± 0.06**
Heart
Absolute (g) | 1.47 ± 0.03** | 1.47 ± 0.05 | 1.29 ± 0.04** | 1.04 ± 0.03**
Relative (mg/g) | 3.68 ± 0.11* | 3.59 ± 0.08 | 3.70 ± 0.05 | 3.93 ± 0.06
Thymus
Absolute (g) | 0.400 ± 0.032**^d^ | 0.400 ± 0.021 | 0.304 ± 0.027* | 0.262 ± 0.025**
Relative (mg/g) | 0.99 ± 0.07^d^ | 0.97 ± 0.04 | 0.87 ± 0.07 | 1.00 ± 0.10
Dorsolateral Prostate Gland
Absolute (g) | 0.450 ± 0.021** | 0.510 ± 0.054^d^ | 0.389 ± 0.017 | 0.200 ± 0.019**^d^
Relative (mg/g) | 1.13 ± 0.06** | 1.23 ± 0.12^d^ | 1.13 ± 0.07 | 0.75 ± 0.07**^d^
Ventral Prostate Gland
Absolute (g) | 0.610 ± 0.032** | 0.578 ± 0.036 | 0.451 ± 0.021** | 0.188 ± 0.023**^d^
Relative (mg/g) | 1.53 ± 0.08** | 1.41 ± 0.07 | 1.30 ± 0.06* | 0.70 ± 0.09**^d^
Seminal Vesicles with Coagulating Gland
Absolute (g) | 1.321 ± 0.034** | 1.409 ± 0.083 | 1.154 ± 0.070 | 0.396 ± 0.067**^d^
Relative (mg/g) | 3.32 ± 0.12** | 3.43 ± 0.15 | 3.32 ± 0.19 | 1.47 ± 0.25**^d^
Right Testis
Absolute (g) | 1.961 ± 0.046** | 1.971 ± 0.031 | 1.816 ± 0.040 | 1.402 ± 0.076**
Relative (mg/g) | 4.92 ± 0.14* | 4.85 ± 0.14 | 5.23 ± 0.11 | 5.30 ± 0.24
Left Testis
Absolute (g) | 1.920 ± 0.046** | 1.944 ± 0.036 | 1.800 ± 0.037 | 1.415 ± 0.073**
Relative (mg/g) | 4.82 ± 0.13** | 4.77 ± 0.10 | 5.19 ± 0.08 | 5.35 ± 0.23*
Right Epididymis
Absolute (g) | 0.653 ± 0.009** | 0.643 ± 0.022 | 0.607 ± 0.020 | 0.424 ± 0.033**
Relative (mg/g) | 1.64 ± 0.04 | 1.57 ± 0.04 | 1.75 ± 0.05 | 1.60 ± 0.12
Left Epididymis
Absolute (g) | 0.643 ± 0.011** | 0.639 ± 0.014 | 0.592 ± 0.014 | 0.432 ± 0.028**
Relative (mg/g) | 1.61 ± 0.04 | 1.57 ± 0.04 | 1.71 ± 0.04 | 1.64 ± 0.10

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are displayed as mean ± standard error of the litter means.

^b^ Statistical analysis performed using the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

^d^ n = 9 due to removal of outliers.

Table 37 Summary of Organ Weights of Adult F_1_ Male Rats in the Prenatal and Reproductive Performance Cohorts Exposed to Bisphenol AF in Feed^a,b,c^

| 0 ppm | | 338 ppm | | 1,125 ppm | | 3,750 ppm
| RPC | PC | RPC | PC | RPC | PC | RPC | | PC
No. of Litters Examined | 22 | 22 | 23 | 21 | 21 | 22 | 20 | | 20
Necropsy Body Wt. (g) | 451.7 ± 6.6** | 419.1 ± 5.6** | 421.9 ± 7.9** | 402.8 ± 5.6 | 389.2 ± 5.8** | 360.6 ± 7.0** | 272.8 ± 6.5** | | 261.9 ± 5.9**
Dorsolateral Prostate Gland
Absolute (g) | 0.521 ± 0.029** | 0.488 ± 0.028** | 0.497 ± 0.018 | 0.441 ± 0.017 | 0.487 ± 0.015^d^ | 0.411 ± 0.022* | 0.169 ± 0.021** | | 0.168 ± 0.016**^e^
Relative (mg/g)^f^ | 1.15 ± 0.06** | 1.17 ± 0.07** | 1.18 ± 0.04 | 1.09 ± 0.04 | 1.25 ± 0.04^d^ | 1.15 ± 0.07 | 0.61 ± 0.07** | | 0.64 ± 0.05**^e^
Ventral Prostate Gland
Absolute (g) | 0.714 ± 0.035** | 0.627 ± 0.031** | 0.714 ± 0.027 | 0.571 ± 0.026 | 0.616 ± 0.027* | 0.466 ± 0.027** | 0.172 ± 0.024** | | 0.161 ± 0.022**^d^
Relative (mg/g) | 1.59 ± 0.08** | 1.50 ± 0.08** | 1.70 ± 0.06 | 1.42 ± 0.06 | 1.59 ± 0.07 | 1.29 ± 0.07* | 0.61 ± 0.07** | | 0.61 ± 0.08**^d^
Seminal Vesicles with Coagulating Gland
Absolute (g) | 1.706 ± 0.044** | 1.466 ± 0.055** | 1.589 ± 0.043 | 1.384 ± 0.032 | 1.515 ± 0.058* | 1.318 ± 0.053* | 0.344 ± 0.069** | | 0.362 ± 0.058**^e^
Relative (mg/g) | 3.79 ± 0.10** | 3.50 ± 0.13** | 3.79 ± 0.12 | 3.44 ± 0.08 | 3.89 ± 0.13 | 3.68 ± 0.15 | 1.20 ± 0.22** | | 1.35 ± 0.19**^e^
Levator Ani/bulbocavernosus Muscle Complex
Absolute (g) | 1.243 ± 0.027** | 1.231 ± 0.036** | 1.190 ± 0.024 | 1.152 ± 0.030 | 1.155 ± 0.022* | 1.087 ± 0.026** | 0.497 ± 0.040** | | 0.471 ± 0.044**
Relative (mg/g) | 2.76 ± 0.07** | 2.94 ± 0.09** | 2.84 ± 0.07 | 2.86 ± 0.07 | 2.97 ± 0.06 | 3.03 ± 0.09 | 1.80 ± 0.12** | | 1.78 ± 0.14**
Cowper’s Glands
Absolute (g) | 0.1198 ± 0.0024** | 0.1121 ± 0.0040** | 0.0990 ± 0.0044** | 0.1047 ± 0.0038 | 0.1004 ± 0.0033** | 0.0935 ± 0.0041**^g^ | 0.0404 ± 0.0046**^g^ | | 0.0371 ± 0.0033**^h^
Relative (mg/g) | 0.27 ± 0.00** | 0.27 ± 0.01** | 0.23 ± 0.01 | 0.26 ± 0.01 | 0.26 ± 0.01 | 0.26 ± 0.01^g^ | 0.14 ± 0.01**^g^ | | 0.14 ± 0.01**^h^
Right Testis
Absolute (g) | 1.997 ± 0.077** | 1.928 ± 0.086** | 1.978 ± 0.027 | 1.883 ± 0.028 | 1.884 ± 0.044 | 1.772 ± 0.046 | 1.396 ± 0.087** | | 1.340 ± 0.056**
Relative (mg/g) | 4.43 ± 0.17** | 4.58 ± 0.21** | 4.71 ± 0.08 | 4.69 ± 0.08 | 4.84 ± 0.09 | 4.93 ± 0.13 | 5.08 ± 0.29* | | 5.16 ± 0.23*
Left Testis
Absolute (g) | 1.965 ± 0.078** | 2.021 ± 0.029** | 1.965 ± 0.028 | 1.903 ± 0.030* | 1.876 ± 0.047 | 1.776 ± 0.047** | 1.469 ± 0.057** | | 1.355 ± 0.054**
Relative (mg/g) | 4.36 ± 0.17** | 4.85 ± 0.11** | 4.68 ± 0.08 | 4.74 ± 0.08 | 4.82 ± 0.10* | 4.95 ± 0.13 | 5.37 ± 0.16** | | 5.22 ± 0.22
Right Epididymis
Absolute (g) | 0.646 ± 0.020** | 0.699 ± 0.023** | 0.629 ± 0.009 | 0.666 ± 0.008 | 0.587 ± 0.014* | 0.623 ± 0.013** | 0.385 ± 0.027** | | 0.407 ± 0.022**
Relative (mg/g) | 1.43 ± 0.04 | 1.66 ± 0.05 | 1.50 ± 0.02 | 1.66 ± 0.03 | 1.51 ± 0.03 | 1.74 ± 0.04 | 1.39 ± 0.09 | | 1.55 ± 0.08
Left Epididymis
Absolute (g) | 0.656 ± 0.019** | 0.708 ± 0.012** | 0.648 ± 0.010 | 0.661 ± 0.009* | 0.602 ± 0.013* | 0.621 ± 0.011** | 0.405 ± 0.020** | | 0.410 ± 0.019**
Relative (mg/g) | 1.45 ± 0.04 | 1.69 ± 0.03 | 1.54 ± 0.02 | 1.65 ± 0.03 | 1.55 ± 0.03 | 1.73 ± 0.04 | 1.47 ± 0.06 | | 1.57 ± 0.07
Preputial Glands
Absolute (g) | 0.1504 ± 0.0089** | 0.1667 ± 0.0106** | 0.1508 ± 0.0127 | 0.1527 ± 0.0154 | 0.1235 ± 0.0072 | 0.1407 ± 0.0107^f^ | 0.1022 ± 0.0070** | | 0.1089 ± 0.0054**
Relative (mg/g) | 0.33 ± 0.02 | 0.40 ± 0.03 | 0.36 ± 0.03 | 0.38 ± 0.04 | 0.32 ± 0.02 | 0.39 ± 0.03 | 0.38 ± 0.03 | | 0.42 ± 0.02

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

RPC = reproductive performance cohort; PC = prenatal cohort.

^a^ Data for the RPC and PC are also presented separately by cohort in Appendix E.

^b^ Data are displayed as mean ± standard error of the litter means.

^c^ Statistical analysis performed using the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^d^ n = 20 due to removal of outliers.

^e^ n = 19 due to removal of outliers.

^f^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

^g^ n = 21 due to removal of outliers.

^h^ n = 18 due to removal of outliers.

There was a BPAF-related significant increase in the relative weights of the adrenal glands and thyroid in the F_1_ males in the subchronic cohort (Table 36). Although absolute adrenal and thyroid gland weights were similar to the control group for the 3,750 ppm group, relative weights were significantly increased, indicating that the adrenals and thyroid were large relative to the size of the animals. There was no effect of BPAF exposure on weights of the adrenal and thyroid glands for the 338 and 1,125 ppm groups.

Absolute weight of the lungs in the 3,750 ppm group of the subchronic cohort was significantly decreased to 21% below the control group, whereas relative weight of the lungs for the 3,750 ppm group was significantly increased (Table 36). There was no effect of BPAF exposure on weight of the lungs for the 338 and 1,125 ppm groups.

For F_1_ males in the subchronic cohort, the absolute liver, kidney (left and right), heart, and thymus weights were significantly decreased to 12%–24% and 29%–38% less than the control group for the 1,125 and 3,750 ppm groups, respectively (Table 36). Relative organ weights were not significantly different from the control group for the right kidney and thymus, suggesting that the lower absolute weights for these tissues might have been secondary to the effect of BPAF on body weight. There were significant decreases in relative liver and left kidney weights and a positive trend for relative heart weight for the 3,750 ppm group. There was no effect of BPAF exposure on liver, kidney (left and right), heart, and thymus weights for the 338 ppm group.

Absolute weights of the dorsolateral prostate for F_1_ males from the 3,750 ppm groups across the three cohorts were significantly decreased by 56%–68% below the respective control groups (Table 36, Table 37). Absolute weights of the ventral prostate across the three cohorts were significantly decreased by 14%–26% and 69%–76% below that of the control group for the 1,125 and 3,750 ppm groups, respectively. Relative weights of the dorsolateral and ventral prostate were significantly decreased for the 3,750 ppm groups across the three cohorts; relative weights for the ventral prostate were also significantly decreased for the 1,125 ppm groups in the subchronic and prenatal cohorts. The magnitudes of the reduction in weights of the dorsolateral prostate in the 3,750 ppm groups and the ventral prostate in the 1,125 and 3,750 ppm groups were more than the magnitudes of the reduction in body weights, suggesting a direct BPAF-mediated suppression of maturation of these tissues. The decrease in absolute weight of the dorsolateral prostate for the 1,125 ppm group was only significant (16%) for the prenatal cohort, although there was also a similar degree of reduction in weight of the dorsolateral prostate (13.6%) in the subchronic cohort, and might have been secondary to the effect of BPAF on body weight. There was no effect of BPAF exposure on prostate weight for the 338 ppm group.

Absolute weights of the seminal vesicles with coagulating glands for F_1_ males across the three cohorts were lower by 10%–13% compared to the control group (significant in the prenatal and reproductive performance cohorts) in the 1,125 ppm groups and significantly decreased by 70%–80% compared to the control group for the 3,750 ppm groups (Table 36, Table 37). Relative weight of the seminal vesicles with coagulating glands for males in the 3,750 ppm group was significantly decreased. The magnitude of the reduction in weight of the seminal vesicles for the 3,750 ppm group was more than the magnitude of the reduction in body weight, suggesting a direct BPAF-mediated suppression of maturation of this tissue. The changes in absolute weight of the seminal vesicles for the 1,125 ppm group might have been secondary to the effect of BPAF on body weight given that the corresponding relative weight was similar to that of the control group. There was no effect of BPAF exposure on seminal vesicle weight for the 338 ppm group.

The levator ani/bulbocavernosus muscle (LABC) and Cowper’s glands were weighed in both the prenatal and reproductive performance cohorts (Table 37). Absolute weights of the LABC were significantly decreased by 7%–12% and 60%–62% compared to the control group for the 1,125 and 3,750 ppm groups, respectively. Relative weights were significantly decreased for the 3,750 ppm group. Absolute weights of the Cowper’s glands were significantly decreased by 17% (reproductive performance cohort only), 16%–17%, and 66%–67% compared to the control group for the 338, 1,125, and 3,750 ppm groups, respectively. Relative weights were significantly decreased for the 3,750 ppm group. The magnitude of the reductions in weights of the LABC and the Cowper’s glands for the 3,750 ppm group were more than the magnitude of the reduction in body weight, suggesting a direct BPAF-mediated suppression of maturation of these tissues. The reductions in absolute weights in the 338 (Cowper’s glands only) and 1,125 ppm groups (LABC and Cowper’s glands) might have been secondary to the effects of BPAF on body weight given that the corresponding relative weights were not significantly different from the control group. There was no effect of BPAF exposure on weights of the LABC for the 338 ppm group.

For F_1_ males across the three cohorts, absolute testis weights (right and left) were lower by 5%–12% and significantly decreased by 25%–33% below the control group for the 1,125 and 3,750 ppm groups, respectively (Table 36, Table 37). Absolute weights of the epididymides were lower by 7%–8% in the subchronic cohort and significantly decreased by 8%–12% in the prenatal and reproductive performance cohorts in the 1,125 ppm group. Absolute weights of the epididymides were significantly decreased by 33%–42% compared to the control group in the 3,750 ppm group. Although relative testis weights were higher for the 1,125 and 3,750 ppm groups and suggest that the lower absolute weights might have been secondary to the effect of BPAF on body weight, the histopathological findings in these tissues indicate a potential direct impact of exposure to BPAF (Appendix E). Relative epididymis weights were similar to the control group. The testicular weight changes in the 3,750 ppm group correlated with a significant increase of testis spermatid head concentration (24% above the control group). The significant decrease in absolute epididymal weight for the 3,750 ppm group compared to the control group correlated with a reduction in cauda epididymal sperm concentration (17% below the control group). There was a significant decrease of absolute testis (left) and epididymis (left) weights for the animals in the 338 ppm prenatal cohort.

The preputial glands were weighed in both the prenatal and reproductive performance cohorts (Table 37). Absolute weight of the preputial glands in the 3,750 ppm group was significantly decreased by 32%–35% below the control group. Relative weight of the preputial glands was not significantly different from the control group, suggesting that the lower absolute weight in the 3,750 ppm group might have been secondary to the effect of BPAF on body weight. There was no effect of BPAF exposure on the weight of the preputial glands for the 338 and 1,125 ppm groups.

#### Female Necropsies

The F_1_ females in the reproductive performance cohort were euthanized at 158–175 days of age when their F_2_ pups reached PND 28. F_1_ females in the prenatal cohort were euthanized on the assumed GD 21 of pregnancy with the F_2_ generation at 123–137 days of age, and the F_1_ subchronic cohort females were 116–120 days of age at the time of necropsy. There were BPAF-related gross findings, including three F_1_ females in the 3,750 ppm group with malformations of the vagina: one had no apparent vaginal opening and two had a misshapen vagina (Table 38, Table 39). Terminal body (necropsy) weights of rats in the 1,125 and 3,750 ppm groups were significantly decreased by 11%–20% and 23%, respectively, relative to the terminal body weight of the control animals (Table 40, Table 41).

Table 38 Summary of Gross Necropsy Findings in Adult F_1_ Female Rats in the Subchronic Cohort Exposed to Bisphenol AF in Feed^a^

| 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
No. of Animals Examined^b^ | 10 (10) | 10 (10) | 10 (10) | 10 (10)
Ovaries
Reduced
Bilateral^c^ | 0** | 0 | 0 | 9 (9)**
Uterus
Reduced
Bilateral | 0** | 0 | 0 | 9 (9)**

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

^a^ Statistical analysis performed using the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^b^ Number of animals (number of litters) examined for gross lesions.

^c^ Number of animals (number of litters) with lesion.

Table 39 Summary of Gross Necropsy Findings in Adult F_1_ Female Rats in the Prenatal and Reproductive Performance Cohorts Exposed to Bisphenol AF in Feed^a,b^

| 0 ppm | | 338 ppm | | 1,125 ppm | | 3,750 ppm
| RPC | PC | RPC | PC | RPC | PC | RPC | PC
No. of Animals Examined^c^ | 22 (22) | 22 (22) | 24 (24) | 21 (21) | 21 (21) | 22 (22) | 20 (20) | 20 (20)
Ovaries
Reduced
Left^d^ | 0 | 0* | 0 | 0 | 0 | 0 | 0 | 2 (2)
Right | 0 | 0* | 0 | 0 | 0 | 0 | 0 | 2 (2)
Bilateral | 0** | 0** | 0 | 0 | 0 | 1 (1) | 18 (18)** | 17 (17)**
Total | 0** | 0** | 0 | 0 | 0 | 1 (1) | 18 (18)** | 19 (19)**
Uterus
Reduced
Bilateral | 0 | 0** | 0 | 0 | 0 | 1 (1) | 0 | 19 (19)**
Vagina
Deformity | 0 | 0 | 0 | 0 | 0 | 0 | 1 (1) | 0
Misshapen | 0 | 0 | 0 | 0 | 0 | 0 | 1 (1) | 1 (1)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; ** p ≤ 0.01.

RPC = reproductive performance cohort; PC = prenatal cohort.

^a^ Data for the RPC and PC are also presented separately by cohort in Appendix E.

^b^ Statistical analysis performed using the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^c^ Number of animals (number of litters) examined for gross lesions.

^d^ Number of animals (number of litters) with lesion.

Table 40 Summary of Organ Weights of Adult F_1_ Female Rats in the Subchronic Cohort Exposed to Bisphenol AF in Feed^a,b^

| 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
No. of Litters Examined | 10 | 10 | 10 | 10
Necropsy Body Wt. (g) | 253.1 ± 5.7** | 234.9 ± 9.9 | 214.8 ± 3.3** | 194.1 ± 7.8**
Right Ovary
Absolute (g) | 0.0766 ± 0.0024** | 0.0716 ± 0.0064 | 0.0633 ± 0.0048* | 0.0283 ± 0.0015**
Relative (mg/g)^c^ | 0.30 ± 0.01** | 0.30 ± 0.02 | 0.29 ± 0.02 | 0.15 ± 0.01**
Left Ovary
Absolute (g) | 0.0812 ± 0.0032** | 0.0743 ± 0.0049 | 0.0593 ± 0.0031** | 0.0289 ± 0.0031**
Relative (mg/g) | 0.32 ± 0.01** | 0.32 ± 0.02 | 0.28 ± 0.01* | 0.15 ± 0.01**
Uterus, Cervix, and Vagina
Absolute (g) | 1.002 ± 0.079** | 0.843 ± 0.127 | 0.694 ± 0.054* | 0.632 ± 0.091**
Relative (mg/g) | 4.00 ± 0.35 | 3.70 ± 0.62 | 3.21 ± 0.21 | 3.25 ± 0.43
Right Kidney
Absolute (g) | 0.89 ± 0.02** | 0.84 ± 0.04 | 0.75 ± 0.03** | 0.71 ± 0.04**
Relative (mg/g) | 3.54 ± 0.05 | 3.57 ± 0.06 | 3.48 ± 0.10 | 3.71 ± 0.20
Left Kidney
Absolute (g) | 0.87 ± 0.01** | 0.83 ± 0.04 | 0.76 ± 0.03** | 0.69 ± 0.03**
Relative (mg/g) | 3.46 ± 0.06 | 3.55 ± 0.05 | 3.53 ± 0.10 | 3.58 ± 0.15
Lung
Absolute (g) | 1.72 ± 0.06** | 1.68 ± 0.09 | 1.57 ± 0.06 | 1.37 ± 0.08**
Relative (mg/g) | 6.78 ± 0.18 | 7.15 ± 0.28 | 7.32 ± 0.22 | 7.14 ± 0.41
Heart
Absolute (g) | 1.01 ± 0.03** | 1.03 ± 0.03 | 0.92 ± 0.02* | 0.82 ± 0.03**
Relative (mg/g) | 4.02 ± 0.08 | 4.40 ± 0.09 | 4.28 ± 0.12 | 4.26 ± 0.16
Adrenal Glands
Absolute (g) | 0.0786 ± 0.0036** | 0.0709 ± 0.0038 | 0.0691 ± 0.0027 | 0.0578 ± 0.0029**
Relative (mg/g) | 0.31 ± 0.01 | 0.30 ± 0.01 | 0.32 ± 0.01 | 0.30 ± 0.02
Thyroid Gland
Absolute (g) | 0.0157 ± 0.0006 | 0.0161 ± 0.0008 | 0.0154 ± 0.0008 | 0.0145 ± 0.0008
Relative (mg/g) | 0.06 ± 0.00** | 0.07 ± 0.00 | 0.07 ± 0.00 | 0.07 ± 0.00*
Liver
Absolute (g) | 8.85 ± 0.25** | 9.04 ± 0.51 | 8.34 ± 0.29 | 7.64 ± 0.38
Relative (mg/g) | 35.00 ± 0.78* | 38.38 ± 1.13 | 38.77 ± 0.94 | 39.56 ± 1.85*
Thymus
Absolute (g) | 0.278 ± 0.014** | 0.293 ± 0.023 | 0.254 ± 0.019 | 0.227 ± 0.012
Relative (mg/g) | 1.10 ± 0.05 | 1.24 ± 0.07 | 1.18 ± 0.08 | 1.17 ± 0.05

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are displayed as mean ± standard error of the litter means.

^b^ Statistical analysis performed using the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

Table 41 Summary of Ovary Weights of Adult F_1_ Female Rats in the Prenatal and Reproductive Performance Cohorts Exposed to Bisphenol AF in Feed^a,b,c^

| 0 ppm | | 338 ppm | | 1,125 ppm | | 3,750 ppm
| RPC | PC | RPC | PC | RPC | PC | RPC | PC
No. of Litters Examined | 18 | 16 | 20 | 20 | 9 | 15 | –^d^ | –
Necropsy Body Wt. (g)^e^ | 306.5 ± 4.0** | 311.7 ± 3.3** | 284.6 ± 3.5** | 282.8 ± 4.4** | 272.2 ± 5.3** | 249.5 ± 5.3** | – | –
Right Ovary
Absolute (g) | 0.0748 ± 0.0038** | 0.0848 ± 0.0067** | 0.0644 ± 0.0043 | 0.0782 ± 0.0046 | 0.0464 ± 0.0053** | 0.0567 ± 0.0048** | – | –
Relative (mg/g)^f^ | 0.24 ± 0.01* | 0.27 ± 0.02 | 0.23 ± 0.01 | 0.28 ± 0.02 | 0.17 ± 0.02** | 0.23 ± 0.02 | – | –
Left Ovary
Absolute (g) | 0.0745 ± 0.0038** | 0.0825 ± 0.0042** | 0.0638 ± 0.0044 | 0.0717 ± 0.0043 | 0.0467 ± 0.0061** | 0.0539 ± 0.0041** | – | –
Relative (mg/g) | 0.24 ± 0.01* | 0.26 ± 0.01* | 0.22 ± 0.01 | 0.25 ± 0.02 | 0.17 ± 0.02** | 0.22 ± 0.02 | – | –

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

RPC = reproductive performance cohort; PC = prenatal cohort.

^a^ Data for the RPC and PC are also presented separately by cohort in Appendix E.

^b^ Data are displayed as mean ± standard error of the litter means.

^c^ Statistical analysis performed using the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^d^ None of the females in the 3,750 ppm group were sperm-positive, so no organ weight data were collected as the females were terminated at the end of cohabitation.

^e^ The terminal body weight for the prenatal females is the final body weight minus the gravid uterine weight.

^f^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

Absolute ovarian weights (left and right) were lower by 7%–14% for the 338 ppm group and significantly decreased by 17%–38% and 63%–64% below the control group for the 1,125 and 3,750 ppm groups, respectively, across the three cohorts (only the subchronic cohort was evaluated at 3,750 ppm) (Table 40, Table 41). Relative ovarian weights were significantly decreased in the 1,125 ppm group (the lower weights of the right ovary in the subchronic cohort and the left and right ovaries in the prenatal cohort were not significant) and in the 3,750 ppm group. The magnitude of the reduction in weights of the ovaries for the 1,125 and 3,750 ppm groups was more than the magnitude of the reduction in body weight relative to the control group, suggesting a direct BPAF-mediated suppression of maturation of this tissue.

The uterus was weighed with the cervix and vagina intact in the subchronic cohort so that it could be processed appropriately for histopathological examination (Table 40). The absolute weight of the uterus/cervix/vagina was lower by 16% for the 338 ppm group and significantly decreased by 31% and 37% for the 1,125 and 3,750 ppm groups, respectively, relative to the control group. Relative weights were lower in all three exposed groups but were not statistically different from the control group. The magnitude of the reduction in weight of the uterus/cervix/vagina was more than the magnitude of the reduction in body weight, suggesting a direct BPAF-mediated suppression of maturation of this tissue.

Absolute kidney (left and right), lung (only at 3,750 ppm), and heart weights were significantly decreased by 9%–16% and 19%–21% below the control group for the 1,125 and 3,750 ppm groups in the subchronic cohort, respectively (Table 40). Relative kidney, lung, and heart weights were not significantly different from the respective control groups, suggesting that the changes in absolute weights of those organs might have been secondary to the effect of BPAF on body weight. There was no effect of BPAF exposure on kidney (left and right), lung, and heart weights for the 338 ppm group.

Absolute weights of the adrenal glands were lower by 10% and 12% for the 338 and 1,125 ppm groups in the subchronic cohort, respectively, and significantly decreased to 26% below the control group for the 3,750 ppm group (Table 40). Relative adrenal gland weights were not significantly different from the control group, suggesting that the changes in absolute weights might have been secondary to the effect of BPAF on body weight.

Absolute weights of the thyroid were not significantly different from the respective control groups in the subchronic cohort (Table 40). Absolute liver and thymus weights showed a negative trend with exposure concentration. Relative thyroid and liver weights were significantly increased from the control group, indicating that the thyroid and liver were large relative to the size of the animals. Relative thymus weights were not significantly different from the control group, suggesting that the changes in absolute weights of the thymus might have been secondary to the effect of BPAF on body weight. There was no effect of BPAF exposure on thyroid, liver, or thymus weights for the 338 and 1,125 ppm groups.

### Clinical Pathology

For male rats in the subchronic cohort, measured mean cell volume (MCV) and mean cell hemoglobin (MCH) displayed a mild but significant increase (5%) in the 3,750 ppm group. The reticulocyte count exhibited a positive trend with exposure concentration (Appendix E). The significantly increased MCV and MCH were likely due to the higher reticulocyte count compared to the control group. The higher number of reticulocytes might have resulted from biological variability or a redistribution of the circulating reticulocytes.

For the 3,750 ppm females, the hemoglobin concentration and erythrocyte count displayed a mild but significant decrease (≤6%) compared to the control group. In addition, the white blood cell count was significantly decreased (26%) in the 3,750 ppm animals, and the monocyte and basophils counts were significantly decreased in most exposed groups relative to the control group. While there was no significant pairwise comparison, there was a negative trend in the lymphocyte count with exposure concentration (Table 42).

Table 42 Summary of Select Hematology Data for F_1_ Adult Female Rats in the Subchronic Cohort Exposed to Bisphenol AF in Feed^a,b^

| 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
n | 10 | 10 | 10 | 10
Erythrocytes (10^6^/µL) | 8.81 ± 0.15** | 8.68 ± 0.07 | 8.55 ± 0.10 | 8.27 ± 0.09**
Hemoglobin (g/dL) | 16.1 ± 0.2** | 15.9 ± 0.1 | 15.7 ± 0.2 | 15.3 ± 0.2**
Mean Cell Hemoglobin Concentration (g/dL) | 31.6 ± 0.2 | 31.4 ± 0.1 | 31.4 ± 0.1 | 31.3 ± 0.1
Mean Cell Volume (fL) | 57.9 ± 0.4* | 58.3 ± 0.4 | 58.5 ± 0.6 | 59.2 ± 0.3
Reticulocytes (10^3^/µL) | 206.3 ± 12.7 | 214.4 ± 11.4 | 210.0 ± 12.9 | 236.3 ± 17.7
White Blood Cells (10^3^/µL) | 10.36 ± 0.72** | 9.57 ± 0.92 | 8.57 ± 0.64 | 7.70 ± 0.80*
Neutrophils (10^3^/µL) | 1.42 ± 0.16 | 1.16 ± 0.09 | 1.05 ± 0.11 | 1.17 ± 0.19
Lymphocytes (10^3^/µL) | 7.76 ± 0.54* | 7.48 ± 0.84 | 6.83 ± 0.52 | 5.81 ± 0.66
Monocytes (10^3^/µL) | 0.39 ± 0.04** | 0.33 ± 0.04 | 0.27 ± 0.03* | 0.26 ± 0.05*
Basophils (10^3^/µL) | 0.25 ± 0.03** | 0.14 ± 0.02** | 0.12 ± 0.01** | 0.10 ± 0.02**

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data displayed as mean ± standard error.

^b^ Statistical analysis performed using the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

Several significant changes were observed in the clinical chemistry parameters (Table 43). Cholesterol concentrations were significantly decreased in the 1,125 and 3,750 ppm male rat groups and in all the BPAF-exposed female groups, relative to the respective control groups. In the 3,750 ppm females, triglyceride concentrations were significantly increased relative to the control group. In male rats, bile acid concentrations were significantly decreased in the 1,125 and 3,750 ppm groups, with the 3,750 ppm group being only 18% of the control group. In male rats, globulin concentrations were minimally but significantly decreased, which drove a mild significant decrease in the total protein concentration. Conversely, the 3,750 ppm female rats exhibited significantly increased globulin concentrations that resulted in a significant decrease in the albumin/globulin ratio relative to the control group. The relevance of these disparate mild globulin changes is uncertain.

Table 43 Summary of Select Clinical Chemistry Data for F_1_ Male and Female Adult Rats in the Subchronic Cohort Exposed to Bisphenol AF in Feed^a,b^

| 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
Male
n | 10 | 10 | 10 | 9
Total Protein (g/dL) | 6.80 ± 0.06* | 6.62 ± 0.08 | 6.60 ± 0.08 | 6.56 ± 0.06*
Albumin (g/dL) | 3.41 ± 0.03 | 3.33 ± 0.04 | 3.36 ± 0.05 | 3.36 ± 0.03
Globulin (g/dL) | 3.39 ± 0.04** | 3.29 ± 0.05 | 3.24 ± 0.05* | 3.20 ± 0.05**
A/G Ratio | 1.01 ± 0.01* | 1.01 ± 0.01 | 1.04 ± 0.01 | 1.05 ± 0.02
Cholesterol (mg/dL) | 94.3 ± 4.0** | 87.7 ± 4.5 | 75.2 ± 3.2** | 58.8 ± 4.1**
Triglycerides (mg/dL) | 154.7 ± 12.7 | 177.2 ± 13.9 | 172.8 ± 14.0 | 191.1 ± 15.2
Bile Acids (µmol/L) | 32.7 ± 4.4** | 25.3 ± 3.8 | 19.7 ± 2.8* | 6.0 ± 0.3**
Female
n | 10 | 10 | 10 | 10
Total Protein (g/dL) | 6.50 ± 0.10 | 6.32 ± 0.11 | 6.41 ± 0.09 | 6.65 ± 0.11
Albumin (g/dL) | 3.48 ± 0.05 | 3.31 ± 0.04 | 3.31 ± 0.05 | 3.34 ± 0.05
Globulin (g/dL) | 3.02 ± 0.06** | 3.01 ± 0.07 | 3.10 ± 0.06 | 3.31 ± 0.07**
A/G Ratio | 1.15 ± 0.02** | 1.10 ± 0.02 | 1.07 ± 0.02** | 1.01 ± 0.02**
Cholesterol (mg/dL) | 100.1 ± 2.4** | 87.5 ± 3.6* | 74.5 ± 5.7** | 63.2 ± 4.8**
Triglycerides (mg/dL) | 101.4 ± 11.6* | 108.0 ± 11.3 | 119.2 ± 20.2 | 167.8 ± 21.3*
Bile Acids (µmol/L) | 23.3 ± 6.2 | 25.9 ± 5.5 | 23.4 ± 3.2 | 10.5 ± 1.8

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

A/G Ratio = albumin/globulin ratio.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed using the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

### Histopathology

This section describes the statistically significant or biologically noteworthy changes in the incidences of nonneoplastic lesions in male and female reproductive organs in the reproductive performance and subchronic cohorts and nonneoplastic lesions in the kidneys in the subchronic cohort. Summaries of the incidences of nonneoplastic lesions are presented in Table 44 and Table 45 for male reproductive performance and subchronic cohort rats, respectively, in Table 46 and Table 47 for female reproductive performance and subchronic cohort rats, respectively, and are also presented as supplemental data in Appendix E.

Table 44 Incidences of Select Nonneoplastic Lesions in Adult F_1_ Male Rats in the Reproductive Performance Cohort Exposed to Bisphenol AF in Feed^a^

| 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
No. Examined^b^ | 22 (22) | 24 (24) | 21 (21) | 20 (20)
Testis
Germinal epithelium, degeneration^c^ | 0** | 0 | 1 (1) [2.0]^d^ | 6 (6)** [1.3]
Leydig cell, atrophy | 0** | 0 | 0 | 11 (11)** [1.8]
Seminiferous tubule, retention, spermatid | 0** | 0 | 0 | 8 (8)** [1.0]
Epididymis
Duct, atrophy | 0** | 0 | 0 | 10 (10)** [1.4]
Duct, hypospermia | 0** | 0 | 1 (1) [1.0] | 6 (6)** [2.0]
Duct, exfoliated germ cell | 0** | 0 | 1 (1) [1.0] | 5 (5)* [1.4]
Prostate Gland
Hypoplasia, dorsolateral | 0** | 0 | 0 | 18 (18)** [2.6]
Hypoplasia, ventral | 0** | 0 | 0 | 18 (18)** [2.6]
Seminal Vesicle
Hypoplasia, bilateral | 0** | 0 | 0 | 18 (18)** [2.6]
Coagulating Gland
Hypoplasia, bilateral | 0** | 0 | 0 | 18 (18)** [2.6]
Cowper’s Glands
Hypoplasia, bilateral | 0** | 0 | 0 | 15 (15)** [2.3]^e^
Hypoplasia, unilateral | 0 | 1 (1) [4.0] | 0 | 0
Hypoplasia, total | 0** | 1 (1) [4.0] | 0 | 15 (15)** [2.3]
Levator Ani/bulbocavernosus Muscle Complex
Hypoplasia | 0** | 0 | 1 (1) [2.0] | 17 (17)** [2.4]

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Statistical analysis performed using the Cochran-Armitage test with a Poly-3 adjustment for both trend and pairwise tests.

^b^ Number of animals (number of litters) with tissue examined microscopically.

^c^ Number of animals (number of litters) with lesion.

^d^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^e^ Two animals in the 3,750 ppm group were not examined for this lesion.

Table 45 Incidences of Select Nonneoplastic Lesions in Adult F_1_ Male Rats in the Subchronic Cohort Exposed to Bisphenol AF in Feed^a^

| 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
No. Examined^b^ | 10 (10) | 10 (10) | 10 (10) | 10 (10)
Testis
Germinal epithelium, degeneration^c^ | 0* | 0 | 0 | 2 (2) [1.5]^d^
Epididymis
Duct, exfoliated germ cell | 0** | 0 | 0 | 3 (3) [1.7]
Prostate Gland
Hypoplasia, dorsolateral | 0** | 0 | 0 | 10 (10)** [1.5]
Hypoplasia, ventral | 0** | 0 | 0 | 10 (10)** [1.5]
Seminal Vesicle
Hypoplasia, bilateral | 0** | 0 | 0 | 10 (10)** [1.6]
Kidney
Corticomedullary junction, mineral | 0 | –^e^ | – | 7 (7)** [1.1]

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Statistical analysis performed using the Cochran-Armitage test with a Poly-3 adjustment for both trend and pairwise tests.

^b^ Number of animals (number of litters) with tissue examined microscopically.

^c^ Number of animals (number of litters) with lesion.

^d^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^e^ No animals evaluated at 338 and 1,125 ppm.

Table 46 Incidences of Select Nonneoplastic Lesions in Adult F_1_ Female Rats in the Reproductive Performance Cohort Exposed to Bisphenol AF in Feed^a^

| 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
No. Examined^b^ | 22 (22) | 24 (24) | 21 (21) | 20 (20)
Ovary
Hypoplasia, bilateral^c^ | 0** | 1 (1) [1.0]^d^ | 0 | 20 (20)** [2.6]
Hypoplasia, unilateral | 0 | 2 (2) [1.0] | 0 | 0
Hypoplasia, total | 0** | 3 (3) [1.0] | 0 | 20 (20)** [2.6]
Uterus
Hypoplasia | 0** | 0 | 0 | 18 (18)** [1.4]
Epithelial, metaplasia, squamous | 0** | 0 | 0 | 20 (20)** [1.0]
Dilation, glandular, cystic | 0** | 0 | 0 | 8 (8)** [1.1]
Stroma, hyalinization | 0** | 0 | 8 (8)** [1.4] | 18 (18)** [3.0]
Epithelium, apoptosis, increased | 0* | 0 | 1 (1) | 3 (3)^e^

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Statistical analysis performed using the Cochran-Armitage test with a Poly-3 adjustment for both trend and pairwise tests.

^b^ Number of animals (number of litters) with tissue examined microscopically.

^c^ Number of animals (number of litters) with lesion.

^d^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^e^ No severity grade was used for the evaluation of this lesion, as directed by the Pathology Working Group.

Table 47 Incidences of Select Nonneoplastic Lesions in Adult F_1_ Female Rats in the Subchronic Cohort Exposed to Bisphenol AF in Feed^a^

| 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
No. Examined^b^ | 10 (10) | 10 (10) | 10 (10) | 10 (10)
Ovary
Hypoplasia, bilateral^c^ | 0** | 0 | 0 | 10 (10)** [2.2]^d^
Uterus
Hypoplasia | 0** | 0 | 0 | 10 (10)** [1.4]
Epithelial, metaplasia, squamous | 0** | 0 | 0 | 10 (10)** [1.3]
Dilation, glandular, cystic | 0** | 0 | 0 | 6 (6)** [1.8]
Stroma, hyalinization | 0** | 0 | 0 | 10 (10)** [3.0]

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

^a^ Statistical analysis performed using the Cochran-Armitage test with a Poly-3 adjustment for both trend and pairwise tests.

^b^ Number of animals (number of litters) with tissue examined microscopically.

^c^ Number of animals (number of litters) with lesion.

^d^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Testes: There was a significant increase in the incidence of germinal epithelium degeneration in the 3,750 ppm reproductive performance cohort and a positive trend in the subchronic cohort with exposure concentration (Table 44, Table 45). The incidences of Leydig cell atrophy and seminiferous tubule spermatid retention were significantly increased in the 3,750 ppm reproductive performance cohort but not in males exposed to lower concentrations, when compared to the control group. Degeneration in the testes encompassed several changes, including vacuolation of germinal epithelium, reduction and focal loss of elongating spermatids, and disorganization of germ cell layers (Figure 34). The severity was generally noted as minimal and was often accompanied by exfoliated germ cells in profiles of the epididymal duct lumen. Leydig cell atrophy was characterized by decreased number and size of Leydig cells (Figure 35). Seminiferous tubule spermatid retention was characterized by persistence of the most mature elongating spermatids after the stage of physiological release, which occurs at stage VIII. Mature elongating spermatids were present at or near the luminal surface in stage IX–XI testes.

Figure 34

Representative Images of Germinal Epithelial Degeneration in the Testis of F_1_ Male Rats in the Reproductive Performance Cohort Exposed to Bisphenol AF in Feed (H&E)

(A) An example of germinal epithelial degeneration is shown from a 3,750 ppm reproductive performance cohort male; this is a late stage tubule with general depletion of the elongating spermatids and disorganization of the pachytene spermatocytes in the germinal epithelium, as well as focal areas of germ cell drop out (arrow; 20x). (B) Another example of germinal epithelium degeneration is shown from a 3,750 ppm reproductive performance cohort male, where the main lesion of degeneration was vacuolation (arrow; 20x). H&E = hematoxylin and eosin stain.

Figure 35

Representative Images of Leydig Cell Atrophy in the Testis of F_1_ Male Rats in the Reproductive Performance Cohort Exposed to Bisphenol AF in Feed (H&E)

(A) Leydig (interstitial) cells next to the seminiferous tubules (arrows) are shown in a control reproductive performance cohort male (10x). (B) Atrophied Leydig cells are shown from a 3,750 ppm reproductive performance cohort male (10x). There is a decrease in both the size and number of Leydig cells in panel B. The increased interstitial space in both panels is due to fixation artifact. H&E = hematoxylin and eosin stain.

Epididymis: There was a significant increase in the incidences of epididymis duct atrophy and duct hypospermia in the 3,750 ppm reproductive performance cohort relative to its control group (Table 44). There was a significant increase in epididymis duct exfoliated germ cell in the 3,750 ppm reproductive performance cohort and a positive trend in the subchronic cohort with exposure concentration (Table 44, Table 45). Epididymis duct atrophy was characterized by generalized or segmental decreased diameters of the duct lumens and increased interstitial stroma (Figure 36). Epididymis duct hypospermia was characterized by a reduced density of sperm in the epididymal duct lumen. (Figure 36). Exfoliated germ cells consisted of numerous individualized sloughed germinal epithelial cells, often with condensed nuclei, and debris within the epididymal duct profiles (Figure 37).

Figure 36

Representative Images of Duct Atrophy and Hypospermia in the Epididymis of F_1_ Male Rats in the Reproductive Performance Cohort Exposed to Bisphenol AF in Feed (H&E)

(A) Normal size and histological appearance of duct profiles in the cauda epididymis are shown from a control reproductive performance cohort male rat (1.25x). (B) The duct profiles in the cauda epididymis are shown from a control reproductive performance cohort male rat (5x). (C) Epididymis duct atrophy with hypospermia is shown from a 3,750 ppm reproductive performance cohort male (1.25x). (D) The epididymis duct atrophy with hypospermia is shown from a 3,750 ppm reproductive performance cohort male (5x). Epididymis duct atrophy resulted in an overall smaller epididymis size with decreased diameters of the duct profiles, intraductal infolding of the epithelium to form a scalloped appearance, and increased interstitial stroma. Hypospermia was frequently a concurrent lesion. A section of testis is in the upper right-hand corner of panels A and C. H&E = hematoxylin and eosin stain.

Figure 37

Representative Image of Exfoliated Germ Cells in the Ducts of the Epididymis of F_1_ Male Rats in the Reproductive Performance Cohort Exposed to Bisphenol AF in Feed (H&E)

An example of a duct from the cauda epididymis with exfoliated germ cells is shown from a 3,750 ppm reproductive performance cohort male in Figure 36D (40x). Numerous individualized sloughed germinal epithelial cells are visible, often with condensed nuclei. H&E = hematoxylin and eosin stain.

Prostate gland: There were significant increases in the incidences of both dorsolateral and ventral prostate gland hypoplasia in the 3,750 ppm reproductive performance and subchronic cohorts (Table 44, Table 45). The prostate gland consists of a paired ventral portion and a paired dorsolateral portion, which together encircle the urethra. Hypoplasia was characterized by smaller glands with occasional malformed lobes compared to the control group (Figure 38).

Figure 38

Representative Images of Hypoplasia in the Prostate Gland, Seminal Vesicle, Coagulating Gland, and Cowper’s Gland of F_1_ Male Rats in the Reproductive Performance Cohort Exposed to Bisphenol AF in Feed (H&E)

(A) Normal prostate (dorsal, ventral, and lateral lobes) gland, seminal vesicle, coagulating gland, and Cowper’s gland are shown from a control reproductive performance cohort male (0.3x). (B) Hypoplasia of the corresponding tissues is shown from a 3,750 ppm reproductive performance cohort male at (0.6x). Hypoplasia was characterized by smaller tissues compared to the control group. H&E = hematoxylin and eosin stain.

Seminal vesicle: There was a significant increase in the incidences of bilateral hypoplasia in the 3,750 ppm reproductive performance and subchronic cohorts (Table 44, Table 45). Hypoplasia was characterized by smaller glands compared to the control group (Figure 38).

Coagulating and Cowper’s glands: There was a significant increase in the incidences of bilateral hypoplasia of these glands in the 3,750 ppm reproductive performance cohort (Table 44). Hypoplasia was characterized by smaller glands compared to the control group (Figure 38).

Levator ani/bulbocavernosus (LABC) muscle complex: There was a significant increase in the incidence of LABC hypoplasia in the 3,750 ppm reproductive performance cohort (Table 44). Hypoplasia of these pelvic floor muscles was characterized by smaller muscles compared to the control group (Figure 39).

Figure 39

Representative Images of Hypoplasia in the Levator Ani/bulbocavernosus (LABC) Muscle Complex of F_1_ Male Rats in the Reproductive Performance Cohort Exposed to Bisphenol AF in Feed (H&E)

(A) Normal LABC muscles are shown from a control reproductive performance cohort male (0.32x). (B) Hypoplastic LABC is shown from a 3,750 ppm reproductive performance cohort male (0.32x). Hypoplasia of this tissue was characterized by an overall smaller size but with normal architecture. H&E = hematoxylin and eosin stain.

Kidney: There was a significant increase in the incidence of mineral in the 3,750 ppm subchronic cohort (Table 45). This lesion consisted of focal, scattered deposits of dark basophilic granular material (mineral) noted primarily along the junction of the cortex and medulla (in the pars recta and thin loops of Henle near the junction of the outer and inner stripes of the outer medulla).

Ovary: There was a significant increase in the incidences of bilateral ovarian hypoplasia in the 3,750 ppm reproductive performance and subchronic cohorts (Table 46, Table 47). This lesion was characterized by an overall reduction in the size of the ovary accompanied by a reduction in numbers of corpora lutea, follicle maturation arrest (many secondary follicles present), and increased interstitial tissue (Figure 40). Primary follicles were present in the ovarian sections.

Figure 40

Representative Images of Hypoplasia in the Ovary of F_1_ Female Rats in the Reproductive Performance Cohort Exposed to Bisphenol AF in Feed (H&E)

(A) Normal size and histological appearance of an ovary is shown from a control reproductive performance cohort female (1.25x). (B) An ovary is shown from a 3,750 ppm reproductive performance cohort female diagnosed with ovarian hypoplasia (1.16x). This lesion was characterized by an overall reduction in the size of the ovary due to a lack of, or reduction in, numbers of corpora lutea and reduced numbers of antral and/or growing follicles. (C) Higher magnification of panel A is shown (5x). Note the prominent corpora lutea (arrows). (D) Higher magnification of panel B is shown (10x). H&E = hematoxylin and eosin stain.

Uterus: There were significant increases in the incidences of hypoplasia, epithelial squamous metaplasia, and cystic glandular dilation in the 3,750 ppm reproductive performance and subchronic cohorts (Table 46, Table 47). There were significant increases in stromal hyalinization in the 1,125 and 3,750 ppm reproductive performance cohorts and in the 3,750 ppm subchronic cohort. There was also a positive trend for uterine epithelium apoptosis in the reproductive performance cohort with exposure concentration. Apoptosis of the uterine luminal epithelium is a normal physiologic response during the estrous cycle. Uterine epithelium apoptosis was diagnosed when there was an increase in the individual small, dark, hyperchromatic epithelial cells within the lining of the uterine lumen compared to normal control animals. Uterine hypoplasia was characterized by an overall smaller size, a thinning and less dense stroma of the endometrium, and a reduction in the number of endometrial glands (Figure 41). Squamous metaplasia included areas of flat or stratified squamous non-keratinizing and keratinizing epithelium replacing the uterine columnar lining epithelium and the glandular epithelium (Figure 42). These areas of squamous metaplasia were throughout the length of the uterine horns with the exception of the area near the uterocervical junction. Cystic glandular dilation was diagnosed when the endometrial glands were severely dilated and occurred more frequently throughout the uterine sections compared to control animals (Figure 43). Compression of the lining epithelium was common.

Figure 41

Representative Images of Hypoplasia in the Uterus of F_1_ Female Rats in the Reproductive Performance Cohort Exposed to Bisphenol AF in Feed (H&E)

(A) Normal uterine horn is shown from a control reproductive performance cohort female (4x). (B) Hypoplastic uterine horn is shown from a 3,750 ppm reproductive performance cohort female (4x). Uterine hypoplasia was characterized by an overall smaller uterus size, thinning and less dense endometrial stroma, and a reduction in the number of endometrial glands. H&E = hematoxylin and eosin stain.

Figure 42

Representative Image of Epithelial Squamous Metaplasia in the Uterus of F_1_ Female Rats in the Reproductive Performance Cohort Exposed to Bisphenol AF in Feed (H&E)

An example of uterine epithelial squamous metaplasia is shown from a 3,750 ppm reproductive performance cohort female (23x). Squamous metaplasia included areas of flat or stratified squamous non-keratinizing and keratinizing epithelium replacing the uterine columnar lining epithelium (short arrow) and the glandular epithelium (long arrow). H&E = hematoxylin and eosin stain.

Figure 43

Representative Image of Cystic Glandular Dilation in the Uterus of F_1_ Female Rats in the Reproductive Performance Cohort Exposed to Bisphenol AF in Feed (H&E)

Cystic glandular dilation is present in this uterus from a 3,750 ppm reproductive performance cohort female (2x). This lesion was characterized by endometrial glands that were severely dilated (arrow) compared to control females. H&E = hematoxylin and eosin stain.

Hyalinization of the stroma was characterized by stroma that had an amphophilic, glassy, and translucent appearance with reduced stromal nuclei (Figure 44).

Figure 44

Representative Images of Endometrial Stromal Hyalinization in the Uterus of F_1_ Female Rats in the Reproductive Performance Cohort Exposed to Bisphenol AF in Feed (H&E)

(A) A high magnification image of normal uterine stroma is shown from a control reproductive performance cohort female (40x). (B) Hyalinization of the endometrial stroma is shown in a 3,750 ppm reproductive performance cohort female (40x). This lesion was characterized by stroma that had an amphophilic, glassy, and translucent appearance with reduced stromal nuclei. H&E = hematoxylin and eosin stain.

### F_2_ Necropsies

Pups were euthanized on PND 91–93; gross pathology findings and organ weights are reported in Appendix E.

#### Male Necropsies

For males, there were BPAF-related significant decreases of cauda epididymal weight at 338 (6% below the control group) and 1,125 ppm (19% below the control group) (Table 48). There was no effect of BPAF exposure on percentage of motile sperm, percentage of progressively motile sperm, cauda epididymal sperm concentration (per g cauda epididymis), or on relative testis spermatid head concentration. There were BPAF-related gross findings in the Cowper’s glands, LABC, prostate gland, and seminal vesicles (Table 49), and for a few animals in the 1,125 ppm group, these organs were reduced in size.

Table 48 Summary of Reproductive System Parameters of F_2_ Male Rats in the Reproductive Performance Cohort Exposed to Bisphenol AF in Feed

Parameter^a^ | 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
No. Examined on PND 91–93^b^ | 51 (17) | 69 (19) | 27 (7) | –^c^
Weights (g)^d,e^
Left cauda epididymis | 0.211 ± 0.005** | 0.198 ± 0.003** | 0.171 ± 0.005** | –
Left epididymis | 0.584 ± 0.009** | 0.551 ± 0.009* | 0.501 ± 0.010** | –
Left testis | 2.014 ± 0.023** | 1.855 ± 0.026** | 1.851 ± 0.041** | –
Spermatid Measurements^f^
Spermatid heads (10^6^/g testis) | 130.3 ± 3.0 | 131.3 ± 2.7 | 135.7 ± 3.0 | –
Spermatid heads (10^6^/testis) | 262.3 ± 6.2 | 243.4 ± 5.6* | 250.2 ± 6.0* | –
Epididymal Spermatozoal Measurements^f^
Sperm motility (%) | 64.9 ± 3.7 | 65.8 ± 1.9 | 64.5 ± 4.4 | –
Sperm progressive motility (%) | 45.4 ± 2.6 | 45.6 ± 1.6 | 47.9 ± 3.6 | –
Sperm (10^6^/g cauda epididymis) | 875.3 ± 26.5 | 880.2 ± 21.2 | 892.1 ± 34.2 | –
Cauda epididymis sperm count (10^6^/cauda epididymis) | 186.6 ± 8.6** | 175.0 ± 6.2 | 152.9 ± 8.7* | –

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

PND = postnatal day.

^a^ Data are presented as mean ± standard error.

^b^ No. Examined on PND 91–93 = the number of pups examined (number of litters). Spermatid head concentration, epididymis weight, and testis weight for one animal in the control group and one animal in the 338 ppm group were excluded as outliers.

^c^ No females were confirmed pregnant for the 3,750 ppm group.

^d^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple comparisons.

^e^ If there was a lesion in the left organ, the contralateral tissue was taken.

^f^ Statistical analysis performed using a bootstrapped Jonckheere test for trend, and a Datta-Satten modified Wilcoxon test with Hommel adjustment for pairwise comparisons.

Table 49 Summary of Gross Necropsy Findings in F_2_ Male Rats Exposed to Bisphenol AF in Feed^a^

| 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
No. of Animals Examined^b^ | 52 (17) | 70 (19) | 27 (7) | –^c^
Cowper’s Gland
Size, reduced
Left^d^ | 1 (1) | 0 | 0 | –
Bilateral | 1 (1) | 0 | 3 (3) | –
Total | 2 (2) | 0 | 3 (3) | –
Levator Ani/bulbocavernosus Muscle Complex
Size, reduced | 0 | 0 | 2 (2) | –
Dorsolateral Prostate Gland
Size, reduced | 1 (1) | 0 | 4 (3) | –
Ventral Prostate Gland
Size, reduced | 1 (1)* | 0 | 5 (3) | –
Seminal Vesicles
Size, reduced
Bilateral | 0* | 0 | 5 (3) | –

Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

^a^ Statistical analysis performed using the Cochran-Armitage test with a Rao-Scott modification for the random effect due to litter.

^b^ Number of animals (number of litters) examined for gross lesions.

^c^ No females were confirmed pregnant for the 3,750 ppm group.

^d^ Number of animals (number of litters) with lesion.

In addition to gross findings, significant decreases of most male reproductive tissue weights, except preputial glands, were observed in both the 338 and 1,125 ppm groups. Terminal mean body weights were not significantly different from the control group for F_2_ males (Table 50). Histopathology was not evaluated for the F_2_ animals.

Table 50 Summary of Organ Weights from F_2_ Male Rats Following Perinatal Exposure to Bisphenol AF^a,b^

| 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
Necropsy Body Wt. (g) | 388.8 ± 6.6 52 (17)^c^ | 374.6 ± 5.7 70 (19) | 362.8 ± 11.1 27 (7) | –^d^
Dorsolateral Prostate Gland
Absolute (g) | 0.410 ± 0.012** 52 (17) | 0.362 ± 0.011** 70 (19) | 0.327 ± 0.017** 27 (7) | –
Relative (mg/g)^e^ | 1.06 ± 0.03** 52 (17) | 0.97 ± 0.03* 70 (19) | 0.90 ± 0.04** 27 (7) | –
Ventral Prostate Gland
Absolute (g) | 0.528 ± 0.018** 52 (17) | 0.514 ± 0.016 70 (19) | 0.401 ± 0.022** 27 (7) | –
Relative (mg/g) | 1.36 ± 0.05** 52 (17) | 1.38 ± 0.04 70 (19) | 1.10 ± 0.04** 27 (7) | –
Seminal Vesicles with Coagulating Gland
Absolute (g) | 1.215 ± 0.035** 50 (16) | 1.144 ± 0.024* 70 (19) | 1.020 ± 0.030** 27 (7) | –
Relative (mg/g) | 3.16 ± 0.10** 50 (16) | 3.07 ± 0.07 70 (19) | 2.82 ± 0.09** 27 (7) | –
Cowper’s Glands
Absolute (g) | 0.0898 ± 0.0023** 51 (17) | 0.0808 ± 0.0027** 68 (19) | 0.0698 ± 0.0033** 27 (7) | –
Relative (mg/g) | 0.23 ± 0.01** 51 (17) | 0.22 ± 0.01* 68 (19) | 0.19 ± 0.01** 27 (7) | –
Levator Ani/bulbocavernosus Muscle Complex
Absolute (g) | 1.037 ± 0.022** 52 (17) | 0.967 ± 0.020** 70 (19) | 0.892 ± 0.037** 27 (7) | –
Relative (mg/g) | 2.68 ± 0.07* 52 (17) | 2.60 ± 0.06 70 (19) | 2.46 ± 0.05* 27 (7) | –
Right Testis
Absolute (g) | 1.949 ± 0.045 52 (17) | 1.837 ± 0.025 69 (19) | 1.829 ± 0.047 27 (7) | –
Relative (mg/g) | 5.03 ± 0.10 52 (17) | 4.93 ± 0.09 69 (19) | 5.07 ± 0.16 27 (7) | –
Left Testis
Absolute (g) | 1.990 ± 0.033* 52 (17) | 1.842 ± 0.027** 70 (19) | 1.851 ± 0.041* 27 (7) | –
Relative (mg/g) | 5.14 ± 0.10 52 (17) | 4.95 ± 0.09 70 (19) | 5.14 ± 0.16 27 (7) | –
Right Epididymis
Absolute (g) | 0.564 ± 0.014** 52 (17) | 0.545 ± 0.009 70 (19) | 0.499 ± 0.010** 27 (7) | –
Relative (mg/g) | 1.46 ± 0.03* 52 (17) | 1.46 ± 0.02 70 (19) | 1.38 ± 0.03 27 (7) | –
Left Epididymis
Absolute (g) | 0.584 ± 0.009** 51 (17) | 0.551 ± 0.009* 69 (19) | 0.501 ± 0.010** 27 (7) | –
Relative (mg/g) | 1.51 ± 0.02** 51 (17) | 1.48 ± 0.02 69 (19) | 1.39 ± 0.03** 27 (7) | –

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are displayed as mean ± standard error of the litter means.

^b^ Statistical analysis performed using mixed models with a random effect for litter for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^c^ Number of animals (number of litters). Organs removed as outliers include: seminal vesicles with coagulating gland (from two animals in the vehicle control group), Cowper’s gland (one from the vehicle control group and two from the 338 ppm group), right testis (one from the 338 ppm group), and left epididymis (one from the vehicle control group and one from the 338 ppm group).

^d^ No females were confirmed pregnant for the 3,750 ppm group.

^e^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

Absolute dorsolateral and ventral prostate weights were significantly decreased relative to the control group by 12% and 20% for the 338 and 1,125 ppm groups (dorsolateral), respectively, and by 24% for the 1,125 ppm group (ventral) (Table 50). Relative weights, as compared to body weight, of the dorsolateral prostate were significantly decreased in the 338 and 1,125 ppm groups, and the relative weight of the ventral prostate was significantly decreased in the 1,125 ppm group compared to the control group. The magnitude of the reductions in dorsolateral and ventral prostate weights was larger than the magnitude of the reduction in body weight, suggesting a direct BPAF-mediated suppression of maturation of these tissues. There was no effect of BPAF exposure on ventral prostate weight in the 338 ppm group.

The magnitude of the reduction in weight of the seminal vesicles, Cowper’s glands, and LABC was slightly more than the magnitude of the reduction in body weight, suggesting a direct BPAF-mediated suppression of maturation of these tissues. Absolute weights of the seminal vesicles with coagulating glands were significantly decreased by 6% and 16% for the 338 and 1,125 ppm groups, respectively, and relative weights were significantly decreased for the 1,125 ppm group (Table 50).

Absolute weights of the Cowper’s glands were significantly decreased by 10% and 22% for the 338 and 1,125 ppm groups, respectively, and relative weights were also significantly decreased for the 338 and 1,125 ppm groups (Table 50).

Absolute weight of the LABC was significantly decreased by 7% and 14% below the control group for the 338 and 1,125 ppm groups, respectively (Table 50). Relative weight of the LABC was significantly decreased for the 1,125 ppm group.

Absolute testis weights were lower by 6%–7% compared with the control group in the 338 and 1,125 ppm groups, with the left testis weight significantly decreased (Table 50). Relative left testis weights were lower than those of the control group for the 338 ppm group, and the 1,125 ppm group was similar to the control group. The absolute epididymal weights for the 338 ppm group were significantly decreased by 6% (left only) and by 12%–14% for the 1,125 ppm group, compared to the control group. Relative left epididymal weights were significantly decreased compared to the control group for the 1,125 ppm group, and there was a negative trend in relative right epididymal weights with exposure concentration. The minimal decreases in testis and epididymal weights (and lack of changes in testis spermatid head concentration and cauda epididymal sperm concentrations) suggest that there was not a strong effect of BPAF on either tissue.

#### Female Necropsies

In females, there were BPAF-related significant decreases of terminal body weight (9% and 16% for the 338 and 1,125 ppm groups, respectively) and ovarian weights for the 338 and 1,125 ppm groups relative to the control group (Table 51).

Table 51 Summary of Organ Weights from F_2_ Female Rats Following Perinatal Exposure to Bisphenol AF^a,b^

| 0 ppm | 338 ppm | 1,125 ppm | 3,750 ppm
No. Examined^c^ | 78 (18) | 77 (19) | 20 (7) | –^d^
Necropsy Body Wt. (g) | 243.5 ± 4.3** | 221.0 ± 3.8** | 204.9 ± 6.4** | –
Right Ovary
Absolute (g) | 0.0680 ± 0.0023** | 0.0564 ± 0.0019** | 0.0458 ± 0.0013** | –
Relative (mg/g) | 0.28 ± 0.01* | 0.26 ± 0.01 | 0.23 ± 0.01* | –
Left Ovary
Absolute (g) | 0.0683 ± 0.0024** | 0.0561 ± 0.0022** | 0.0470 ± 0.0019** | –
Relative (mg/g) | 0.28 ± 0.01** | 0.25 ± 0.01 | 0.23 ± 0.01* | –

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are displayed as mean ± standard error of the litter means.

^b^ Statistical analysis performed using mixed models with a random effect for litter for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^c^ No. Examined = the number of pups examined (number of litters).

^d^ No females were confirmed pregnant for the 3,750 ppm group.

^e^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

Absolute ovarian weights were significantly decreased compared with the control group by 17%–18% and 31%–33% for the 338 and 1,125 ppm groups, respectively (Table 51). Relative ovarian weights were significantly decreased for the 1,125 ppm group. The magnitude of the reduction in weights of the ovaries in the 1,125 ppm group was more than the magnitude of the reduction in body weight, suggesting a direct BPAF-mediated suppression of maturation of this tissue. However, there were no gross findings for the ovaries, and histopathology was not evaluated for the F_2_ females.

## Genetic Toxicology

BPAF was not mutagenic in Salmonella typhimurium strains TA98 and TA100 or in Escherichia coli strain WP2 uvrA (pKM101) in tests conducted with and without induced male Sprague Dawley rat liver S9 mix. In all three strains, the highest dose was limited by cytotoxicity. However, BPAF was markedly more cytotoxic to the two S. typhimurium strains than to the E. coli strain (Table D-1).

BPAF was also evaluated using the in vivo peripheral blood micronucleus assay to assess its ability to induce chromosomal damage in the form of structural or numerical alterations. No significant increases in the frequencies of micronucleated immature erythrocytes (PCEs) were observed in male or female rats administered BPAF (338–3,750 ppm) for 17 weeks in dosed feed, and no significant changes in % PCE were observed, suggesting that BPAF exposure did not affect erythropoiesis (Table D-2).