# Materials and Methods

## Overview of Pre- and Postnatal Dose Range-finding and Modified One-Generation Study Designs

Modified one-generation (MOG) studies are composed of two interrelated parts: (1) a dose range-finding study (Figure 3) and (2) a MOG study (Table 1; Figure 4). If the acceptable range of exposure concentrations required to avoid excessive general and perinatal toxicity is unknown, a pre- and postnatal dose range-finding study is conducted. Nulliparous females are mated at the animal vendor and sent to the testing laboratory. Dosing typically begins at implantation (gestation day [GD] 6) and continues through weaning on lactation day (LD) 28. Offspring are exposed in utero, during lactation, and through consumption of dosed feed.

Figure 3

Design of a Dose Range-finding Study

F_0_ dams are exposed to the test article from gestation day (GD) 6 through weaning on lactation day (LD) 28 and evaluated for maternal toxicity. F_1_ offspring are exposed in utero through postnatal day (PND) 28 and evaluated for signs of in utero and postnatal toxicity.

Table 1 Key Modified One-Generation Study Design Endpoints

Cohort | Key Endpoints
F_0_ Dams | Maternal toxicity endpoints (body weight, feed consumption, clinical observations)
F_1_ Generation^a^ | Clinical observations
| Body weights
| Feed consumption
| Necropsy
| Pup survival
| Anogenital distance, nipple/areola retention, testis descent, vaginal cytology
Reproductive Performance Cohort | F_1_ reproductive performance
| F_1_ andrology and sperm parameters
| F_1_ histopathology
| F_2_ litter size, viability, and growth
| F_2_ necropsy
Prenatal Cohort | F_1_ reproductive performance
| F_2_ fetal external, visceral, skeletal, and head soft tissue examinations
| F_2_ necropsy
Subchronic Cohort | F_1_ hematology
| F_1_ clinical chemistry
| F_1_ histopathology

^a^ Additional cohorts (e.g., biological sampling cohort) and associated endpoints may be included in the study design.

Figure 4

Design of a Modified One-Generation Rat Study

F_0_ dams are exposed to the test article from gestation day (GD) 6 through weaning on lactation day (LD) 28 and evaluated for maternal toxicity. F_1_ offspring are exposed in utero and during lactation through postnatal day (PND) 28 and evaluated for signs of toxicity. After weaning, F_1_ offspring are allocated into cohorts for prenatal, reproductive performance, or additional assessments (e.g., subchronic or biological sampling cohorts) and exposure to test article continues until necropsy. F_2_ offspring are exposed in utero and during lactation and postweaning until necropsy (reproductive performance cohort).

In MOG studies, time-mated females are administered the test article from GD 6 through weaning (evidence of mating = GD 0). The subsequent F_1_ litters are standardized to a specified litter size (n = 8 or 10), with equal representation of both sexes. These offspring are continuously exposed to the test article via the same route of exposure and dose concentration as their dams. Multiple endpoints indicative of potential endocrine alteration (e.g., anogenital distance [AGD], nipple retention in males, pubertal markers) are measured (Table 1). Randomly selected F_1_ animals are taken to adulthood for gross and histopathological examinations and can be allocated at weaning (postnatal day [PND] 28) to various cohorts. Histopathological examination of multiple animals per litter increases the power of statistical tests to detect adverse effects.^41^

The ability of F_1_ animals to mate and produce viable offspring is evaluated in the reproductive performance cohort. The potential for the test article to induce fetal defects is assessed in the prenatal cohort: F_2_ fetuses are examined on GD 21, which includes examination of external morphology, fetal viscera, head (soft tissue and skeletal components), and skeleton (osseous and cartilaginous defects). Abnormalities are categorized as either malformations, which are permanent structural changes that could adversely affect survival, development, or function; or variations, which are a divergence beyond the usual range of structural constitution that might not adversely affect survival or health,^42^ consistent with descriptions by Makris et al.^43^ Endpoints common to most cohorts are described in Table 1.

Subchronic toxicity, including effects on clinical chemistry and hematology, are assessed in a 3-month cohort. Other cohorts can also be added (e.g., for internal dose estimation, neurobehavioral, toxicokinetic, and/or immunotoxicity assessments) to identify potential hazards across multiple functional outcomes. If necessary, more than one animal per sex can be selected from each litter and assigned to a cohort (e.g., reproductive performance). Examining multiple animals per litter increases the likelihood of detecting adverse responses and collectively makes the most use of the animals produced.

In the studies reported here, F_0_ females were administered the test article in feed beginning on GD 6. F_1_ and F_2_ offspring were exposed in utero, during lactation, and through consumption of dosed feed.

## Procurement and Characterization

BPAF was obtained from 3B Pharmachem International Co., Ltd (Wuhan, China) in a single lot (20100425) that was used in the dose range-finding and MOG studies. The bulk chemical of BPAF lot 20100425 was received in two batches, which were screened for identification and purity to ensure acceptable quality. Subsequently, the two batches were combined and homogenized by mixing for 5 minutes. The final batch was transferred to 80-oz amber glass bottles sealed with Teflon-lined lids and stored at ambient conditions. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at MRIGlobal (Kansas City, MO) (Appendix A). Reports on analyses performed in support of the BPAF studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

Lot 20100425 of the chemical, a white powder, was identified as BPAF by infrared (IR), ^1^H and ^13^C nuclear magnetic resonance (NMR), and ultraviolet/visible (UV/Vis) spectroscopies. The IR, ^1^H, and ^13^C NMR spectra, and UV/Vis spectra (Appendix A) were consistent with reference spectra and the anticipated structure of BPAF. Direct infusion mass spectrometry (DIMS) confirmed the molecular weight. The melting point, octanol/water partition coefficient (K_OW_), and elemental analysis of lot 20100425 matched BPAF.

The purity of lot 20100425 was determined using high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection and differential scanning calorimetry (DSC). Headspace gas chromatography (GC/headspace) was performed to determine residual solvent content (Table A-1). Karl Fisher titration was conducted to estimate moisture content.

Purity assessment by HPLC/UV found one major peak accounting for 99.86% and one minor peak accounting for 0.13% of the total integrated area. Purity by DSC was 100%. No significant residual solvent impurities were found. Karl Fisher titration indicated a water content of 0.026%. The bulk purity of lot 20100425 was determined to be >99.5%.

Accelerated stability studies confirmed that lot 20100425 was stable for at least 2 weeks when stored in sealed glass vials at temperatures from −20°C to 60°C. Periodic reanalyses of the bulk chemical performed by the study laboratory using HPLC/UV showed no degradation.

## Preparation and Analysis of Dose Formulations

Dose formulations of BPAF in LabDiet 5K96 Verified Casein Diet feed were prepared approximately monthly following the protocols outlined in Table A-2. Dose formulations of 0, 937.5, 1,875, 3,750, 7,500, and 15,000 ppm were used for the dose range-finding study, and dose formulations of 0, 338, 1,125, and 3,750 ppm were used for the MOG study. Formulations were stored in sealed plastic bag-lined containers for up to 42 days at 5°C.

The method of preparation was validated for concentration ranges of approximately 200–10,000 ppm. High-dose method verification confirmed that formulations up to approximately 45,000 ppm could be diluted into the validated calibration curve range. The optimal extraction solvent was determined to be acidified acetonitrile (99:1, acetonitrile:acetic acid, v:v).

Prior to study start, the stability and homogeneity of the formulations were determined using HPLC/UV. Stability of the 250 and 937.5 ppm formulations was confirmed for up to 42 days under refrigerated or freezer conditions while protected from light. A 7-day simulated dose study of the 250 and 937.5 ppm formulations was conducted to determine stability in animal room conditions. Formulations in the absence and presence of rodent urine and feces under dosing conditions were stable for up to 7 days. A decrease in recovery of BPAF was observed under simulated animal room conditions when the formulation was mixed with excreta, with recovery of BPAF reduced to approximately 77% by day 7, when compared to the day 0 determined concentration. However, when samples from the 7-day simulated dose study of the 937.5 ppm formulation spiked with rodent urine and feces were analyzed using an acid-digestion method, recovery increased to 90.8% on day 7. These results indicate extensive reversible binding of BPAF to feed in the presence of rodent urine and feces and not chemical instability when mixed with feed. Homogeneity of the dose formulations was confirmed at 250, 937.5, and 15,000 ppm in 22-kg preparations of dose formulations and at 338 and 3,750 ppm in 37-, 50-, and 100-kg preparations.

Analyses of pre- and postadministration dose formulations were conducted throughout the study using HPLC/UV to determine purity (Table A-3, Table A-4). All preadministration samples were within 10% of the target concentrations. Postadministration samples were collected from the animal room at the end of the exposure period. For the dose range-finding study, postadministration samples were within 30% of the target concentrations and within 28% of the preadministration concentrations. For the MOG study, postadministration samples were within 22% of the target concentrations and within 20% of the preadministration concentrations. Excreta contained in the samples might have affected BPAF recovery of the dose formulations as the results mimic findings from the 7-day simulated dose study. The concentration values for the postadministration samples were considered to have demonstrated acceptable stability.

## Animal Source

Female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were obtained from Envigo (formerly Harlan Laboratories, Inc., Dublin, VA) for use in the dose range-finding and MOG studies. Sexually mature (11 to 12 weeks old) females were time-mated overnight at the vendor and were received on GD 1 or 2 for both the dose range-finding and MOG studies. GD 0 was defined as the day positive evidence of mating was observed.

## Animal Health Surveillance

In accordance with the National Toxicology Program (NTP) Sentinel Animal Program (Appendix C), 10 female sentinel animals were evaluated in the dose range-finding study. Twenty female sentinel animals, as well as 15 F_1_ male sentinel animals that were reassigned from the control group at weaning, were evaluated in the main study. All test results were negative.

## Animal Welfare

Animal care and use were in accordance with the Public Health Service Policy on Humane Care and Use of Laboratory Animals. All animal studies were conducted in a facility accredited by AAALAC International. Studies were approved by the RTI International Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Experimental Design

### Dose Range-finding Study

Time-mated female rats were received on GDs 1 or 2, randomized based on GD 3 body weight, and placed on a 5K96 Casein diet containing 0, 937.5, 1,875, 3,750, 7,500, or 15,000 ppm BPAF from GD 6 through LD 28. Feed and water were available ad libitum. Information on feed composition and contaminants is provided in Appendix B. Dose selection was based on results of previously conducted studies in which BPAF was orally administered to rats.^28^ No mortality was observed in rats administered up to 600 mg BPAF/kg body weight/day (mg/kg/day) by oral gavage for 3 days; therefore, a feed concentration of 15,000 ppm BPAF, estimated to be equivalent to a dose of 1,000 mg/kg/day, was chosen as the maximum exposure concentration for the dose range-finding study.

Fifteen time-mated female rats were allocated to each exposure group. Viability, clinical observations, body weights, pup counts (litters were not standardized), and feed consumption were recorded to help determine the maximum exposure concentration that could be tolerated by the dams while not affecting the number of pups, so the MOG study could be populated with a sufficient number of offspring. Maternal plasma, amniotic fluid, and fetuses were collected from three dams per group on GD 18 for bioanalytical method development. On LD 4, maternal plasma was collected from dams with whole litter loss from the 1,875 ppm (two dams) and 3,750 ppm (one dam) groups. On PND 4, pup carcasses with heads were collected from the 0 (six pups), 1,875 (six pups), and 3,750 ppm (six pups) groups. On LD 28, maternal plasma was collected from three dams per group, and pup plasma was collected from three pups/sex/litter. Selected samples were analyzed for free (parent) and total (combined parent and conjugated forms) BPAF to determine the extent of maternal transfer and the internal dose to inform design of the MOG study. The corresponding data are reported elsewhere.^44^

All other dams and pups were euthanized on LD 28 without further examination. Females that did not litter were euthanized approximately 3 days after expected littering, received a gross necropsy, and had their pregnancy status determined. If present, the numbers of implantation sites and ovarian corpora lutea were recorded. F_1_ pups that were removed for health reasons or had died, and all females euthanized early in the 15,000 ppm group received a gross necropsy. Further details of animal maintenance and study design are given in Table 2.

Table 2 Experimental Design and Materials and Methods in the Dose Range-finding and Modified One-Generation Studies of Bisphenol AF (Preweaning)

Dose Range-finding Study | Modified One-Generation Study
Study Laboratory
RTI International (Research Triangle Park, NC) | Same as dose range-finding study
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats | Same as dose range-finding study
Animal Source
Envigo (formerly Harlan Laboratories, Inc., Dublin, VA) | Same as dose range-finding study
Day of Arrival
November 27, 2012 (GD 1 or GD 2) | May 7 or 9, 2013 (GD 1 or GD 2)
Average Age on Arrival
11–12 weeks | Same as dose range-finding study
Weight Range at Randomization
186.7–255.3 g on GD 3 | 187.5–260.7 g on GD 3
Date of First Exposure
GD 6 (December 1, 2012) | F_0_ females: GD 6 (May 11–14, 2013)
| F_1_ rats (all cohorts): lifetime exposure
| F_2_ rats: lifetime exposure
Duration of Exposure
GD 6 through LD 28 | F_0_ females: GD 6 through LD 28
| F_1_ rats (biosampling cohort): lifetime exposure through PND 28 (males and females) or until day of vaginal opening (females)
| F_1_ rats (subchronic cohort): lifetime exposure through PND 115–119 (males) or through PND 116–120 (females)
| F_1_ rats (prenatal cohort): lifetime exposure through PND 119–121 (males) or through PND 123–137 (females)
| F_1_ rats (reproductive performance cohort): lifetime exposure through PND 152–154 (males) or through PND 158–175 (females)
| F_2_ rats (reproductive performance cohort): in utero through PND 91–93
Date of Last Exposure
LD 28 (January 16, 2013) | F_0_ females: LD 28 (June 24–28, 2013)
| F_1_ rats (biosampling cohort): PND 28 (June 24–27, 2013) or day of vaginal opening (June 24–July 7, 2013)
| F_1_ rats (subchronic cohort): PND 115–119 (through September 23, 2013) (males) or PND 116–120 (through September 24, 2013) (females)
| F_1_ rats (prenatal cohort): PND 119–121 (through September 25–27, 2013) (males) or PND 123–137 (through September 30–October 13, 2013) (females)
| F_1_ rats (reproductive performance cohort): PND 152–154 (October 28–30, 2013) (males) or PND 158–175 (November 5–19, 2013) (females)
| F_2_ rats (reproductive performance cohort): PND 91–93 (through January 7–21, 2014)
Necropsy Dates
Gross necropsies were conducted on F_0_ females euthanized early in the 15,000 ppm group, F_0_ females that did not deliver a litter, and F_1_ offspring euthanized moribund or found dead. | F_0_ females: LD 28 (June 24–28, 2013)
Gross necropsies were conducted on F_0_ females euthanized early in the 15,000 ppm group, F_0_ females that did not deliver a litter, and F_1_ offspring euthanized moribund or found dead. | F_1_ rats (biosampling cohort): June 24–27, 2013 (males and females) or June 24–July 7, 2013 (females on day of vaginal opening)
| F_1_ rats (subchronic cohort): September 23–24, 2013
| F_1_ rats (prenatal cohort): September 25–27, 2013 (males) or September 30–October 13, 2013 (females)
| F_1_ rats (reproductive performance cohort): October 28–30, 2013 (males) or November 5–19, 2013 (females)
| F_2_ rats (reproductive performance cohort): January 7–21, 2014
Average Age at Necropsy
Not performed | F_0_ females: ~19 weeks
| F_1_ rats (biosampling cohort): 28 days (males and females), or 26–39 days (females on day of vaginal opening)
| F_1_ rats (subchronic cohort): 115–119 days (males) or 116–120 days (females)
| F_1_ rats (prenatal cohort): 119–121 days (males) or 123–137 days (females)
| F_1_ rats (reproductive performance cohort): 152–154 days (males) or 158–175 days (females)
| F_2_ rats (reproductive performance cohort): 91–93 days (males and females)
Size of F_0_ Study Groups
15 time-mated females | 35 time-mated females
Method of Randomization and Identification
Time-mated animals were individually identified by an implanted micro transponder (Bio Medic Data Systems, Seaford, DE) and assigned to exposure group by stratified randomization of GD 3 body weights using Provantis^®^ (Instem, Stone, United Kingdom) electronic data collection system. | Same as dose range-finding study, except F_1_ and F_2_ pups were identified by paw tattoo, and postweaning F_1_ males and F_1_ females were identified by an implanted micro transponder.
Animals per Cage
1 (with litter) | F_0_ females: 1 (with litter)
| F_1_ rats (biosampling cohort): ≤3 (males or females) until termination
| F_1_ rats (subchronic cohort): ≤3 (males or females) until termination
| F_1_ rats (prenatal cohort): ≤3 (males or females) until PND 98, then housed individually except during cohabitation
| F_1_ rats (reproductive performance cohort): ≤3 (males or females) until PND 98, then housed individually except during cohabitation or when housed with their litters
| F_2_ rats (reproductive performance cohort): ≤3 (males or females) until PND 91–93
Diet
Irradiated certified Advanced Protocol Verified Casein Diet 1 IF 5K96 (PMI Nutrition International, Richmond, IN), available ad libitum | Same as dose range-finding study
Water
Tap water (Durham, NC) via automatic watering system (Avidity Science, formerly Edstrom Industries, Inc., Waterford, WI), available ad libitum | Same as dose range-finding study
Cages
Solid-bottom polycarbonate cages (Lab Products, Inc., Seaford, DE), rotated biweekly and changed at least once per week | Solid-bottom polycarbonate cages (Lab Products, Inc., Seaford, DE), rotated biweekly and changed at least once per week (individually housed animals) or twice per week (group-housed animals and females with litters)
Bedding
Certified irradiated Sani-Chips^®^ hardwood cage bedding (P.J. Murphy Forest Products Corp., Montville, NJ), changed weekly | Certified irradiated Sani-Chips^®^ hardwood cage bedding (P.J. Murphy Forest Products Corp., Montville, NJ), changed weekly (individually housed animals) or twice per week (group-housed animals and females with litters)
Cage Filters
Filter paper (Granville Milling Co., Creedmoor, NC), changed biweekly | Same as dose range-finding study
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed and rotated every 2 weeks during the study | Same as dose range-finding study
Animal Room Environment
Temperature: 71.8°F ± 1.5°F Relative humidity: 52.6% ± 7.5% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Temperature: 72°F ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour
Exposure Concentrations
0, 937.5, 1,875, 3,750, 7,500, or 15,000 ppm BPAF in feed, available ad libitum | 0, 338, 1,125, or 3,750 ppm BPAF in feed, available ad libitum
Type and Frequency of Observation of F_0_ and F_1_ Dams
Viability was assessed at least twice daily, and clinical observations were recorded at least once daily. Female body weights were recorded daily during gestation (GD 3–21) and during lactation on LDs 1, 4, 7, 11, 14, 18, 21, 25, and 28. Feed consumption was recorded at 3-day intervals from GD 3 through GD 21 and for LDs 1–4, 4–7, 7–11, 11–14, 14–18, 18–21, 21–25, and 25–28. | Viability was assessed at least twice daily, and clinical observations were recorded at least once daily. Female body weights were recorded daily during gestation (GD 3–21) and during lactation on LDs 1, 4, 7, 10, 13, 16, 19, 21, 25, and 28. Feed consumption was recorded at 3-day intervals from GD 3 through GD 21 and for LDs 1–4, 4–7, 7–10, 10–13, 13–16, 16–19, 19–21, 21–25, and 25–28.
Type and Frequency of Observation of F_1_ and F_2_ Pups
Viability was assessed at least twice daily, and clinical observations were recorded at least once daily. The number of live and dead pups in each litter was counted daily. Individual pups were sexed and weighed on PNDs 1, 4, 7, 14, 21, 24, 25, and 28. Litters were not standardized on PND 4, and all offspring (unless euthanized and biological samples collected for subsequent analytical method development) were retained until PND 28 to assess litter size, sex distribution, pup body weights, and survival during lactation. | Viability was assessed at least twice daily, and clinical observations were recorded at least once daily. The number of live and dead pups in each litter was counted daily. Individual pups were sexed and weighed on PNDs 1, 4, 7, 10, 13, 16, 19, 21, 25, and 28. F_1_ and F_2_ litters were standardized to a litter size of 10 (5/sex/litter, when possible) and 8 pups (4/sex/litter, when possible), respectively, on PND 4. Endocrine F_1_/F_2_ endpoints: AGD and corresponding pup weight on PND 1; areolae/nipple retention on PND 13; testicular descent beginning on PND 14
Primary Method of Euthanasia
100% carbon dioxide (F_0_ females and PND 28 pups); decapitation (GD 18 fetuses; PND 4 pups) | 100% carbon dioxide (adults and PND 28 pups); decapitation or administration of a solution containing sodium pentobarbital (PND 4 pups)
Necropsy and Postmortem Evaluation
F_0_ dams and their pups were euthanized on LD 28 without necropsy. Females that did not litter were euthanized ~3 days after expected littering, received a gross necropsy, and had their pregnancy status determined. If present, the numbers of implantation sites and ovarian corpora lutea were recorded. F_1_ pups that were removed for health reasons or had died and all F_0_ females euthanized early in the 15,000 ppm group received a gross necropsy. | F_0_ dams were euthanized on LD 28, received a gross necropsy, and had their number of implantation sites and corpora lutea recorded. Females that did not litter were euthanized 3 days after expected littering, received a gross necropsy, and had their pregnancy status determined. If present, the number of implantation sites and corpora lutea was recorded. Histopathological analysis of gross lesions was performed, if collected.
Internal Dose Assessment
On GD 18, maternal plasma, amniotic fluid, and fetuses were collected from three pregnant dams/group. On LD 4, maternal plasma was collected from dams with whole litter loss from the 1,875 ppm (two dams) and 3,750 ppm (one dam) groups. On PND 4, pup carcasses with heads were collected from the 0 (six pups), 1,875 (six pups), and 3,750 ppm (six pups) groups. On LD 28, maternal plasma was collected from three dams/group, and pup plasma was collected from 3 pups/sex/litter. Selected samples were analyzed for free (parent) and total (combined parent and conjugated forms) BPAF to determine the extent of maternal transfer and to inform the design of the MOG study. The corresponding data are not reported. | On GD 18, maternal plasma, amniotic fluid, and fetuses were collected from three pregnant dams per group. On LD 4, maternal plasma was collected from three dams with litters from the 338 and 1,125 ppm groups. Pup plasma was collected on PND 4 from 9 pups/sex/group (from at least 3 litters/group). On LD 28, maternal plasma was collected from 3 dams/group, and pup plasma was collected from 3 pups/sex/group. Samples were analyzed for free (parent) and total (combined parent and conjugated forms) BPAF using a validated analytical method and results were published elsewhere.^44^

GD = gestation day; LD = lactation day; PND = postnatal day; BPAF = bisphenol AF; AGD = anogenital distance; MOG = modified one-generation.

### Modified One-Generation Study with Prenatal, Reproductive Performance, and Subchronic Cohorts

Time-mated F_0_ female rats, 35 per group, were received on GDs 1 or 2, randomized based on GD 3 body weight, and placed on a 5K96 Casein diet containing 0, 338, 1,125, or 3,750 ppm BPAF ad libitum on GD 6. The exposure concentration of 3,750 ppm was expected to result in minimal maternal toxicity and to ensure that the model system was appropriately challenged, increasing the likelihood of identifying any toxicological signal in the offspring. The F_1_ and F_2_ generations were exposed to BPAF via the dam during gestation and lactation, and directly via 5K96 feed at the same exposure concentration as their respective dams. Viability, clinical observations, body weights, pup counts, and feed consumption were recorded. F_1_ and F_2_ litters were standardized to ten pups (5/sex/litter, when possible) and eight pups (4/sex/litter, when possible), respectively, on PND 4. At weaning on PND 28, F_1_ offspring were randomly assigned to reproductive performance (1/sex/litter), prenatal development (1/sex/litter), subchronic (1/sex/litter from 10 litters), or biological sample collection (6/sex for sample collection on PND 28 to determine internal dose and up to 12 females for sample collection at vaginal opening [VO]) cohorts. In addition, 15 F_1_ control males were reassigned as sentinels. F_1_ animals that were not assigned to a cohort were considered extra animals and were euthanized on PND 28. The F_2_ offspring were carried out to 91 days to allow for comparisons of similar parameters between the F_1_ and F_2_ generations. Information on feed composition and contaminants is provided in Appendix B. Additional details of animal maintenance and study design are given in Table 2 and Table 3.

Table 3 Experimental Design and Materials and Methods in the Modified One-Generation Study of Bisphenol AF (Postweaning)

Modified One-Generation Study
F_1_ Postweaning Assessments
All Cohorts: Viability was assessed at least twice daily, and clinical observations recorded at least once daily. F_1_ male body weights and feed consumption were recorded once weekly. F_1_ female body weights and feed consumption were recorded at least once weekly during the premating interval. Vaginal opening (and concomitant body weight) was evaluated beginning on PND 20, balanopreputial separation (and concomitant body weight) was evaluated beginning on PND 35.
Prenatal and Reproductive Performance Cohorts: After collection of vaginal lavage samples for 16 days, F_1_ nonsibling mating pairs (one male and one female per litter) from the same exposure group were cohabitated until evidence of mating or for ≤15 days. F_1_ dams were observed for the same gestational endpoints as the F_0_ dams.
Prenatal Cohort: F_1_ dams were evaluated at GD 21 necropsy, and F_2_ fetuses were assessed for external, visceral, and skeletal variations and malformations.
Reproductive Performance Cohort: F_1_ dams and F_2_ pups were evaluated for the same lactational endpoints as the F_0_ dams and F_1_ pups.
F_1_ Necropsy and Postmortem Evaluation
Prenatal Cohort: F_1_ dams were euthanized on GD 21. Necropsies were performed on all females. Terminal body weights and ovary (left and right) and gravid uterus weights were recorded. The number of corpora lutea on each ovary was recorded. The number and location of all fetuses and resorptions (early or late) and the total number of implantation sites were recorded. If there was no macroscopic evidence of pregnancy, the uterus was stained to visualize potential evidence of implantation sites. Live fetuses were counted, sexed, weighed, and examined for external morphological abnormalities, including examination of the oral cavity for cleft palate. Gross placental morphology was also evaluated. Live fetuses were euthanized and then examined for visceral morphological abnormalities by fresh dissection. The sex of each fetus was confirmed by internal examination. The heads from approximately one-half of the fetuses in each litter were fixed, sectioned, and examined. All fetuses were eviscerated, fixed, stained, and examined for skeletal developmental variations, malformations, or other morphological findings. After positive evidence of mating, male sires were weighed, euthanized, and necropsied, and the following organ weights recorded: Cowper’s glands (paired), epididymis (left and right), LABC muscle, preputial glands (paired), dorsolateral and ventral prostate gland, seminal vesicles with coagulating glands, and testis (left and right). Histopathology of gross lesions was assessed.
Reproductive Performance Cohort: F_1_ dams were euthanized on LD 28, and sires were euthanized after assessment of fertility, fecundity, and F_2_ generation pup survival. Terminal body weights and the following organ weights were recorded for the F_1_ and F_2_ males and females: Cowper’s glands (paired), epididymis (left and right), LABC muscle, ovary (left and right), preputial glands (paired), dorsolateral and ventral prostate gland, seminal vesicles with coagulating glands, and testis (left and right). Histopathology was performed on the following organs for F_1_ males and/or females: Cowper’s glands, epididymis, LABC muscle, ovaries, pituitary gland, preputial glands, dorsolateral and ventral prostate gland, seminal vesicles with coagulating glands, testis, uterus (with cervix and vagina), and gross lesions. Cauda epididymal sperm motility, cauda epididymal sperm concentration, and testicular sperm head counts were also assessed for all F_1_ and F_2_ males. For the F_2_ generation, organ weights were collected for the same organs as for the F_1_ necropsy, with the brain also weighed. The same reproductive tissues were fixed, but histopathology was not evaluated for any tissues or gross lesions.
Biological Sampling Cohort: Rats were randomly allocated for collection of biological samples. On PND 28, plasma was collected from 6 weanlings/sex/group. At the time of vaginal opening, serum, ovaries (paired), and brains were collected from up to 12 females/group and frozen for potential future analyses. Results of the plasma analyses have been reported previously.^44^ Rats were subjected to a gross necropsy, and histopathology was performed on gross lesions.
Subchronic Cohort: F_1_ males and females were euthanized on PND 115–119 and PND 116–120, respectively. Blood was collected by cardiac puncture and processed for hematology and clinical chemistry analyses. Additional blood samples were also collected for micronucleus determination. The following hematology parameters were analyzed: erythrocyte count, hemoglobin concentration, hematocrit, mean corpuscular volume, mean corpuscular hemoglobin, mean corpuscular hemoglobin concentration, leukocyte count, leukocyte differential, reticulocyte count, and platelet count. The following clinical chemistry parameters were analyzed: total protein, albumin, urea nitrogen, creatinine, alanine aminotransferase, sorbitol dehydrogenase, alkaline phosphatase, bile acids, glucose, creatine kinase, cholesterol, and triglycerides. The following organ weights were recorded: adrenal glands (paired), epididymis (right and left), heart, kidney (right and left), liver, lungs, ovary (left and right), dorsolateral and ventral prostate gland, seminal vesicles with coagulating glands, testis (right and left), thymus, thyroid (fixed), and uterus with cervix and vagina. In addition to gross lesions, histopathology was performed on the following organs: adrenal glands (paired), bone with marrow, brain, cervix, clitoral glands, epididymides (paired), esophagus, eyes, Harderian glands, heart and aorta, kidneys (paired), large intestine (cecum, colon, and rectum), liver, lungs, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovaries (paired), pancreas, parathyroid glands, pituitary gland, preputial glands, prostate gland, salivary glands, seminal vesicles with coagulating gland, small intestine (duodenum, jejunum, and ileum), spleen, stomach (forestomach and glandular), testes (paired), thymus, thyroid gland, trachea, urinary bladder, uterus, vagina, and Zymbal’s glands.

PND = postnatal day; GD = gestation day; LABC = levator ani/bulbocavernosus; LD = lactation day.

#### Endocrine-sensitive and Pubertal Endpoints

AGD and corresponding body weight (for covariate analyses) were recorded for each F_1_ and F_2_ pup on PND 1. AGD was measured using a stereomicroscope with a calibrated ocular reticle. The distance between the midpoint of the anal opening to the caudal edge of the genital papilla was recorded and converted to millimeters (mm). F_1_ and F_2_ male pups were evaluated for retention of areolae/nipples on PND 13 and observed for testicular descent over 28 days, beginning on PND 14. Acquisition of balanopreputial separation (BPS), defined as complete retraction of the prepuce from the glans penis, was evaluated in all F_1_ and F_2_ males over 98 (F_1_) or 75 (F_2_) days, beginning on PND 35, and body weight was recorded upon BPS acquisition. External genitalia were examined for malformations and undescended testes (cryptorchidism). The acquisition of VO was evaluated in F_1_ and F_2_ females beginning on PND 23–24 until PND 39–41, and the corresponding body weight recorded upon VO acquisition.

#### Vaginal Cytology

Beginning on PND 82 (approximately 16 days before mating) and PND 75 for F_1_ and F_2_ females, respectively, vaginal lavages were collected from the F_1_ females (in the prenatal, reproductive performance, and subchronic cohorts) and from F_2_ females (in the reproductive performance cohort) for 16 consecutive days for evaluation of estrous cyclicity. Vaginal vaults were moistened with saline, if necessary, and samples of vaginal fluid and cells were spotted onto a slide and subsequently stained with toluidine blue. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (diestrus, proestrus, estrus, and metestrus).^45^

#### F_1_ Cohabitation and Assessment of Mating

Sexually mature F_1_ animals in the prenatal (14–17 weeks; one male and one female per litter) and reproductive performance (13–18 weeks; one male and one female per litter) cohorts were randomly assigned a mating partner, avoiding sibling pairings, and paired in a 1:1 ratio for up to 15 days. Mating was confirmed by daily examination for the presence of a vaginal copulation plug or sperm in a vaginal lavage. The day of confirmed mating was considered GD 0. Females in the prenatal cohort that did not exhibit evidence of mating were euthanized with 100% carbon dioxide and necropsied at the end of cohabitation. Females in the reproductive performance cohort that did not exhibit evidence of mating, did not deliver a litter, or with whole litter loss were euthanized with 100% carbon dioxide and necropsied when F_2_ pups reached PND 28. The uterus of apparently nonpregnant females was examined grossly and stained with ammonium sulfide to identify potential implantation sites. The number of corpora lutea on the ovary were enumerated, and gross lesions were examined for histopathological changes.

#### Prenatal Cohort

On GD 21, pregnant F_1_ females were euthanized with 100% carbon dioxide and F_2_ fetuses were removed from the uterus, individually weighed (live fetuses only), and examined externally for alterations, including inspection of the oral cavity for cleft palate. Gross placental morphology was also evaluated. Live fetuses were subsequently euthanized by oral administration of sodium pentobarbital. F_1_ females with no evidence of mating were euthanized with 100% carbon dioxide and necropsied and examined for gross lesions, which were retained and examined histologically. Fetal sex was confirmed by inspection of gonads in situ. All F_2_ fetuses in each litter were examined for soft tissue alterations under a stereomicroscope.^46; 47^ The heads were removed from approximately half of the fetuses in each litter, fixed in Bouin’s solution, and subsequently examined by freehand sectioning.^48^ This technique precludes skeletal evaluations of the skull; therefore, remaining heads and all fetuses were eviscerated, fixed in ethanol, macerated in potassium hydroxide, stained with Alcian blue and Alizarin red, and examined for subsequent cartilage and osseous alterations.^49; 50^ External, visceral, and skeletal fetal findings were recorded as developmental variations or malformations. At the end of cohabitation, male sires were necropsied, selected organs were weighed, and gross lesions were collected for potential histological examination. In addition, due to clotting of some of the blood samples collected from males in the subchronic cohort at scheduled necropsy, blood samples from males in the prenatal cohort were collected at necropsy and used for micronucleus, hematology, and clinical chemistry evaluations.

#### Reproductive Performance Cohort

Fertility and fecundity were assessed in one male and one female representing each F_1_ litter and all exposure groups. Pup viability was assessed daily during lactation. F_2_ offspring were standardized to a litter size of eight pups (4/sex/litter, when possible) on PND 4. F_1_ males were euthanized with 100% carbon dioxide at approximately 22 weeks of age after assessment of fertility, fecundity, and F_2_ generation pup survival. The F_1_ females and the F_2_ offspring were euthanized with 100% carbon dioxide on PND 91–93, when the F_1_ females were 23–25 weeks of age. F_2_ offspring were carried out to PND 91–93 to determine whether any effects in the F_1_ generation would be replicated. F_2_ offspring were given a gross necropsy. F_1_ sires were necropsied after completion of littering for the F_2_ generation; selected organs were weighed, and gross lesions were collected for potential histological examination.

Immediately after euthanasia, the left testis and epididymis were removed, trimmed, and weighed. The cauda epididymis was then weighed, and samples were collected for determining cauda epididymal sperm motility, number, and density via automated sperm analyzer (Hamilton Thorne, Inc., Beverly, MA). The sampled left cauda epididymis and the intact corpus and caput were frozen at −80°C for subsequent determination of epididymal sperm concentration from the left cauda epididymis. The left testis was frozen at −80°C for subsequent determination of homogenization-resistant spermatid head counts for calculations of daily sperm production and efficiency of daily sperm production.^51^ The right testis and epididymis were examined histologically. Gross lesions took precedence over sperm parameter assessments (i.e., if the left testis was grossly abnormal, it and the left epididymis would be examined histologically, and the right testis and epididymis, if grossly normal, would be subjected to sperm assessments).

#### Subchronic Cohort

General toxicity was assessed in one male and one female representing 10 random litters (within an exposure concentration) and all exposure groups. F_1_ males and females were euthanized and necropsied on PND 115–119 and PND 116–120, respectively. The animals were anesthetized with carbon dioxide and euthanized by exsanguination. Blood was collected by cardiac puncture. Approximately 500 μL of whole blood was collected into a tripotassium ethylenediaminetetraacetic acid (K_3_ EDTA)-treated tube for hematology analyses. Up to 3 mL whole blood was collected into a serum separator tube for preparation of serum for clinical chemistry analyses. The samples for clinical pathology analyses were stored at 4°C until transferred to Antech^®^ GLP (Morrisville, NC) on the same day as necropsy for the clinical pathology analyses. The parameters measured are listed in Table 3.

In addition, approximately 200 μL of whole blood was collected into a K_3_ EDTA-treated tube for micronucleus determination. The micronucleus samples were stored at 4°C until transferred to the designated NTP laboratory (Integrated Laboratory Systems, LLC, Research Triangle Park, NC) on the same day as the necropsy.

#### Biological Sampling Cohort

On GD 18, maternal plasma, amniotic fluid, and fetuses were collected from three pregnant dams per group. On LD 4, maternal plasma was collected from three dams with litters from the 338 and 1,125 ppm groups. Pup plasma was collected on PND 4 from nine pups/sex/group (from at least three litters per group). On LD 28, maternal plasma was collected from three dams per group, and pup plasma was collected from three pups/sex/group. In addition, plasma was collected from six weanlings/sex/group on PND 28. Adult and PND 28 animals were euthanized with 100% carbon dioxide and PND 4 pups were decapitated or administered a solution containing sodium pentobarbital. Samples were analyzed for free (parent) and total (combined parent and conjugated forms) BPAF using a validated analytical method and published elsewhere.^44^ In addition, at the time of VO, serum and brains were collected from up to 12 females per group from this cohort and frozen for potential future analyses. Ovaries (paired) were also collected and sent for standard histopathology evaluation (Experimental Pathology Laboratories, Inc., Research Triangle Park, NC).

#### Necropsy and Histopathology

Complete necropsies were performed on adult F_1_ males and F_1_ females in the subchronic and reproductive performance cohorts, unscheduled deaths, F_0_ females, F_1_ males and F_1_ females in the prenatal cohort, F_1_ females in the reproductive performance cohort that either had no evidence of mating or did not produce a litter, and F_2_ offspring. All gross lesions were examined histologically. In addition, several protocol-required tissues were examined microscopically from the adult F_1_ males and females in the prenatal, reproductive performance, and subchronic cohorts. Tissues from the F_2_ animals in the reproductive performance cohort were collected and fixed but not evaluated. In the prenatal cohort, organ weights were recorded for the Cowper’s glands (paired), epididymis (left and right), levator ani/bulbocavernosus (LABC) muscle, ovary (left and right), preputial glands (paired), dorsolateral and ventral prostate gland, seminal vesicles with coagulating glands, and testis (left and right). In the reproductive performance cohort, organ weights were recorded for the Cowper’s glands (paired), epididymis (left and right), LABC muscle, ovary (left and right), preputial glands (paired), dorsolateral and ventral prostate gland, seminal vesicles with coagulating glands, testis (left and right), and brain (F_2_ only). In the subchronic cohort, organ weights were recorded for the adrenal glands (paired), epididymis (right and left), heart, kidney (right and left), liver, lungs, ovary (left and right), dorsolateral and ventral prostate gland, seminal vesicles with coagulating glands, testis (right and left), thymus, thyroid (fixed), and uterus with cervix and vagina.

The initial histological examination was performed on adult F_1_ males and F_1_ females in the subchronic and reproductive performance cohorts by an experienced, board-certified veterinary pathologist. The slides, individual animal data records, and pathology tables were subsequently evaluated by an independent quality assessment (QA) laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. A QA pathologist evaluated selected slides from the various cohorts. The testes, epididymides, dorsolateral and ventral prostate, seminal vesicle, penis, ovaries, and uterus were reviewed from all animals in the F_1_ reproductive performance and subchronic cohorts for which the tissue had been examined previously by the study laboratory pathologist. In addition, the LABC muscle, Cowper’s glands, coagulating gland, and vagina were examined in the F_1_ reproductive performance cohort, and the adrenal gland and kidneys were reviewed from all control and 3,750 ppm males and females in the F_1_ subchronic cohort.

The QA report and the reviewed slides were submitted to the NTP pathologist, who reviewed and addressed any inconsistencies in the diagnoses made by the laboratory and QA pathologist. The QA pathologist, who served as the coordinator of the Pathology Working Group (PWG) presented representative histopathology slides containing examples of lesions related to test agent administration, examples of disagreements in diagnoses between the laboratory and QA pathologist, or lesions of general interest to the PWG for review. The PWG consisted of the NTP pathologist and other pathologists experienced in rodent toxicological pathology. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, QA pathologist, and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^52^ and Boorman et al.^53^

## Statistical Methods

Statistical methods were chosen based on distributional assumptions as well as on the need to incorporate within-litter correlation among animals. Unless specifically mentioned, all endpoints were tested for a trend across exposure groups, followed by pairwise tests for each exposure group against the control group. Significance of all trend and pairwise tests is reported at both 0.05 and 0.01 levels.

### Analysis of Fetal Malformations and Variations

Incidences of malformations and variations in fetuses were summarized as number of litters affected and as number of fetuses affected. Trend and pairwise analyses of the fetal malformations and variations was conducted using a Cochran-Armitage test with a Rao-Scott adjustment, as described below.

The tendency of fetuses from the same litter to respond more similarly than fetuses from different litters has been referred to as the “litter effect”^54^ and reflects littermates’ similarities in genetics and in utero experiences. Failure to account for correlation within litters leads to underestimates of variance in statistical tests, resulting in higher probabilities of Type I errors (“false positives”). Therefore, the Cochran-Armitage trend test for incidence data was modified to accommodate litter effects using the Rao-Scott approach.^55^ The Rao-Scott approach accounts for litter effects by estimating the ratio of the variance in the presence of litter effects to the variance in the absence of litter effects. This ratio is then used to adjust the sample size downward to yield the estimated variance in the presence of litter effects. The Rao-Scott approach was implemented in the Cochran-Armitage test as recommended by Fung et al.,^56^ formula ₸_RS2_.

### Analysis of Incidences of Gross Pathology and Morphology Findings

For the F_0_ dams, incidences of gross findings and histopathology were summarized as number of animals affected. Because some of these animals did not survive until the removal day for their cohort, analysis of the histopathological findings was conducted using the Poly-3 test, as described below.

The Poly-k test^57-59^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage trend test to account for survival differences. Following Bailer and Portier,^57^ a value of k = 3 was used in the analysis of site-specific lesions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams.^60^ Poly-3 tests used the continuity correction described by Nam.^61^

For the F_1_ and F_2_ animals, incidences of gross findings and histopathology were summarized as number of litters affected and number of animals affected. To account for within-litter correlation, the Rao-Scott adjustment (as described earlier) was applied to the Cochran-Armitage test in the analysis of this data. For histopathology data in F_1_ cohorts in which survival issues may apply, the Poly-3 correction was also applied.

All p values calculated for gross pathological and histopathological data are one-sided and include a continuity correction.

### Analysis of Continuous Endpoints

Before statistical analysis, extreme values identified by the outlier test of Dixon and Massey^62^ for small samples (n < 20) and Tukey’s outer fences method^63^ for large samples (n ≥ 20) were examined by NTP personnel, and implausible values were eliminated from the analysis.

In some instances, no considerations for litter effects were necessary in the analysis of the continuous data. This was the case for the F_0_ generation and for the F_1_ prenatal cohort for which there was only one animal per litter. In these instances, organ and body weight measurements, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^64^ and Williams.^65; 66^

When litter effects were present, organ and body weight endpoints were analyzed using linear mixed models, with litters as a random effect. To adjust for multiple comparisons, a Dunnett-Hsu adjustment was used.^67^ Pup and fetal weights were adjusted for litter size (see below). AGD was adjusted for the body weight of the pup taken on the day of AGD measurement. The adjusted AGDs were analyzed as normal variates with litter effects using a linear mixed model.

Feed consumption, litter sizes, pup survival, implantations, number of resorptions, uterine content endpoints, spermatid, and epididymal spermatozoal measurements typically have skewed distributions. When litter effects were not present, these endpoints were analyzed using the nonparametric multiple comparison methods of Shirley^68^ (as modified by Williams^69^ and Dunn^70^). For these endpoints, the Jonckheere test^71^ was used to assess the significance of the exposure concentration-related trends and to determine, at the 0.01 level of significance, whether a trend-sensitive test (the Williams or Shirley test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic exposure concentration-related trend (the Dunnett or Dunn test).

When litter effects were present for non-normally distributed continuous endpoints, the trend across exposure groups was analyzed by a permutation test based on the Jonckheere trend test implemented by randomly permuting whole litters across exposure groups and bootstrapping within the litters (see, for example, Davison and Hinckley^72^). Pairwise comparisons were made using a modified Wilcoxon test that incorporated litter effects.^73^ The Hommel procedure was used to adjust for multiple comparisons.^74^

### Analysis of Feed Consumption Data

Feed consumption was measured at 3-day intervals for F_0_ and F_1_ dams during gestation and lactation and at least weekly thereafter. In some cases, consumption is reported over intervals that span multiple measurements (e.g., GD 6–21 and LD 1–14). These long-interval values are calculated at the animal or cage level using a weighted average of available constituent subinterval measurements, which are weighted by the underlying subinterval lengths. When spillage is noted or an outlier value is removed from the analysis, the subinterval value for the animal is not reported, and the long interval is calculated excluding that subinterval. As a result, there may be instances in which more animals are reported for a long interval (e.g., GD 6–21) than are reported for the constituent subintervals (e.g., GD 6–9, GD 9–12).

### Analysis of Gestational and Fertility Indices

When litter effects were not present, Cochran-Armitage trend tests were used to test the significance of trends in gestational and fertility indices across exposure groups. Fisher’s exact test was used to conduct pairwise comparisons of each exposed group with the control group. P values for these analyses are two-sided.

### Body Weight Adjustments

Because body weights typically decrease with increasing litter size, adjusting body weight for litter size in the analysis of fetal and pup weights can provide additional precision to detect test article effects.^75^ Body weight adjustments are appropriate when the litter effect, as evidenced by decreasing weights with increasing litter size, is relatively constant across exposure concentrations. Adjusted fetal weights were calculated by fitting a linear model to litter mean fetal weights as a function of litter size and exposure concentration, and the estimated coefficient of litter size was then used to adjust each litter mean fetal weight based on the difference between its litter size and the mean litter size. Preweaning pup body weights were adjusted for live litter size by fitting a linear model to body weights as a function of exposure concentration and litter size, with the coefficient of litter size retained for adjustment as above. Prestandardization PND 4 body weights were adjusted for PND 1 litter size, and body weights measured between PND 4 poststandardization and PND 21 were adjusted for PND 4 poststandardization litter size. After adjustment, mean body weights were analyzed with a linear mixed model with a random litter effect.

### Analysis of Time-to-Event Data

Time-to-event endpoints, such as day of attainment of testicular descent, BPS, and VO, have a number of features that require careful model selection: non-normality of distributions, litter-based correlation, and censored values, meaning attainment was not observed before the end of the observation period. Further, growth retardation, reflected in the weaning weight, is an important covariate in the case of BPS and VO given the relationship between normal day of expected attainment and body weight.

When attainment times were approximately normally distributed and attainment was observed for all animals, two approaches for modeling discrete developmental endpoints were taken. First, a mixed model was fit to attainment day as a function of exposure concentration with a random litter effect. For BPS and VO, a second mixed model was fit to attainment day as a function of exposure concentration and weaning weight with a random litter effect. Dunnett-Hsu adjustments were used to account for multiple comparisons.

If censored observations were observed, survival analysis methods were used. In this case, a Cox proportional hazards model was fit with exposure concentration and weaning weight as covariates, a random effect for litter, and a Hommel adjustment for multiple comparisons.

To calculate mean attainment values adjusted for weaning weight, a linear model was fit to attainment day as a function of exposure concentration and weaning weight. The estimated coefficient of weaning weight was then used to adjust each attainment day based on the difference between the measured weaning weight and the mean weaning weight.

Cumulative response percentage, obtained using the methods of Kaplan-Meier, was plotted against time to attainment for unadjusted attainment times as well as attainment times adjusted for weaning weight. For litter-based plots, the litter median was used as time to attainment if >50% of the pups for that litter attained. Otherwise, litters with ≤50% of the pups attaining had time to attainment set to the final day of observation. These litters are included in the denominator of Kaplan-Meier calculations but not the numerator.

### Analysis of Vaginal Cytology Data

Vaginal cytology data consist of daily observations of estrous cycle stages over a 16-day period. Differences from the control group for cycle length and number of cycles were analyzed using a Datta-Satten modified Wilcoxon test with a Hommel adjustment for multiple comparisons.

To identify disruptions in estrous cyclicity, a continuous-time Markov chain model (multi-state model) was fit using a maximum likelihood approach,^76^ producing estimates of stage lengths for each exposure group. Confidence intervals for these estimates were obtained based on bootstrap sampling of the individual animal cycle sequences. Stage lengths that were significantly different from the control group were identified using permutation testing with a Hommel adjustment.

### Historical Control Data

The concurrent control group is the most valid comparison to the exposed groups and is the only control group analyzed statistically in NTP developmental and reproductive toxicity studies. However, historical control data are often helpful in interpreting potential exposure concentration-related effects, particularly for uncommon fetal findings that occur at a very low incidence. For meaningful comparisons, the conditions for studies in the historical control database must be generally similar. Factors that might affect the background incidences of fetal findings at a variety of sites are diet, strain/stock, route of exposure, study type, and/or laboratory that conducted the study. The NTP historical control database for fetal findings contains all fetal evaluations from teratology studies and/or modified one-generation studies for each laboratory. In general, the historical control database for a given study includes studies using the same route of administration and study design. However, historical control data for rats in this NTP Developmental and Reproductive Toxicity Technical Report contain data from feed and gavage (all routes) studies conducted at RTI International. The concurrent controls are included in the historical control data set. NTP historical controls are available online at https://ntp.niehs.nih.gov/data/controls/index.html.

## Quality Assurance Methods

This study was conducted in compliance with the Food and Drug Administration’s Good Laboratory Practice for Nonclinical Laboratory Studies (Title 21, Part 58 of the Code of Federal Regulations).^77^ In addition, this study was audited retrospectively by an independent QA assessment contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Developmental and Reproductive Toxicity Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this report.

## Genetic Toxicology

The genetic toxicology of BPAF was assessed by testing whether the chemical induces mutations in various strains of Salmonella typhimurium and Escherichia coli and increases the frequency of micronucleated erythrocytes in rat peripheral blood. The protocol for these studies and the results are given in Appendix D.

The genetic toxicity studies have evolved from an earlier effort by NTP to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the relationship between the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were developed originally to clarify proposed mechanisms of chemical-induced DNA damage, given the relationship between electrophilicity and mutagenicity,^78^ and the somatic mutation theory of cancer.^79; 80^ Not all cancers, however, arise through genotoxic mechanisms.

### Bacterial Mutagenicity

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites.^81^ A positive response in the Salmonella test was shown to be the most predictive in vitro indicator for rodent carcinogenicity (89% of the Salmonella mutagens are rodent carcinogens).^82; 83^ Additionally, no battery of tests that included the Salmonella test improved the predictivity of the Salmonella test alone. Other tests, however, can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation.

### Peripheral Blood Micronucleus Test

Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division.^84; 85^ Acute in vivo bone marrow chromosome aberration and micronucleus tests appear to be less predictive of carcinogenicity than the Salmonella test.^86; 87^ However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies.^88^ Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is important to the overall understanding of the risks associated with exposure to a particular chemical.