# Introduction

Figure 1

Bisphenol AF (CASRN 1478-61-1; Chemical Formula: C_15_H_10_F_6_O_2_; Molecular Weight: 336.23)

Synonyms: 4,4’-(hexafluoroisopropylidene)diphenol; 2,2-bis(4-hydroxyphenyl)hexafluoropropane; 2,2-bis(4-hydroxyphenyl)perfluoropropane; phenol, 4,4’-[2,2,2-trifluoro-1-(trifluoromethyl)ethylidene]bis-; hexafluorobisphenol a.

## Chemical and Physical Properties

Bisphenol AF (BPAF) is a white to light gray powder with a melting point of 160°C–162°C. BPAF is relatively insoluble in water (estimated median of 209 ppm at 21.5°C; log octanol/water partition coefficient [K_OW_] = 4.64 ± 0.10) and is soluble in most organic solvents.^1; 2^

## Production, Use, and Human Exposure

BPAF can be synthesized from the reaction of a phenol and a fluorinated precursor (e.g., fluorinated aldehyde or ketone) in the presence of an organic sulfonic acid catalyst.^3^

BPAF is commonly used as a curing or crosslinking agent in the processing of fluorocarbon elastomers^4^ and in rubber processing to alter polymer properties of a compound by forming covalent, hydrogen, or other bonds between polymer molecules.^5^ BPAF is often used in combination with triphenyl benzylphosphonium chloride (BTPPC/BeTPC) in organic synthesis as a wetting reagent and as a phase transfer catalyst in the production of fluoroelastomers and printing inks. BPAF-cured fluoroelastomers have material characteristics, including thermal stability, chemical resistance, and compression set resistance, which are useful in plastics manufacturing and other fabrication processes. In addition, BPAF is used as a monomer in the synthesis of other specialty polymers, including polyimides, polyamides, polyesters, and polycarbonates, allowing use in a wide range of specialty applications (e.g., in gas separation and semiconductor processing).^6^ Polymers containing BPAF are useful in high-temperature composites, electronic materials, and other specialty applications.

BPAF’s physical and chemical properties suggest that it resides primarily in soil, water, or sediment, depending on the mode of entry, and that it is not readily biodegradable.^7^ Predicted half-life in atmospheric conditions (0.133 days) suggests that BPAF (neutral form) is not persistent in air; however, biodegradation models indicate that the half-life in water/soil and sediment is >182 days and 365 days, respectively.^7^

BPAF has been detected in the general population around the world, suggesting environmental exposure. Free BPAF was detected in 85% of urine samples from university students in South China, with a median urine concentration of 0.03 ng/mL.^8^ The frequency of detection of BPAF reported in other studies in China, however, was <6.5%.^9; 10^ Urinary concentrations of total BPAF were also low (≤0.173 ng/mL) and were found in <30% of samples tested.^9^ BPAF was below the limit of detection (LOD) of 0.02 µg/mL in urine samples from a European Union biomonitoring study of 144 adults.^11^ Urinary BPAF concentrations up to 88.3 ng/L were observed in children, but the mean concentration was only 3.4 ng/L due to the low detection rate of 46%.^12^

In serum, BPAF was detected in 33% of samples from 181 pregnant women in China with a concentration up to 0.4 ng/mL.^13^ It was also detected in 100% of maternal plasma, cord plasma, and placenta samples from 60 women in South China,^14^ with mean BPAF concentrations of 13.1, 80.4, and 28.4 pg/g, respectively. The higher concentrations in cord plasma relative to maternal plasma and placenta suggest a high maternal transfer rate and the potential for accumulation in fetal cord blood. BPAF was also detected in 21% of human breast milk samples with a mean concentration of 0.092 ng/mL.^15^ In serum from an elderly population near an e-waste recycling plant, BPAF concentrations up to 0.043 ng/mL were reported.^16^

## Regulatory Status

BPAF is part of the compiled inventory of substances likely to meet the criteria of Annex III to the European Union’s Registration, Evaluation, Authorisation and Restriction of Chemicals (REACH) Regulation, and it is listed as both a suspected hazard to the aquatic environment and as persistent in the environment. In the United States, it is listed in the Toxic Substances Control Act (TSCA) inventory and, in its dipotassium salt form (phenol, 4,4’-[2,2,2-trifluoro-1-(trifluoromethyl)ethylidene]bis-,dipotassium salt (CASRN 25088-69-1)), is approved as an indirect food additive (Section 177.2400 perfluorocarbon-cured elastomers) and can be used as articles or components of articles intended for repeated use in contact with nonacid food (pH above 5.0).^17; 18^

## Absorption, Distribution, Metabolism, Excretion, and Toxicokinetics

### Experimental Animals

The National Toxicology Program (NTP) investigated the absorption, distribution, metabolism, and excretion (ADME) and toxicokinetic properties of BPAF in male and female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats and B6C3F1/N mice.^19; 20^ BPAF was excreted primarily in feces following a single gavage dose of 3.4, 34, or 340 mg/kg body weight [^14^C]-labeled BPAF administered to rats (65%–80%) or to mice (63%–72%).^19^ Excretion of [^14^C]-labeled BPAF in urine was low to moderate, with females (rat, 15%; mouse, 24%) excreting more than males (rat, 4%; mouse, 10%) following a single 34 mg/kg gavage dose. Concomitant with higher urinary excretion, the fecal excretion was lower in females (rat, 65%; mouse, 53%) compared to males (rat, 77%; mouse, 72%).^19^ Approximately 52% of an orally administered 34 mg/kg dose in male rats was recovered in bile 24 hours postadministration. Most of the dose excreted in feces, however, was recovered after 24 hours; this delay in fecal excretion supports enterohepatic recirculation of BPAF-derived moieties.^19^ Following a 34 mg/kg intravenous dose in male and female rats and mice, 63%–76% of the administered dose was recovered in feces with ≤16% recovered in urine.^19^ Taken collectively, these data demonstrate that BPAF was well-absorbed in rats and mice after gavage administration and that most of the dose recovered in feces of rats and mice (63%–80%) was likely the absorbed dose, which was excreted via bile to the intestine. [^14^C]-labeled BPAF was distributed to tissues, but the total radioactivity in tissues at 72 hours postadministration was ≤2%, showing low potential for tissue retention.^19^

Metabolites identified in bile were monoglucuronide, diglucuronide, and mixed glucuronide sulfate conjugates of the [^14^C]-labeled BPAF; parent BPAF was not detected.^19^ The main analyte detected in feces was the parent BPAF, however, which suggests deconjugation of metabolites in the intestine before excretion via feces. In urine, parent [^14^C]-labeled BPAF and mono- and diglucuronides were detected. The metabolism of BPAF in rodents is shown in Figure 2.^19^ Li et al.^21^ also reported four urinary metabolites of BPAF (diglucuronide, glucuronide, a dehydrated form of glucuronide, and a sulfate conjugate) after daily gavage administration of 200 mg/kg in Sprague Dawley rats for 2 weeks.

Figure 2

Metabolism of Bisphenol AF in Rodents

Adapted from Waidyanatha et al.^19^

Toxicokinetic properties of both free BPAF (parent) and total BPAF (combined parent and conjugated forms) were investigated after a single oral dose of 34, 110, or 340 mg/kg in Hsd:Sprague Dawley^®^ SD^®^ rats and B6C3F1/N mice.^20^ BPAF was absorbed rapidly in male and female rats with a time to reach maximum concentration (T_max_) of ≤2.20 hours for free BPAF. BPAF was cleared rapidly with a plasma elimination half-life of ≤3.35 hours. The maximum concentration (C_max_) and the area under the concentration versus time curve (AUC) of free BPAF increased proportionally to the dose in both sexes. Total BPAF T_max_ was also short in male and female rats (≤1.07 hours). In addition, total C_max_ and AUC values were ≥27-fold and ≥52-fold higher, respectively, than corresponding free BPAF values. These data demonstrate rapid and extensive first pass conjugation of BPAF in the intestine and the liver after oral administration. Absorption of BPAF after oral administration of the 34 mg/kg dose in mice was more rapid than in rats, with the C_max_ for free BPAF reached at 0.46 hours; however, plasma elimination of free BPAF was slightly slower than in rats, with a half-life ≤4.22 hours. As in rats, C_max_ and AUC in mice were much higher for total BPAF than for free BPAF (≥30-fold and ≥12-fold higher, respectively). Consistent with this finding, the oral bioavailability in rats (approximately 1%) and mice (3%–6%) was low. There was no apparent sex-related effect in toxicokinetic parameters for free or total BPAF in rats or mice.^20^

Following exposure of male Hsd:Sprague Dawley^®^ SD^®^ rats and B6C3F1/N mice to 338, 1,125, or 3,750 ppm BPAF via feed for 7 days, free BPAF C_max_ and AUC, per a unit BPAF dose were four- to ninefold and two- to sixfold higher, respectively, in mice than in rats. The difference was greater at the higher exposure concentration likely due to lower chemical consumption by rats in the 3,750 ppm group. For total BPAF, rats showed a higher systemic exposure compared to mice at lower exposure concentrations. At the highest exposure concentration, the total BPAF systemic exposure was either lower (C_max_) or similar (AUC) to mice with the difference likely due to lower chemical consumption by rats in the highest exposure group (3,750 ppm). The total BPAF C_max_ and AUC were higher than the corresponding free values in rats (C_max_ ≥ 130-fold; AUC ≥ 127-fold) compared to mice (C_max_ ≥ 16-fold; AUC ≥ 16-fold), demonstrating that the extent of conjugation of BPAF in rats was much higher than in mice. For free BPAF, the plasma elimination half-lives were similar between the two species (rats, 7.10–10.5 hours; mice, 4.50–6.66 hours); however, for total BPAF, half-lives were about two- to threefold longer in rats (7.44–13.3 hours) compared to mice (3.49–4.18 hours).^22^

BPAF was rapidly taken up by zebrafish, with equilibrium concentrations reached in 24–72 hours following whole-body exposure to 1–20 µg BPAF/L.^23^ BPAF concentrations were higher in males (8.5–174 µg/kg) than in females (5.0–105 µg/kg) at all exposure concentrations after 168 hours of exposure. Glucuronide conjugate of BPAF was the major metabolite observed, and concentrations found were higher than those of free BPAF. Glucuronide concentrations were higher in females (approximately 54–1,180 µg/kg) than in males (approximately 24–533 µg/kg), which, combined with the lower free BPAF concentrations in females, suggests more extensive glucuronidation in female zebrafish.

BPAF was cleared more rapidly by rat hepatocytes compared to mouse hepatocytes in vitro (the half-life for rat was 6–13 minutes and for mouse was approximately 36–66 minutes).^19^

### Humans

The literature contains no studies on in vivo ADME data of BPAF in humans. In human hepatocytes in vitro, BPAF was cleared more slowly than in hepatocytes from rats or mice, with a half-life of 101–156 minutes. Metabolites corresponding to mono- and diglucuronides and sulfate conjugates were detected.^19^ Metabolism of BPAF to its glucuronide was also shown in human liver microsomes with an estimated maximum velocity (V_max_) of 11.6 nmol/min/mg.^21^ The authors also reported glucuronidation of BPAF could be mediated through several human recombinant UDP-glucuronosyltransferases (UGTs), including UGT1A1, UGT1A3, UGT1A8, UGT1A9, UGT2B4, UGT2B7, UGT2B15, and UGT2B17, among which UGT2B7 showed the highest efficiency of glucuronidation among those tested.^21^

## Developmental and Reproductive Toxicity

### Models of Endocrine Activity

BPAF has been reported to bind strongly to estrogen receptor alpha (ERα) and estrogen receptor beta (ERβ) over estrogen-related receptor (ERR) gamma. Receptor-binding activity was stronger for ERβ than for ERα; however, when assessed using a reporter gene assay, BPAF was a full agonist for ERα and almost completely inactive in stimulating the basal constitutive activity of ERβ. BPAF acted as a strong antagonist against the activity of the endogenous ERβ agonist 17beta-estradiol. Results from Matsushima’s research group suggest that BPAF can function as an endocrine-disrupting chemical, acting as either an agonist or antagonist, and can perturb physiological processes mediated through ERα and/or ERβ.^24^ BPAF also can activate ER-regulated gene transcription^25^ and stimulate estrogen-sensitive human breast cancer cell (MCF-7) proliferation.^26; 27^ In the Hershberger assay (antagonist mode), however, BPAF-exposed rats displayed an increase in the relative weight of the Cowper’s glands and glans penis along with significantly decreased body weights (approximately 6%–20%).^28^

Studies conducted according to the Organisation for Economic Co-operation and Development (OECD) Test Guideline 407 suggest that BPAF has estrogenic properties as demonstrated by Leydig cell atrophy and irregular estrous cycles.^29^ Uterotrophic and Hershberger repeated dose tests showed significant increases in relative uterine weights and significant increases in glans penis weight, respectively.^28^

### Experimental Animals

In a combined repeated dose toxicity study with reproduction/developmental toxicity screening (OECD Test Guideline 422) performed in Sprague Dawley rats administered BPAF via oral gavage,^30^ the female fertility index decreased with increasing dose, and at the high dose of 300 mg BPAF/kg body weight/day (mg/kg/day), no pregnancies were observed (11, 10, 8, and 0 pregnant females at 0, 30, 100, and 300 mg/kg/day, respectively). Furthermore, the number of corpora lutea and the number of implants were also reduced with increasing dose. No adverse effects on offspring or differences in sex ratio and body weights of offspring (up to postnatal day [PND] 4) were noted between treated and control animals. In the same study, effects on male reproductive organs were noted, and Leydig cell atrophy was observed at the 100 and 300 mg/kg/day doses.^30^ This effect is consistent with effects reported for a 28-day repeated dose toxicity study^29^ in which Leydig cell atrophy was observed in 5 out of 10 male Sprague Dawley rats exposed to 100 mg/kg/day (highest dose tested).

In an in vivo mammary gland study, CD-1 mice were exposed via oral gavage to 0, 0.05, 0.5, or 5 mg/kg BPAF twice per day from gestation day (GD) 10.5 to GD 17.5; offspring were observed for up to 16 months. BPAF exposure in this study resulted in accelerated pubertal mammary development and a significant dose-related increase in nonneoplastic lesions in BPAF-exposed groups by 14 months.^31^ Lactational transfer was observed in a cross-fostered study using Sprague Dawley rats in which BPAF was administered to dams by oral gavage during gestation (GD 3–19) or lactation (lactation days [LD] 3–19) at 0 and 100 mg/kg/day. Lactational exposure caused significantly increased concentrations of BPAF in serum and testis from male rat pups, indicating that BPAF was transferred via breast milk.^32^

### Humans

The literature contains no studies on the developmental or reproductive toxicity of BPAF in humans.

## General Toxicity

### Experimental Animals

The rat oral median lethal dose (LD_50_) has been reported to be 3,400 mg/kg.^33^ Adverse effects have been observed in studies submitted to the European Chemicals Agency (ECHA), with a no-observed-adverse-effect level (NOAEL) of 10 mg/kg/day.^34^

In a short-term repeat dose toxicity study in rats conducted according to OECD Test Guideline 407,^29^ 10 animals/sex/group were administered 0, 10, 30, or 100 mg/kg/day BPAF via oral gavage for at least 28 days. In the 100 mg/kg/day group, salivation was noted early after dosing, although this sign disappeared within 90 minutes of administration. Primary findings included a decrease of body weight gains in males at 100 mg/kg/day and in females at both 30 and 100 mg/kg/day. In male rats, white blood cell counts, total cholesterol, and albumin values decreased in the 100 mg/kg/day group; in female rats, cholinesterase and total cholesterol values decreased and total bilirubin values increased in the 100 mg/kg/day group. Serum thyroxine (T_4_) values increased in the 100 mg/kg/day groups of both sexes, but no changes in thyroid stimulating hormone (TSH) were detected in any dose groups. In male rats, relative kidney, adrenal, and brain weights increased significantly in the 100 mg/kg/day group, and the absolute prostate (ventral and dorsolateral), ventral prostate, seminal vesicle, liver, heart, and spleen weights decreased relative to the control group. In female rats, relative brain weight increased significantly in the 30 and 100 mg/kg/day groups, and absolute heart weight decreased in the 100 mg/kg/day group. In addition, pathological changes were noted in several tissues. The NOAEL for systemic toxicity was 10 mg/kg/day due to the reduction in body weight gain and abnormal estrous cycles in the female rats dosed at 30 mg/kg/day.

### Humans

The literature contains no studies on the general toxicity of BPAF in humans.

## Genetic Toxicity

The genetic toxicity of bisphenol A (BPA) and BPA analogs have been reviewed.^35^ In contrast to some of the other BPA analogs, little information exists on the genotoxic potential of BPAF, although, of the studies available, several have published positive results for BPAF.

As part of a class study of BPA analogs, BPAF-induced cytotoxicity was measured in five different DT40 chicken lymphoblastoid cell lines, each deficient in a different key gene involved in DNA repair processes (e.g., nonhomologous end joining, base excision repair, translation synthesis, homologous recombination). In contrast to BPA and other BPA analogs, such as bisphenol M and bisphenol F (BPF), there was no evidence of enhanced cytotoxicity compared with wild-type DNA repair competent DT40 cells observed in any of the five DT40 cell lines treated with BPAF (concentrations ≤25 µM).^36^ Furthermore, BPAF did not induce chromosomal aberrations in any of the five DT40 knockout cell lines (Ku70^-/-^, Polβ^-/-^, RAD54^-/-^, REV3^-/-^, and XPA^-/^), and no increase in γH2AX foci was observed in the single DT40 RAD54^-/-^ cell line tested, which had been shown to be most sensitive to DNA damage induced by BPA analogs.^36^

In contrast to the DT40 studies, several studies in mammalian cell models reported positive results with BPAF. Hercog et al.^37^ reported that BPAF, over a concentration range of 5–20 µg/mL, showed greater cytotoxicity than BPA, BPF, or bisphenol S in HepG2 cells after 24 and 72 hours of incubation. BPAF induced increases in γH2AX foci, indicators of DNA double strand breaks, at the 10 and 20 µg/mL concentrations after 24 hours of exposure. Testing BPAF at a lower, environmentally relevant concentration (1 ng/mL), however, revealed no increases in γH2AX foci. Mixtures of the four BPA analogs at ng concentrations also did not result in increases in γH2AX foci.

In the in vitro alkaline comet assay using primary human peripheral lymphocytes, Mokra et al.^38^ found significant increases in percent tail DNA at BPAF concentrations of 0.1–10 µg/mL after 1 hour incubation. Significant increases in DNA damage also were observed in the neutral version of the comet assay at BPAF concentrations of 1 and 10 µg/mL after 1 hour incubation, a response that the authors suggest is indicative of BPAF-induced DNA double strand breaks. Increased levels of DNA damage were also seen with BPAF in both the alkaline and the neutral comet assays following 4 hours incubation, in which the top dose was limited to 1 µg/mL. The observed increases in DNA damage induced by BPAF were greater than the increases seen with BPA, BPF, or bisphenol S over the same concentration ranges and incubation times.

Lei et al.^39^ tested BPAF, BPA, bisphenol E, bisphenol C, tetrachlorobisphenol A, and thiodiphenol in the alkaline comet assay using MCF-7 cells over a concentration range of 1–50 µM in dimethyl sulfoxide. Increases in percent tail DNA were observed with BPAF and several of the other BPA analogs although only at doses that induced significant cytotoxicity, thus confounding interpretation of the results.

In a modified in vitro alkaline comet assay using DNA glycosylases designed to assess the relative amount of oxidative base damage induced by BPAF, BPA, BPF, and bisphenol S in primary human peripheral lymphocytes, BPAF was reported to significantly increase percent tail DNA at doses as low as 0.01 µg/mL after 48 hours incubation and 0.1 µg/mL after 4 hours incubation.^40^ BPAF also induced greater increases in percent tail DNA than BPA and the other two analogs tested in the same assay.

## Study Rationale

BPAF was selected for evaluation based on a review of compounds that are potentially endocrine-active after concerns were raised about possible effects of BPA on the brain, behavior, and prostate gland of fetuses, infants, and children at current human exposure levels. The review assessed a number of agents that could have endocrine activity and were either persistent in the environment or had high human exposures, including chemicals that are structurally related to BPA.

BPAF, a fluorinated analog of BPA used in the production of polycarbonates, fluoroelastomers, and epoxy resins, was therefore chosen due to the potential for endocrine activity, lack of adequate toxicity data, and possible environmental persistence due to the presence of fluorine atoms.

BPAF exposure via diet was selected for this study because the oral route is a relevant exposure pathway for humans. To minimize the potential endocrine activity of phytoestrogens, which are often present in rodent diets, a diet low in phytoestrogens was used.