# Acknowledgments

This work was supported by the Intramural Research Program (ES103316, ES103318, and ES103319) at the National Institute of Environmental Health Sciences, National Institutes of Health and performed for the National Toxicology Program, Public Health Service, U.S. Department of Health and Human Services under contracts HHSN273201800006C, GS00Q14OADU417 (Order No. HHSN273201600015U), HHSN273201600011C, HHSN273201500012C, HHSN273201500006C, HHSN273201500014C, HHSN273201400020C, HHSN273201400023C, HHSN273201400001C, HHSN273201300009C, HHSN316201200054W, HHSN273201100001C, and N01-ES-75564.