# Appendix D Genetic Toxicology

## D.1 Data Evaluation Protocol

The National Toxicology Program (NTP) considers biological as well as statistical factors to determine an overall assay result. For an individual assay, the statistical procedures for data analysis are described in the following protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. In such cases, all the data are critically evaluated with attention given to possible protocol variations in determining the weight of evidence for an overall conclusion of chemical activity in an assay. For in vitro assays conducted with and without exogenous metabolic activation, results obtained in the absence of activation are analyzed separately from results obtained in the presence of activation. The summary table in the abstract of this report presents NTP’s scientific judgment regarding the overall evidence for activity of the chemical in an assay.

## D.2 Bacterial Mutagenicity

### D.2.1 Bacterial Mutagenicity Test Protocol

Testing procedures were modified from those originally reported by Zeiger et al.^126^. Coded samples of bisphenol AF (BPAF) were incubated with the Salmonella typhimurium (TA98, TA100) or Escherichia coli WP2 uvrA (pKM101) tester strains either in buffer or S9 mix (metabolic activation enzymes and cofactors from phenobarbital/benzoflavone-induced male Sprague Dawley rat liver) for 20 minutes at 37°C. Top agar supplemented with L-histidine (or tryptophan for the E. coli strain) and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine- or tryptophan-independent mutant colonies arising on these plates were counted after incubation for 2 days at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and at least six doses of BPAF. The highest dose tested was limited by toxicity in all strains. All trials were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose-related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed after chemical treatment. No minimum percentage or fold increase is required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background. Results obtained in trials conducted in the absence of S9 activation are not combined with results obtained in the presence of activation; each testing condition is independently evaluated.

### D.2.2 Results

BPAF was not mutagenic in S. typhimurium strains TA98 and TA100, or in E. coli strain WP2 uvrA (pKM101) in tests conducted with and without induced male Sprague Dawley rat liver S9 mix. In all three strains, the top dose was limited by cytotoxicity. However, BPAF was markedly more cytotoxic to the two S. typhimurium strains, compared with the E. coli strain (Table D-1).

Table D-1 Mutagenicity of Bisphenol AF in Bacterial Tester Strains^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9
TA98
| 0 | 46 ± 4.0 | 56 ± 1.9 | 50 ± 7.2 | 55 ± 1.3
| 4.0 | 50 ± 6.9 | 49 ± 4.5 | – | –
| 8.0 | 53 ± 4.6 | 67 ± 9.2 | 55 ± 7.5 | 60 ± 3.2
| 20.0 | 48 ± 4.6 | 58 ± 1.7 | 48 ± 0.9 | 58 ± 4.6
| 30.0 | 37 ± 1.7 | 50 ± 0.9 | – | –
| 50.0 | 14 ± 1.5^s^ | 26 ± 2.2 | 41 ± 3.8 | 68 ± 1.2
| 125.0 | Toxic | Toxic | 36 ± 2.9 | 39 ± 0.6
| 250.0 | – | – | 18 ± 0.3^s^ | 28 ± 1.2
| 500.0 | – | – | Toxic | 7 ± 1.5^s^
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control^b^ | | 523 ± 31.1 | 618 ± 31.5 | 1,339 ± 30.4 | 1,449 ± 23.6
TA100
| 0 | 95 ± 6.4 | 134 ± 14.7 | 103 ± 4.7 | 139 ± 7.0
| 4.0 | 94 ± 2.3 | 128 ± 5.2 | – | –
| 8.0 | 108 ± 7.0 | 159 ± 32.4 | 99 ± 4.7 | 134 ± 13.1
| 20.0 | 89 ± 5.7 | 111 ± 3.1 | 114 ± 6.5 | 129 ± 10.3
| 30.0 | 85 ± 6.3 | 102 ± 9.0 | – | –
| 50.0 | 3 ± 1.0^s^ | 10 ± 4.0^s^ | 103 ± 4.9 | 124 ± 2.6
| 125.0 | 2 ± 1.0^s^ | Toxic | 83 ± 9.3 | 105 ± 7.3
| 250.0 | – | – | 30 ± 2.1^s^ | 52 ± 2.3^s^
| 500.0 | – | – | 26 ± 4.0^s^ | Toxic
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control | | 709 ± 4.4 | 761 ± 32.9 | 711 ± 64.1 | 610 ± 25.8
Escherichia coli WP2 uvrA (pKM101)
| 0 | 154 ± 7.4 | 151 ± 3.8 | 218 ± 17.2 | 180 ± 7.8
| 125.0 | 136 ± 4.0 | 139 ± 8.1 | 221 ± 11.3 | 223 ± 13.5
| 250.0 | 109 ± 4.3 | 115 ± 0.0 | 186 ± 8.4 | 178 ± 6.4
| 500.0 | 91 ± 6.9 | 78 ± 4.8 | 167 ± 16.4 | 161 ± 3.3
| 750.0 | 52 ± 10.2^s^ | 83 ± 4.7 | 127 ± 6.3 | 125 ± 2.3
| 1,000.0 | 52 ± 3.5^s^ | 26 ± 1.7^s^ | 80 ± 14.2^s^ | 108 ± 10.7
| 2,000.0 | 31 ± 6.8^s^ | 46 ± 2.2^p^ | 32 ± 1.5^p^ | 18 ± 1.7^x^
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control | | 2,425 ± 140.4 | 3,010 ± 26.5 | 1,324 ± 24.3 | 1,585 ± 85.5

^p^ = precipitate; ^s^ = slight toxicity; ^x^ = slight toxicity and precipitate.

^a^ Studies performed at Integrated Laboratory Systems, LLC. Data are presented as revertants/plate (mean ± standard error) from three plates; 0 μg/plate served as the solvent control (dimethyl sulfoxide).

^b^ The positive controls in the absence of metabolic activation were 2-nitrofluorene (TA98), sodium azide (TA100), and 4-nitro-quinoline-N-oxide (E. coli). The positive controls for metabolic activation were benzo[a]pyrene (TA100) and 2-aminoanthracene (TA98 and E. coli).

## D.3 Micronucleus Assay

### D.3.1 Peripheral Blood Micronucleus Test Protocol

At termination of the studies of BPAF, blood samples (approximately 200 μL) were collected from male and female rats, placed in ethylenediaminetetraacetic acid (EDTA)-coated tubes, and shipped overnight to the testing laboratory. Upon arrival, blood samples were fixed in ultracold methanol using a MicroFlowPLUS Kit (Litron Laboratories, Rochester, NY) according to the manufacturer’s instructions. Fixed samples were stored in a −80°C freezer until analysis. Thawed blood samples were analyzed for frequency of micronucleated immature erythrocytes (i.e., reticulocytes or polychromatic erythrocytes [PCEs]) and mature erythrocytes (i.e., normochromatic erythrocytes [NCEs]) using a flow cytometer^127^; both the mature and immature erythrocyte populations can be analyzed separately by employing special cell surface markers to differentiate the two cell types. Because the very young reticulocyte subpopulation (CD71+ cells) can be targeted using this technique, rat blood samples can be analyzed for damage that occurred in the bone marrow within the past 24–48 hours, before the rat spleen appreciably alters the percentage of PCEs in circulation.^128^ In mice, both the mature and immature erythrocyte populations can be evaluated for micronucleus frequency because the mouse spleen does not sequester and eliminate damaged erythrocytes. Damaged erythrocytes achieve steady state in the peripheral blood of mice after four weeks of continuous exposure. Approximately 20,000 PCEs and 1 × 10^6^ NCEs were analyzed per animal for frequency of micronucleated cells, and the percentage of immature erythrocytes (% PCE) was calculated as a measure of bone marrow toxicity resulting from chemical exposure.

Prior experience with the large number of cells scored using flow cytometric scoring techniques^129; 130^ suggests it is reasonable to assume that the proportion of micronucleated reticulocytes is approximately normally distributed. The statistical tests selected for trend and for pairwise comparisons with the control group depend on whether the variances among the groups are equal. The Levene test at α = 0.05 is used to test for equal variances. In the case of equal variances, linear regression is used to test for a linear trend with exposure concentration and the Williams test is used to test for pairwise differences between each exposed group and the control group. In the case of unequal variances, the Jonckheere test is used to test for linear trend and the Dunn test is used for pairwise comparisons of each exposed group with the control group. To correct for multiple pairwise comparisons, the p value for each comparison with the control group is multiplied by the number of comparisons made. In the event that this product is >1.00, it is replaced with 1.00. Trend tests and pairwise comparisons with the control group are considered statistically significant at p ≤ 0.025.

In the micronucleus test, it is preferable to base a positive result on the presence of both a positive trend as well as at least one significantly elevated exposed group compared with the corresponding control group. In addition, historical control data are used to evaluate the biological significance of any observed response. Both statistical significance and biological significance are considered when arriving at a call. The presence of either a positive trend or a single significant exposed group generally results in an equivocal call. The absence of both a trend and any significant differences between exposed groups and the control group results in a negative call. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed (in acute studies), and the magnitudes of those effects.

### D.3.2 Results

BPAF was also evaluated in the in vivo peripheral blood micronucleus assay for ability to induce chromosomal damage in the form of structural or numerical alterations; no significant increases in the frequencies of PCEs were observed in male or female rats administered BPAF (338–3,750 ppm) for 17 weeks in dosed feed, and no significant changes in % PCE were observed, suggesting that BPAF exposure did not affect erythropoiesis (Table D-2).

Table D-2 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male and Female Rats in the Modified One-Generation Study of Bisphenol AF^a^

| Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)^b^ | P Value^c^
Male
Exposure Concentration (ppm)
0 | 5 | 0.62 ± 0.18 | | 0.09 ± 0.03 | | 1.02 ± 0.09
338.0 | 5 | 0.56 ± 0.10 | 0.724 | 0.07 ± 0.02 | 0.737 | 1.09 ± 0.07 | 0.542
1,125.0 | 5 | 0.51 ± 0.15 | 0.806 | 0.06 ± 0.01 | 0.818 | 1.10 ± 0.08 | 0.572
3,750.0 | 5 | 0.34 ± 0.07 | 0.839 | 0.07 ± 0.01 | 0.850 | 1.25 ± 0.11 | 0.116
Trend^d^ | | p = 0.942 | | p = 0.722 | | p = 0.083
Female
Exposure Concentration (ppm)
0 | 5 | 0.61 ± 0.09 | | 0.06 ± 0.01 | | 0.87 ± 0.05
338.0 | 5 | 0.55 ± 0.05 | 0.803 | 0.07 ± 0.01 | 0.596 | 0.89 ± 0.07 | 1.000
1,125.0 | 5 | 0.52 ± 0.10 | 0.874 | 0.05 ± 0.01 | 0.684 | 0.83 ± 0.08 | 1.000
3,750.0 | 5 | 0.40 ± 0.04 | 0.899 | 0.06 ± 0.01 | 0.719 | 1.12 ± 0.11 | 0.067
Trend | | p = 0.976 | | p = 0.683 | | p = 0.027

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at Integrated Laboratory Systems, LLC.

^b^ Data presented as mean ± standard error.

^c^ Pairwise comparisons with the vehicle control group performed using the Williams or Dunn test (p ≤ 0.025).

^d^ Exposure concentration-related trends evaluated by linear regression of the Jonckheere test (p ≤ 0.025).