# Appendix B Ingredients, Nutrient Composition, and Contaminant Levels in 5K96 Rat Ration

Additional information on ingredients, vitamins, and minerals in the 5K96 rat diet can be found online.^125^

Table B-1 Nutrient Composition of 5K96 Rat Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 20.74 ± 0.3050 | 20.4–21.1 | 5
Crude Fat (% by Weight) | 4.34 ± 0.5899 | 3.5–5.1 | 5
Crude Fiber (% by Weight) | 3.158 ± 0.2216 | 2.82–3.41 | 5
Ash (% by Weight) | 5.826 ± 0.1627 | 5.56–5.96 | 5
Vitamins
Vitamin A (IU/kg) | 14,936 ± 7,602 | 1,480–19,800 | 5
Thiamine (ppm) | 17.82 ± 1.9071 | 15.8–20.5 | 5
Minerals
Calcium (%) | 1.120 ± 0.0982 | 0.949–1.19 | 5
Phosphorus (%) | 0.891 ± 0.0615 | 0.795–0.952 | 5

Table B-2 Contaminant Levels in 5K96 Rat Ration

Contaminant | Mean ± Standard Deviation | Range | Number of Samples
Arsenic (ppm) | 0.3886 ± 0.0581 | 0.291–0.438 | 5
Cadmium (ppm) | 0.0403 ± 0.0051 | 0.0339–0.046 | 5
Lead (ppm) | 0.2866 ± 0.1347 | 0.15–0.511 | 5
Mercury (ppm) | 0.0127 ± 0.0036 | 0.01–0.0177 | 5
Selenium (ppm) | 0.4338 ± 0.0503 | 0.346–0.471 | 5
Aflatoxins (ppb)^a^ | <2.0 | – | 5
Nitrate Nitrogen (ppm)^b^ | 17.14 ± 3.0778 | 13.1–20.6 | 5
Nitrite Nitrogen (ppm)^a,b^ | <1.0 | – | 5
BHA (ppm)^a,c^ | <1.0 | – | 5
BHT (ppm)^a,c^ | <1.0 | – | 5
Aerobic Plate Count (CFU/g) | <10.0 | – | 5
Coliform (MPN/g) | <3.0 | – | 5
Escherichia coli (MPN/g) | <10.0 | – | 5
Enterobacteriaceae (MPN/g) | <3.0 | – | 5
Total Nitrosamines (ppb)^d^ | 4.48 ± 4.1578 | 0–10.5 | 5
N-Nitrosodimethylamine (ppb)^d^ | 2.74 ± 3.3968 | 0–7.8 | 5
N-Nitrosopyrrolidine (ppb)^d^ | 1.74 ± 1.1104 | 0–2.7 | 5
Pesticides (ppm)
α-BHC^a^ | <0.01 | – | 5
β-BHC^a^ | <0.02 | – | 5
γ-BHC^a^ | <0.01 | – | 5
δ-BHC^a^ | <0.01 | – | 5
Heptachlor^a^ | <0.01 | – | 5
Aldrin^a^ | <0.01 | – | 5
Heptachlor Epoxide^a^ | <0.01 | – | 5
DDE^a^ | <0.01 | – | 5
DDD^a^ | <0.01 | – | 5
DDT^a^ | <0.01 | – | 5
HCB^a^ | <0.01 | – | 5
Mirex^a^ | <0.01 | – | 5
Methoxychlor^a^ | <0.05 | – | 5
Dieldrin^a^ | <0.01 | – | 5
Endrin^a^ | <0.01 | – | 5
Telodrin^a^ | <0.01 | – | 5
Chlordane^a^ | <0.05 | – | 5
Toxaphene^a^ | <0.10 | – | 5
Estimated PCBs^a^ | <0.20 | – | 5
Ronnel^a^ | <0.01 | – | 5
Ethion^a^ | <0.02 | – | 5
Trithion^a^ | <0.05 | – | 5
Diazinon^a^ | <0.10 | – | 5
Methyl Chlorpyrifos | 0.0625 ± 0.0295 | 0.0464–0.115 | 5
Methyl Parathion^a^ | <0.02 | – | 5
Ethyl Parathion^a^ | <0.02 | – | 5
Malathion^a^ | <0.02 | – | 5
Endosulfan I^a^ | <0.01 | – | 5
Endosulfan II^a^ | <0.01 | – | 5
Endosulfane Sulfate^a^ | <0.03 | – | 5

All samples were irradiated. BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.