# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization

Bisphenol AF (BPAF) was obtained from 3B Pharmachem International Co., Ltd (Wuhan, China) in a single lot (20100425) that was used in the dose range-finding and MOG studies. The bulk chemical of BPAF lot 20100425 was received in two batches, which were screened for identification and purity to ensure acceptable quality. Subsequently, the two batches were combined and homogenized by mixing for 5 minutes. The final batch was transferred to 80-oz amber glass bottles sealed with Teflon-lined lids and stored at ambient conditions. Identity, purity, and stability analyses were conducted on the final batch by the analytical chemistry laboratory at MRIGlobal (Kansas City, MO). Reports on analyses performed in support of the BPAF studies are on file at the National Institute of Environmental Health Sciences.

Lot 20100425 of BPAF used in this study was a white powder. The melting point of lot 20100425 was determined to be 162.9°C–163.9°C. The octanol/water partition coefficient (K_OW_) was determined to be 42,634 ± 21,044, which resulted in an average log P of 4.63.

The lot identity was confirmed using infrared (IR), ^1^H and ^13^C nuclear magnetic resonance (NMR), and ultraviolet/visible (UV/Vis) spectroscopies. The IR spectrum was in good agreement with the anticipated structure and the reference spectrum from the National Institute of Advanced Industrial Science and Technology (AIST) (Tokyo, Japan) Spectral Database for Organic Compounds (SDBS No. 21770) for BPAF (Figure A-1). ^1^H and ^13^C NMR spectra (Figure A-2, Figure A-3) were consistent with the anticipated structure and the reference spectrum from The Aldrich Library of ^13^C and ^1^H NMR Spectra Edition 1. The UV/Vis spectrum (Figure A-4) supported the structure and was consistent with the reference spectrum from Sadtler Research Laboratories (Philadelphia, PA) (22247 UV). In addition, direct infusion mass spectrometry (DIMS) and elemental analysis were performed to aid in identity confirmation. DIMS confirmed a molecular weight of 336 g/mol for lot 20100425. Elemental analysis was performed by ICON plc (formerly ICON Development Solutions, LLC, Whitesboro, NY). The relative amount of carbon (54.03%), hydrogen (2.94%), fluorine (33.79%), and nitrogen (0.35%) were within 2% of anticipated ratios.

The moisture content of lot 20100425 was determined by Karl Fisher titration. The purity of lot 20100425 was determined using differential scanning calorimetry (DSC) and high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection. In addition, headspace gas chromatography (GC/headspace) was performed to determine residual solvent content. Karl Fisher titration indicated a water content of 0.026 ± 0.005%. The DSC analysis yielded a purity of 100% with a melting point of 161.80°C. The HPLC/UV analysis demonstrated one major peak accounting for 99.86% and one minor peak accounting for 0.13% of the total integrated area (Table A-1, System A). The GC/headspace analysis indicated residual solvent peak responses for methanol, cis-1,2-dichloroethene, pyridine, and tetralin, but these were not present at levels greater than the corresponding peaks in the Class 2 standard mixtures (Table A-1, System B). The overall purity of lot 20100425 was determined to be >99.5%.

Accelerated stability studies were conducted on samples of BPAF stored protected from light in amber vials at frozen (−20°C), refrigerated (5°C), ambient (25°C), and elevated (60°C) conditions. After 2 weeks, samples were analyzed by HPLC/UV (Table A-1, System A). Stability of BPAF was confirmed for at least 2 weeks when stored in sealed glass vials at temperatures from −20°C to 60°C.

Periodic reanalysis of the bulk chemical performed by the study laboratory at RTI International (Research Triangle Park, NC) using HPLC/UV (Table A-1, System C) before, during, and after the animal studies showed no degradation relative to a frozen reference standard.

## A.2 Preparation and Analysis of Dose Formulations

Dose formulations were prepared monthly by mixing BPAF with 5K96 Verified Casein Diet feed (Table A-2). For the dose range-finding study, formulations were prepared at concentrations of 0, 937.5, 1,875, 3,750, 7,500, and 15,000 ppm (two sets, November and December 2012). The 15,000 ppm formulation was not prepared in December 2012 as the group was terminated early and the formulation was not required. For the modified one-generation study, formulations were prepared at concentrations of 0, 338, 1,125, and 3,750 ppm (11 sets, April to December 2013). The formulation set prepared on November 18, 2013, included only the 0 ppm formulation. Formulations were stored at approximately 5°C and were considered stable for up to 42 days.

Prior to study start, the homogeneity and stability of the formulations were determined by the analytical laboratory using HPLC/UV (Table A-1, System A). The method of preparation was validated for concentration ranges of approximately 200–10,000 ppm for BPAF in feed. High-dose method verification confirmed that formulations up to approximately 45,000 ppm can be diluted into the validated curve range. Additionally, the optimal extraction solvent was determined to be acidified acetonitrile (99:1, acetonitrile:acetic acid, v:v). Homogeneity was confirmed in 22 kg preparations of dose formulations at 250, 937.5, and 15,000 ppm. Homogeneity was confirmed in 37, 50, and 100 kg preparations of dose formulations at 338 and 3,750 ppm by the study laboratory using HPLC/UV (Table A-1, System C).

Stability of the 250 and 937.5 ppm formulations was confirmed for up to 42 days under refrigerated or frozen conditions while protected from light. A 7-day simulated dose study of the 250 and 937.5 ppm formulations was conducted to determine stability in animal room conditions. The formulations spiked with rodent urine and feces had a recovery of approximately 77% by day 7, when compared to the day 0 determined concentration. However, when samples from a 7-day simulated dose study of 937.5 ppm formulation spiked with rodent urine and feces were analyzed using an acid-digestion method, the recovery increased to 90.8%. These results indicate extensive reversible binding of BPAF to feed in the presence of rodent urine and feces and absence of chemical instability when mixed with feed. These results indicate that 5K96 Verified Casein Diet feed formulations containing BPAF are stable under dosing conditions for up to 7 days.

Analysis of pre- and postadministration dose formulations were conducted throughout the studies by the study laboratory using HPLC/UV (Table A-1, System C). Postadministration samples were collected from the animal room at the end of the exposure period. For the dose range-finding study, all dose formulations were analyzed pre- and postadministration (Table A-3). All preadministration samples were within 10% of the target concentration. Postadministration samples were between 70.0% and 93.6% of the target concentrations, with the 7,500 ppm formulation from December 10, 2012, being the only one within 10%. For the modified one-generation study, preadministration samples were analyzed four times over the course of the study, and postadministration samples were analyzed from the first and last formulations representing all four dose groups (Table A-4). All preadministration samples were within 10% of the target concentration. Postadministration samples were between 78.4% and 92.9% of the target concentrations, with the 338 ppm formulation from September 30, 2013, being the only one within 10%.

Table A-1 Chromatography Systems Used in the Modified One-Generation Study of Bisphenol AF

Chromatography | Detection System | Column | Mobile Phase
System A
High-performance liquid chromatography | Ultraviolet at 210 nm | Altima C-18, Alltech, 250 mm × 4.6 mm ID, 5 μm particle size | 60:40 acetonitrile:water, 1.0 mL/min flow rate
System B
Headspace gas chromatography | Flame ionization detection at 250°C | Restek, Rxi-624Sil MS, 30 m × 0.32 mm ID, 1.8 µm film thickness | Helium, 2.5 mL/min flow rate
System C
High-performance liquid chromatography | Ultraviolet at 274 nm | Altima C-18, Alltech, 250 mm × 4.6 mm ID, 5 μm particle size | 60:40 acetonitrile:water, 1.0 mL/min flow rate

ID = internal diameter.

Table A-2 Preparation and Storage of Dose Formulations in the Modified One-Generation Study of Bisphenol AF

Preparation
A premix of bisphenol AF (BPAF) (lot 20100425) and LabDiet 5K96 Verified Casein Diet feed was diluted with additional feed to reach the target concentration. To make the premix, an appropriate amount of LabDiet 5K96 Verified Casein Diet feed was weighed into a plastic bag. BPAF was weighed into a small container, then transferred into a large stainless-steel container followed by an equal amount of feed from the plastic bag. The contents of the container were thoroughly mixed with a spatula. The remaining feed was used to wash residual BPAF from the weighing container and sides of the stainless-steel mixing container. The contents were mixed thoroughly using the spatula between additions until all feed was incorporated into the premix. To prepare the formulations from the premix, LabDiet 5K96 Verified Casein Diet feed was weighed into a plastic bag. Feed was transferred to the bottom of an 8-quart twin shell blender. An appropriate amount of premix was added to the blender and also evenly distributed between ports. The remaining blank feed was used to rinse the premix container into the blender. The blender ports were sealed, and the formulation was blended for ~15 minutes using an intensifier bar for the first ~5 minutes.
Chemical Lot Number
20100425
Maximum Storage Time
42 days
Storage Conditions
Stored in sealed plastic bag-lined containers at 5°C (refrigerated)
Study Laboratory
RTI International (Research Triangle Park, NC)

Table A-3 Results of Analyses of Dose Formulations Administered to Rats in the Dose Range-finding Study of Bisphenol AF

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration (ppm)^a^ | Difference from Target (%)
November 12, 2012 | November 15–20, 2012 | 0 | BLOQ | NA
November 12, 2012 | November 15–20, 2012 | 937.5 | 980 | 5.0
November 12, 2012 | November 15–20, 2012 | 1,875 | 1,810 | −3.5
November 12, 2012 | November 15–20, 2012 | 3,750 | 3,590 | −4.3
November 12, 2012 | November 15–20, 2012 | 7,500 | 7,050 | −6.0
November 12, 2012 | November 15–20, 2012 | 15,000 | 14,500 | −3.3
December 10, 2012 | December 12–14, 2012 | 0 | BLOQ | NA
December 10, 2012 | December 12–14, 2012 | 937.5 | 860 | −8.3
December 10, 2012 | December 12–14, 2012 | 1,875 | 1,740 | −7.2
December 10, 2012 | December 12–14, 2012 | 3,750 | 3,470 | −7.5
December 10, 2012 | December 12–14, 2012 | 7,500 | 7,080 | −5.6
Animal Room Samples
November 12, 2012 | January 8–10, 2013 | 0 | BLOQ | NA
November 12, 2012 | January 8–10, 2013 | 937.5 | 799 | −14.8
November 12, 2012 | January 8–10, 2013 | 1,875 | 1,650 | −12.0
November 12, 2012 | January 8–10, 2013 | 3,750 | 3,030 | −19.2
November 12, 2012 | January 8–10, 2013 | 7,500 | 5,830 | −22.3
November 12, 2012 | January 8–10, 2013 | 15,000 | 10,500 | −30.0
December 10, 2012 | January 23–25, 2013 | 0 | BLOQ | NA
December 10, 2012 | January 23–25, 2013 | 937.5 | 673 | −28.2
December 10, 2012 | January 23–25, 2013 | 1,875 | 1,430 | −23.7
December 10, 2012 | January 23–25, 2013 | 3,750 | 3,140 | −16.3
December 10, 2012 | January 23–25, 2013 | 7,500 | 7,020 | −6.4

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Average of triplicate analyses.

Table A-4 Results of Analyses of Dose Formulations Administered to Rats in the Modified One-Generation Study of Bisphenol AF

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration (ppm)^a^ | Difference from Target (%)
April 29, 2013 | April 30, 2013 | 0 | BLOQ | NA
April 29, 2013 | April 30, 2013 | 338 | 305 | −9.8
April 29, 2013 | April 30, 2013 | 1,125 | 1,040 | −7.6
April 29, 2013 | April 30, 2013 | 3,750 | 3,500 | −6.7
July 15, 2013 | July 18, 2013 | 0 | BLOQ | NA
July 15, 2013 | July 18, 2013 | 338 | 322 | −4.7
July 15, 2013 | July 18, 2013 | 1,125 | 1,080 | −4.1
July 15, 2013 | July 18, 2013 | 3,750 | 3,580 | −4.5
September 30, 2013 | October 1–2, 2013 | 0 | BLOQ | NA
September 30, 2013 | October 1–2, 2013 | 338 | 315 | −6.8
September 30, 2013 | October 1–2, 2013 | 1,125 | 1,110 | −1.3
September 30, 2013 | October 1–2, 2013 | 3,750 | 3,810 | 2.0
December 16, 2013 | December 17–18, 2013 | 0 | BLOQ | NA
December 16, 2013 | December 17–18, 2013 | 338 | 324 | −4.1
December 16, 2013 | December 17–18, 2013 | 1,125 | 1,120 | −0.4
Animal Room Samples
April 29, 2013 | June 19–21, 2013 | 0 | BLOQ | NA
April 29, 2013 | June 19–21, 2013 | 338 | 296 | −12.4
April 29, 2013 | June 19–21, 2013 | 1,125 | 882 | −21.6
April 29, 2013 | June 19–21, 2013 | 3,750 | 2,950 | −21.3
September 30, 2013 | November 13–19, 2013 | 0 | BLOQ | NA
September 30, 2013 | November 13–19, 2013 | 338 | 314 | −7.1
September 30, 2013 | November 13–19, 2013 | 1,125 | 951 | −15.5
September 30, 2013 | November 13–19, 2013 | 3,750 | 3,050 | −18.7

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Average of triplicate analyses.

Figure A-1

Reference Infrared Absorption Spectrum of Bisphenol AF

Figure A-2

^1^H Nuclear Magnetic Resonance Spectrum of Bisphenol AF (Lot 20100425)

Figure A-3

^13^C Nuclear Magnetic Resonance Spectrum of Bisphenol AF (Lot 20100425)

Figure A-4

Ultraviolet/Visible Spectrum of Bisphenol AF (Lot 20100425)