# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2690-2052

DOI: https://doi.org/10.22427/NTP-DART-07

Report Series: NTP Developmental and Reproductive Toxicity Report Series

Report Series Number: 07

Official citation: National Toxicology Program (NTP). 2022. NTP developmental and reproductive toxicity technical report on the prenatal development studies of 2-((1-(4-phenoxyphenoxy)propan-2-yl)oxy)pyridine (CASRN 95737-68-1) in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats and New Zealand White (Hra:NZW SPF) rabbits. Research Triangle Park, NC: National Toxicology Program. DART Report 07.