# Peer Review

The National Toxicology Program (NTP) conducted a peer review of the draft NTP Developmental and Reproductive Toxicity Technical Report on the Prenatal Development Studies of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine (CASRN 95737-68-1) in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats and New Zealand White (Hra:NZW SPF) Rabbits by letter in April 2021 by the experts listed below. Reviewer selection and document review followed established NTP practices. The reviewers were charged to:

1. Peer review the draft Developmental and Reproductive Toxicity Technical Report on the Prenatal Development Studies of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine.
2. Comment on NTP’s interpretations of the data.

NTP carefully considered reviewer comments in finalizing this report.

## Peer Reviewers

- Christopher Bowman, Ph.D.
  Research Fellow, Developmental and Reproductive Toxicology
  Pfizer, Inc.
  Groton, Connecticut, USA
- Kimberley Treinen, Ph.D.
  Toxicology Consultant
  KT Toxicology and Drug Development LLC
  Hopkinton, Massachusetts, USA