# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Designed studies, evaluated and interpreted results, and reported findings
  B.S. McIntyre, Ph.D., Study Scientist
  M.V. Behl, Ph.D.
  C.R. Blystone, Ph.D.
  H.C. Cunny, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.K. Roberts, Ph.D.
  V.G. Robinson, M.S.
  K.R. Ryan, Ph.D.
  K.A. Shipkowski, Ph.D.
  K.R. Shockley, Ph.D.
  V.L. Sutherland, Ph.D.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
- Provided oversight for data management
  J.M. Fostel, Ph.D.
- Southern Research, Birmingham, Alabama, USA
  Conducted studies and evaluated fetal findings
  C.D. Hébert, Ph.D., Principal Investigator
  J.R. Furr, B.S.
- Conducted pilot toxicokinetic study in rats
  P.B. Bushdid, Ph.D.
  M.D. Merrell, Ph.D.
- RTI International, Research Triangle Park, North Carolina, USA
  Conducted prestart chemistry activities, dose formulations, and biological sample chemistry analyses
  R.A. Fernando, Ph.D., Principal Investigator
  J.C. Blake, B.A., Deputy Principal Investigator
  D.B. Browning, B.S.
  S.D. Cooper, M.S.
  M. Silinski, Ph.D.
- ASRC Federal, Research Triangle Park, North Carolina, USA
  Prepared data for report
  P. Brown, B.S.
  C. Martini, B.S.
  C. Myers, M.S.
  N. Sayers, B.S.