# References

1 National Center for Biotechnology Information (NCBI). PubChem Compound Summary for Pyriproxyfen. Bethesda, MD: National Center for Biotechnology Information; 2020. https://pubchem.ncbi.nlm.nih.gov/compound/91753
2 National Center for Biotechnology Information (NCBI). PubChem Pyriproxyfen: 8.3 USDA Pesticide Data Program. Bethesda, MD: National Center for Biotechnology Information; 2020. https://pubchem.ncbi.nlm.nih.gov/compound/Pyriproxyfen#section=USDA-Pesticide-Data-Program
3 U.S. Environmental Protection Agency (USEPA). Letter to Valent USA Corporation regarding label amendments. Washington, DC: U.S. Environmental Protection Agency, Office of Prevention Pesticides and Toxic Substances; 2012. https://www3.epa.gov/pesticides/chem_search/ppls/059639-00160-20120717.pdf
4 World Health Organization (WHO). Pyriproxyfen in drinking-water: Use for vector control in drinking-water sources and containers. 2008. https://www.who.int/water_sanitation_health/water-quality/guidelines/chemicals/pyriproxyfen-background.pdf?ua=1
5 Musso D, Gubler DJ. Zika virus. Clin Microbiol Rev. 2016; 29(3):487–524. 10.1128/CMR.00072-15 27029595
6 Baud D, Gubler DJ, Schaub B, Lanteri MC, Musso D. An update on Zika virus infection. Lancet. 2017; 390(10107):2099–2109. 10.1016/S0140-6736(17)31450-2 28647173
7 Code of Federal Regulations (CFR). 2002; 40(Part 180).
8 Red Universitaria de Ambiente y Salud (REDUAS). Report from physicians in the crop-sprayed town regarding Dengue-Zika, microcephaly, and massive spraying with chemical poisons. 2016. https://reduas.com.ar/report-from-physicians-in-the-crop-sprayed-town-regarding-dengue-zika-microcephaly-and-massive-spraying-with-chemical-poisons/
9 Reis V. Nota técnica sobre microcefalia e doenças vetoriais relacionadas ao Aedes aegypti: os perigos das abordagens com larvicidas e nebulizações químicas – fumacê. 2016. https://www.abrasco.org.br/site/outras-noticias/institucional/nota-tecnica-sobre-microcefalia-e-doencas-vetoriais-relacionadas-ao-aedes-aegypti-os-perigos-das-abordagens-com-larvicidas-e-nebulizacoes-quimicas-fumace/15929/
10 Parens R, Nijhout HF, Morales A, Xavier Costa F, Bar-Yam Y. A possible link between pyriproxyfen and microcephaly. PLoS currents. 2017; 9:ecurrents.outbreaks.5afb0bfb8cf31d39a34baba37b19b34edbac.
11 World Health Organization (WHO). Guidelines for drinking-water quality. Third edition incorporating the first and second addenda. Volume 1. Recommendations. Geneva; 2008.
12 Matsunaga H, Yoshino H, Isobe N, Kaneko H, Nakatsuka I, Yamada H. Metabolism of pyriproxyfen in Rats. 1. Absorption, disposition, excretion, and biotransformation studies with [phenoxyphenyl-14C]pyriproxyfen. J Agric Food Chem. 1995; 43(1):235–240. 10.1021/jf00049a042
13 Yoshino H, Kaneko H, Nakatsuka I, Yamada H. Metabolism of pyriproxyfen. 3. In vitro metabolism in rats and mice. J Agric Food Chem. 1996; 44(6):1578–1581. 10.1021/jf950510q
14 U.S. Environmental Protection Agency (USEPA). Data evaluation record: Sumilarv. Study type: Developmental toxicity study in rats (segments II and III). Washington, DC: U.S. Environmental Protection Agency, Office of Pesticide Programs, Health Effects Division; 1993. 68D10075. https://archive.epa.gov/pesticides/chemicalsearch/chemical/foia/web/pdf/129032/129032-018.pdf
15 U.S. Environmental Protection Agency (USEPA). Data evaluation record: Sumilarv technical. Study type: Reproductive toxicity. Washington, DC: U.S. Environmental Protection Agency, Office of Pesticide Programs, Health Effects Division; 1993. 68D10075. https://archive.epa.gov/pesticides/chemicalsearch/chemical/foia/web/pdf/129032/129032-021.pdf
16 U.S. Environmental Protection Agency (USEPA). Data evaluation report: Sumilarv (S-31183). Study type: Teratogenicity-developmental toxicity, rabbit. Washington, DC: U.S. Environmental Protection Agency, Office of Pesticide Programs, Health Effects Division; 1993. https://archive.epa.gov/pesticides/chemicalsearch/chemical/foia/web/pdf/129032/129032-015.pdf
17 U.S. Environmental Protection Agency (USEPA). Data evaluation report: Sumilarv (S-31183). Study type: Acute oral toxicity in rats. Washington, DC: U.S. Environmental Protection Agency, Office of Pesticide Programs, Health Effects Division; 1993. D179381. https://archive.epa.gov/pesticides/chemicalsearch/chemical/foia/web/pdf/129032/129032-009.pdf
18 U.S. Environmental Protection Agency (USEPA). Data evaluation report: Sumilarv (S-31183). Study type: Acute dermal toxicity in rats. Washington, DC: U.S. Environmental Protection Agency, Office of Pesticide Programs, Health Effects Division; 1993. D179381. https://archive.epa.gov/pesticides/chemicalsearch/chemical/foia/web/pdf/129032/129032-014.pdf
19 U.S. Environmental Protection Agency (USEPA). Data evaluation report: Sumilarv (S-31183). Study type: Acute inhalation toxicity in rats. Washington, DC: U.S. Environmental Protection Agency, Office of Pesticide Programs, Health Effects Division; 1993. D179381. https://archive.epa.gov/pesticides/chemicalsearch/chemical/foia/web/pdf/129032/129032-013.pdf
20 U.S. Environmental Protection Agency (USEPA). Data evaluation report: Sumilarv (S-31183). Study type: Eye irritation study in rabbits. Washington, DC: U.S. Environmental Protection Agency, Office of Pesticide Programs, Health Effects Division; 1993. D179381. https://archive.epa.gov/pesticides/chemicalsearch/chemical/foia/web/pdf/129032/129032-011.pdf
21 U.S. Environmental Protection Agency (USEPA). Data evaluation report: Sumilarv (S-31183). Study type: Skin irritation study in rabbits. Washington, DC: U.S. Environmental Protection Agency, Office of Pesticide Programs, Health Effects Division; 1993. D179381. https://archive.epa.gov/pesticides/chemicalsearch/chemical/foia/web/pdf/129032/129032-012.pdf
22 Suzuki T. Sumilarv - Skin sensitization test with S-31183 in Guinea pigs (Original report written in Japanese, translated by Takachi Suzuki, May 14, 1987). Japan: Ministry of Agriculture, Forestry and Fisheries; 1987. NNT-70-0022. https://archive.epa.gov/pesticides/chemicalsearch/chemical/foia/web/pdf/129032/129032-010.pdf
23 Code of Federal Regulations (CFR). Pyriproxyfen; Pesticide Tolerance. 1999; 40(Part 180).
24 U.S. Environmental Protection Agency (USEPA). Data evaluation report: Sumilarv (S-31183). Study type: Oncogenicity study, mouse. Washington, DC: U.S. Environmental Protection Agency, Office of Pesticide Programs, Health Effects Division; 1993. D176679. https://archive.epa.gov/pesticides/chemicalsearch/chemical/foia/web/pdf/129032/129032-020.pdf
25 U.S. Environmental Protection Agency (USEPA). Data evaluation report: Sumilarv (S-31183). Study type: Rat chronic feeding and oncogenicity-(83-5). Washington, DC: U.S. Environmental Protection Agency, Office of Pesticide Programs, Health Effects Division; 1993. https://archive.epa.gov/pesticides/chemicalsearch/chemical/foia/web/pdf/129032/129032-024.pdf
26 U.S. Environmental Protection Agency (USEPA). Data evaluation report: S-31183. Study type: Subchronic 90-day oral toxicity. U.S. Environmental Protection Agency, Office of Pesticide Programs, Health Effects Division; 1993. https://archive.epa.gov/pesticides/chemicalsearch/chemical/foia/web/pdf/129032/129032-008.pdf
27 U.S. Environmental Protection Agency (USEPA). Data evaluation report: S-31183. Study type: 90-day feeding studies-non-rodent. U.S. Environmnetal Protection Agency, Office of Pesticide Programs, Health Effects Division; 1993. https://archive.epa.gov/pesticides/chemicalsearch/chemical/foia/web/pdf/129032/129032-016.pdf
28 Chernoff N, Setzer RW, Miller DB, Rosen MB, Rogers JM. Effects of chemically induced maternal toxicity on prenatal development in the rat. Teratology. 1990; 42(6):651–658. 10.1002/tera.1420420610 2087686
29 U.S. Environmental Protection Agency (USEPA). Guidelines for developmental toxicity risk assessment. Washington, DC: U.S. Environmental Protection Agency, Risk Assessment Forum; 1991. EPA Document No. EPA/600/FR-91/001.
30 Tyl RW. Commentary on the role of maternal toxicity on developmental toxicity. Birth Defects Res B Dev Reprod Toxicol. 2012; 95(3):262–266. 10.1002/bdrb.21015 22706915
31 Organisation for Economic Cooperation and Development (OECD). OECD guideline for the testing of chemicals, test no. 44, prenatal developmental toxicity study. Paris, France: Organisation for Economic Co-operation and Development; 2001.
32 Makris SL, Solomon HM, Clark R, Shiota K, Barbellion S, Buschmann J, Ema M, Fujiwara M, Grote K, Hazelden KP. Terminology of developmental abnormalities in common laboratory mammals (version 2). Congenit Anom (Kyoto). 2009; 49(3):123–246. 10.1111/j.1741-4520.2009.00239.x 20002907
33 Suckow MA, Weisbroth S, Franklin C. The Laboratory Rat. Cambridge, MA: Academic Press; 2005.
34 Hayes AW, Kruger CL. Hayes’ Principles and Methods of Toxicology. Boca Raton, FL: CRC Press; 2014. 10.1201/b17359
35 Salewski E. Färbemethode Zum Makroskopischen Nachweis von Implantationsstellen am Uterus der Ratte. Naunyn Schmiedebergs Arch Exp Pathol Pharmakol. 1964; 247(4):367–367. 10.1007/BF02308461
36 Tyl RW, Marr MC. Developmental toxicity testing-Metholodogy In: Hood RD, editor. Developmental and Reproductive Toxicology A Practical Approach. 2006.
37 Staples RE. Detection of visceral alterations in mammalian fetuses. Teratology. 1974; 9(3):259–260. 4832056
38 Stuckhardt JL, Poppe SM. Fresh visceral examination of rat and rabbit fetuses used in teratogenicity testing. Teratog Carcinog Mutagen. 1984; 4(2):181–188. 10.1002/tcm.1770040203 6145223
39 Thompson RF. Foundations of Physiological Psychology. New York, NY: Harper and Row Publishers; 1967. Chapter 4, Basic neuroanatomy; p. 79–82.
40 Marr MC, Price CJ, Myers CB, Morrissey RE. Developmental stages of the CD® (Sprague-Dawley) rat skeleton after maternal exposure to ethylene glycol. Teratology. 1992; 46(2):169–181. 10.1002/tera.1420460210 1440420
41 Hirohashi A. Study of S-31183 by oral administration during the period of fetal organogenesis in rabbits. 1989. https://archive.epa.gov/pesticides/chemicalsearch/chemical/foia/web/pdf/129032/129032-015.pdf
42 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
43 Shirley E. A non-parametric equivalent of William’s test for contrasting increasing dose levels of treatment. Biometrics. 1977; 33:386–389. 10.2307/2529789 884197
44 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42:183–186. 10.2307/2531254 3719054
45 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
46 Jonckheere A. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41:133–145. 10.1093/biomet/41.1-2.133
47 Dixon WJ, Massey FJ Jr. Introduction to Statistical Analysis. New York, NY: McGraw-Hill Book Company, Inc; 1957. 10.2307/2332898
48 Tukey J. Exploratory Data Analysis. Reading, MA: Addison-Wesley; 1977. Easy summaries – numerical and graphical; p. 43–44.
49 Armitage P. Tests for linear trends in proportions and frequencies. Biometrics. 1955; 11(3):375–386. 10.2307/3001775
50 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
51 Kupper LL, Portier C, Hogan MD, Yamamoto E. The impact of litter effects on dose-response modeling in teratology. Biometrics. 1986; 42(1):85–98. 10.2307/2531245 3719065
52 Rao JN, Scott AJ. A simple method for the analysis of clustered binary data. Biometrics. 1992; 48(2):577–585. 10.2307/2532311 1637980
53 Fung KY, Krewski D, Rao JN, Scott AJ. Tests for trend in developmental toxicity experiments with correlated binary data. Risk Anal. 1994; 14(4):639–648. 10.1111/j.1539-6924.1994.tb00277.x 7972964
54 Code of Federal Regulations (CFR). 21(Part 58).
55 National Toxicology Program (NTP). DART-07: Developmental and Reproductive Toxicity: Growth and clinical finding tables (I), pathology tables (PA), developmental and reproductive tables (R) from NTP developmental and reproductive toxicity studies. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2020. 10.22427/NTP-DATA-DART-07
56 National Toxicology Program (NTP). Data release: Developmental neurotoxicity data integration and visualization enabling resource (DNT-DIVER). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health. 10.22427/NTP-DATA-002-00062-0001-0000-1 [Last updated: 12/3/2018]
57 Padilla S, Corum D, Padnos B, Hunter DL, Beam A, Houck KA, Sipes N, Kleinstreuer N, Knudsen T, Dix DJ, et al. Zebrafish developmental screening of the ToxCast™ Phase I chemical library. Reprod Toxicol. 2012; 33(2):174–187. 10.1016/j.reprotox.2011.10.018 22182468
58 Truong L, Gonnerman G, Simonich MT, Tanguay RL. Assessment of the developmental and neurotoxicity of the mosquito control larvicide, pyriproxyfen, using embryonic zebrafish. Environ Pollut. 2016; 218:1089–1093. 10.1016/j.envpol.2016.08.061 27593350
59 National Toxicology Program (NTP). Screen for developmental toxicity in zebrafish-study 1. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health. 10.22427/NTP-DATA-002-00077-0001-0000-7 [Last updated April 23, 2020]
60 Enomoto M, Pan H, Suzuki F, Takigawa M. Physiological role of vitamin A in growth cartilage cells: Low concentrations of retinoic acid strongly promote the proliferation of rabbit costal growth cartilage cells in culture. J Biochem. 1990; 107(5):743–748. 10.1093/oxfordjournals.jbchem.a123119 2398039
61 Enomoto M, Kinoshita A, Pan HO, Suzuki F, Yamamoto I, Takigawa M. Demonstration of receptors for parathyroid hormone on cultured rabbit costal chondrocytes. Biochem Biophys Res Commun. 1989; 162(3):1222–1229. 10.1016/0006-291X(89)90804-8 2548491
62 Takigawa M, Enomoto M, Shirai E, Nishii Y, Suzuki F. Differential effects of 1 alpha,25-dihydroxycholecalciferol and 24R,25-dihydroxycholecalciferol on the proliferation and the differentiated phenotype of rabbit costal chondrocytes in culture. Endocrinology. 1988; 122(3):831–839. 10.1210/endo-122-3-831 3257732
63 The DevTox Project. DevTox.Nomenclature. Berlin, Germany: German Federal Institute for Risk Assessment (BfR); 2012. https://www.devtox.org/nomenclature/ml_organ.php?lan=en
64 Charles River. Historical control data in New Zealand white rabbits. 2017. https://www.criver.com/sites/default/files/noindex/historical-control-data/embryo-fetal-hcd-ashland-rabbits.pdf
65 LabDiet. Certified high fiber rabbit diet. 2012. http://www.labsupplytx.com/wp-content/uploads/2013/07/5325-Certified-High-Fiber-Rabbit-Diet.pdf
66 Nishimura Y, Inoue A, Sasagawa S, Koiwa J, Kawaguchi K, Kawase R, Maruyama T, Kim S, Tanaka T. Using zebrafish in systems toxicology for developmental toxicity testing. Congenit Anom (Kyoto). 2016; 56(1):18–27. 10.1111/cga.12142 26537640
67 Lieschke GJ, Currie PD. Animal models of human disease: Zebrafish swim into view. Nat Rev Genet. 2007; 8(5):353–367. 10.1038/nrg2091 17440532
68 Dzieciolowska S, Larroque AL, Kranjec EA, Drapeau P, Samarut E. The larvicide pyriproxyfen blamed during the Zika virus outbreak does not cause microcephaly in zebrafish embryos. Sci Rep. 2017; 7:40067. 10.1038/srep40067 28051181
69 Quevedo C, Behl M, Ryan K, Paules RS, Alday A, Muriana A, Alzualde A. Detection and prioritization of developmentally neurotoxic and/or neurotoxic compounds using zebrafish. Toxicol Sci. 2019; 168(1):225–240. 10.1093/toxsci/kfy291 30521027