# Conclusions

Under the conditions of the rat prenatal developmental toxicity study, there was no evidence of developmental toxicity of 2-((1-(4-phenoxyphenoxy)propan-2-yl)oxy)pyridine (MPEP) in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats administered 62.5, 125, 250, or 500 mg/kg/day based on the absence of effects on reproductive parameters, fetal weight, or increased incidence of fetal malformations or variations. The highest dose administered was 500 mg/kg/day, which did not result in overt maternal toxicity.

Under the conditions of the rabbit prenatal developmental toxicity study, there was equivocal evidence of developmental toxicity of MPEP in New Zealand White (Hra:NZW SPF) rabbits based on the occurrence of the malformation “seventh costal cartilage not fused to sternum” in dosed groups. This finding was observed at 250 mg/kg/day, a dose that induced some maternal toxicity.