# Discussion

2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine (MPEP) is an insecticide that acts as a juvenile insect hormone analog and growth regulator, preventing insect larvae from developing into adults and rendering them unable to reproduce. MPEP can be formulated into a variety of dispersant products for both home and agricultural use.^2,3^ Adding MPEP to potable water in cisterns/barrels was approved by the World Health Organization in 2008 to control mosquito populations in Zika virus-endemic areas.^4^ Although prenatal toxicity studies were conducted using experimental animals by the insecticide’s sponsoring manufacturer for marketing approval, and these were considered acceptable by governmental health authorities and showed no apparent hazard,^4,7^ the public has expressed concern that human exposure to MPEP during pregnancy could contribute to the cranial malformations observed in babies born to women infected with the Zika virus. Prenatal toxicology study results that might inform public health decisions were not available in the public domain. Given this knowledge gap, the National Toxicology Program (NTP) initiated a series of studies to inform potential human hazard.

NTP conducted prenatal developmental toxicity studies with MPEP in two mammalian species, Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats and New Zealand White (Hra:NZW SPF) rabbits, to investigate the possibility that MPEP exposure might induce skeletal malformations. The potential for MPEP to induce external and visceral variations and malformations also was assessed. In parallel, plasma MPEP concentrations in pregnant rats and rabbits and fetuses of both species were determined.

Dose selection for the rat prenatal developmental toxicity study was partially informed by the U.S. Environmental Protection Agency’s summary of the manufacturer’s submission data, which indicated effects on maternal body weight at 300 mg MPEP/kg body weight/day (mg/kg/day) and mortality at 1,000 mg/kg/day MPEP. The current high dose of 500 mg/kg/day was half the dose associated with mortality, and the current 250 mg/kg/day dose was comparable to the dose that reduced maternal body weight. MPEP was well tolerated by the dams, which allowed for the complete evaluation of embryo-fetal development. The high dose of 500 mg/kg/day was associated with a transient decrease in maternal body weight gain and feed consumption after dose initiation, demonstrating some minimal maternal toxicity. Higher dose levels would likely have induced greater effects on body weight that could result in nonspecific fetal toxicity. Exposure to MPEP did not affect any pregnancy or litter parameters. Fetal weight trended lower with increasing dose; however, the effect in the 500 mg/kg/day group was minimal (<4%) and was associated with a slight increase in litter size. The trend in decreasing fetal weights was not associated with an increase in skeletal variants, a relational response that is often observed, indicating that this decrease in weight was likely spurious.

Fetal rat visceral findings included minimal higher incidences of liver variations, including additional fissures and discoloration. Fissures were observed in the left lateral, left medial, and right medial lobes of the liver, and, when combining all locations, no apparent effect of MPEP exposure on the incidence was observed. The combined incidence was similar to what had been observed in control groups. These data indicate that the apparent higher incidence of liver lobe fissures in the 500 mg/kg/day group was likely incidental and not attributed to MPEP exposure.

Liver discoloration, a variation, was observed in the left medial and left lateral lobes of several fetuses from different litters in the 250 and 500 mg/kg/day groups; this variation was also observed in one fetus in the 125 mg/kg/day group. Discoloration was not coincident with the presence of fissures. Liver lobe discoloration could be an incidental finding but may be an indirect effect of MPEP on fetal liver metabolism, or organ insult. Unlike the increased incidences of cervical vertebra findings that were reported in the manufacturer’s study,^41^ the incidences of cervical vertebrae malformations in the current study were lower in the MPEP-exposed groups than in the control group.

Dose range-finding and prenatal developmental toxicity studies were performed in the rabbit to determine whether MPEP induced malformations or variations in a second mammalian species. In the dose range-finding study, overt maternal toxicity was observed in the 400 and 500 mg/kg/day dose groups, resulting in those groups being removed from the study. A lower prevalence of moribundity/morbidity was observed in the 300 mg/kg/day dose group. Uterine and fetal weights were slightly lower in the 300 mg/kg/day dose group relative to the vehicle control group, but the minimal response could have been secondary to maternal toxicity. No external or placental observations were attributed to MPEP exposure. A high dose of 250 mg/kg/day was therefore selected for the prenatal developmental toxicity study to ensure sufficient challenge to the doe to increase identification of fetal alteration if present.

The dose of 250 mg/kg/day was generally well tolerated by most does, but a limited number in this group exhibited unacceptably lower body weight and feed consumption, resulting in three animals being removed from the study. Two does in the 250 mg/kg/day dose group delivered prior to necropsy. The five early removals and two nonpregnant does collectively resulted in 16 litters being available for examination. Litter size, postimplantation loss, and fetal weight were not affected by MPEP exposure. The findings indicate that the 250 mg/kg/day dose resulted in some limited maternal toxicity, thus the does and fetuses received the highest dose possible without affecting apical indictors of nonspecific, maternally induced, fetal toxicity.

Fetuses exposed to 125 and 250 mg/kg/day MPEP displayed a higher incidence in costal seventh cartilage not fused to sternum (malformation). The absence of this cartilaginous structure in the rabbit could be a developmental delay resulting from localized changes in chondrocyte proliferation.^60-62^ Feed consumption by, and mean body weight gains of, these does were similar to does for which fetuses did not display the malformation, suggesting that this finding is not the result of maternal toxicity. This structural defect is recognized by the International Federation of Teratology Societies.^32,63^ This finding is not specifically listed in the publicly available New Zealand White rabbit historical control data from Charles River’s commercial contract laboratories; however, the malformation “costal cartilage anomaly” has been observed at a very low incidence in control animals (17/15,511 [fetuses]; 13/1,759 [litters]).^64^ These marginal effects, which may or may not be related to MPEP exposure, are considered equivocal evidence of developmental toxicity.

MPEP concentrations were measured in both maternal and fetal samples in rats and rabbits following exposure to MPEP. In rats, maternal MPEP concentrations in plasma were 91- and 26-fold higher and fetal concentrations were 13- and 6-fold higher than those in rabbits for the 62.5 and 250 mg/kg/day groups, respectively. In rats, fetal plasma concentrations were 18%–26% of the concentrations in dams suggesting moderate gestational transfer of MPEP. Unlike rats, fetal concentrations in rabbits were similar to maternal concentrations demonstrating considerable transfer of MPEP from does to fetuses. The increase in MPEP concentration in fetuses was minimal between 125 and 250 mg/kg groups and may be a plausible explanation for similar fetal malformations observed between the groups. MPEP was observed in matrices from vehicle control groups. However, the concentrations of MPEP in the rat feed used in these studies were confirmed to be below the limit of quantitation of the feed analysis method of 0.01 mg/kg feed; MPEP concentrations were not measured in the rabbit feed. Therefore, potential low-level exposure of study animals to MPEP via feed cannot be ascertained. In rats, the MPEP concentration in control fetuses was much higher than that in respective dams, whereas in the dosed groups the reverse was observed, suggesting that the concentration of MPEP observed in control groups was mostly introduced poststudy during sample preparation and analysis. In rabbits, the MPEP concentration in fetuses and does was similar across the control and dosed groups, suggesting potential low-level exposure to MPEP or related compounds. Current EPA individual tolerances for MPEP present in non-grass animal feed range from 0.7 to 2.0 ppm; therefore the presence of MPEP in control animal samples is not unexpected.

Microcephaly was observed in the NTP zebrafish model; however, this finding is possibly coincidental with yolk sac anomalies and should not be considered informative on potential human hazard. The log K_OW_ of MPEP is >5, suggesting that it can bioaccumulate in the lipids in the egg yolk, resulting in much higher exposures of zebrafish embryos than would be expected in placental mammals.

Collectively, the rat and rabbit fetal examination data do not suggest that MPEP is teratogenic in mammals, although it does induce morphological alterations in zebrafish embryos. Thus, the results of these rat and rabbit studies do not support the hypothesis that MPEP is the direct cause of the microcephaly observed in Zika virus-endemic areas in which MPEP is used as an insecticide to control mosquito populations. The difference between the zebrafish findings and the findings in rats and rabbits suggests potential species differences between lower vertebrate models and more established vertebrate models used to assess human-relevant outcomes. The results in zebrafish could suggest that microcephaly may be a common chemical-mediated response in embryonic zebrafish screening assays and not entirely MPEP specific.