# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-DART-07.^55^

## Prenatal Developmental Toxicity Study in Rats

### Maternal Findings

#### Viability and Clinical Observations

All rats survived until study termination with the exception of one rat removed early due to a dose administration error (Table 3). No clinical observations were attributed to 2-((1-(4-phenoxyphenoxy)propan-2-yl)oxy)pyridine (MPEP) administration (Appendix F). Red vaginal discharge was observed in one dam in the 125 mg MPEP/kg body weight/day (mg/kg/day) on gestation day (GD) 19 and at necropsy on GD 21; the same dam exhibited nidation sites after uterine staining. Given the singular incidence and no effect on mean postimplantation loss, this observation was considered an incidental response. One dam in the 500 mg/kg/day dose group delivered prior to scheduled necropsy on GD 21.

Table 3 Summary of Maternal Disposition of Rats in the Prenatal Developmental Toxicity Gavage Study of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

| 0 mg/kg/day | 62.5 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day | 500 mg/kg/day
Time-mated Females^a^ | 25 | 25 | 25 | 25 | 25
Accidental Death^b^ | 0 | 0 | 1 | 0 | 0
Delivered Early | 0 | 0 | 0 | 0 | 1
Pregnant (on GD 21)^a^ | 23 | 20 | 22 | 20 | 22
Nonpregnant (on GD 21) | 2 | 5 | 2 | 5 | 2

GD = gestation day.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^b^ Dosing accident.

#### Body Weights and Feed Consumption

A significant decrease in mean body weight gain (22%–28%) relative to the vehicle control group was observed in the 250 and 500 mg/kg/day dose groups over the GD 6–9 interval. Subsequent mean body weights and body weight gains of the MPEP dose groups were similar to those of the vehicle control group (Table 4; Figure 4). No MPEP-related effect on GD 6–21 mean body weight or body weight gains adjusted for gravid uterine weight (at necropsy) was observed. Daily mean body weights and body weight gains of dams in each dose group are available in Appendix F.

Table 4 Summary of Maternal Mean Body Weight Gains of Rats in the Prenatal Developmental Toxicity Gavage Study of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

Gestation Day Interval^a,b^ | 0 mg/kg/day | 62.5 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day | 500 mg/kg/day
6–21 | 145.6 ± 4.1 (23) | 147.2 ± 3.1 (20) | 137.2 ± 7.5 (22) | 137.0 ± 5.6 (20) | 145.0 ± 4.3 (22)
3–6 | 14.9 ± 0.8 (23) | 15.3 ± 1.0 (20) | 13.4 ± 1.2 (22) | 13.9 ± 1.0 (20) | 15.4 ± 0.6 (23)
6–9 | 13.0 ± 0.9** (23) | 11.3 ± 0.7 (20) | 11.1 ± 0.6 (22) | 9.4 ± 1.0** (20) | 10.2 ± 1.0** (23)
9–12 | 17.0 ± 0.8 (23) | 14.9 ± 0.8 (20) | 15.6 ± 0.6 (22) | 16.5 ± 1.0 (20) | 15.4 ± 0.9 (23)
12–15 | 20.1 ± 1.4 (23) | 22.1 ± 0.7 (20) | 19.7 ± 1.6 (22) | 17.3 ± 1.3 (20) | 22.3 ± 1.4 (23)
15–18 | 43.5 ± 1.5 (23) | 43.7 ± 1.2 (20) | 40.8 ± 3.0 (22) | 42.5 ± 1.8 (20) | 46.0 ± 1.9 (23)
18–21 | 51.9 ± 1.6 (23) | 55.2 ± 2.1 (20) | 50.0 ± 3.0 (22) | 51.4 ± 2.4 (20) | 51.2 ± 2.1 (22)

Statistical significance for a dose group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

^a^ Body weight gains for pregnant animals are given in grams. Data are displayed as mean ± standard error (number of dams).

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

Figure 4

Maternal Growth Curves for Pregnant Rats Administered 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine by Gavage in the Prenatal Developmental Toxicity Study

Information for statistical significance in maternal weights is provided in Table 4 and Appendix F.

A concomitant dose-related decrease (~11%) in maternal feed consumption was observed in the 500 mg/kg/day dose group over the GD 6–9 interval (Table 5). Feed consumption by the 500 mg/kg/day dose group was generally higher, relative to the vehicle control group, over subsequent intervals; however, feed consumption by this group over the GD 6–21 interval was similar to that by the vehicle control group.

Table 5 Summary of Maternal Feed Consumption of Rats in the Prenatal Developmental Toxicity Gavage Study of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

Gestation Day Interval^a,b^ | 0 mg/kg/day | 62.5 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day | 500 mg/kg/day
6–21 | 21.7 ± 0.3 (23) | 22.0 ± 0.3 (20) | 21.5 ± 0.3 (22) | 21.8 ± 0.4 (20) | 22.2 ± 0.4 (23)
3–6 | 18.6 ± 0.3 (23) | 19.4 ± 0.3 (20) | 18.5 ± 0.3 (22) | 18.6 ± 0.4 (20) | 19.0 ± 0.4 (23)
6–9 | 18.4 ± 0.3** (23) | 18.2 ± 0.3 (20) | 17.7 ± 0.3 (22) | 17.7 ± 0.6 (20) | 16.4 ± 0.4** (23)
9–12 | 19.3 ± 0.3 (23) | 19.5 ± 0.4 (20) | 18.9 ± 0.3 (22) | 18.7 ± 0.4 (20) | 19.0 ± 0.5 (23)
12–15 | 20.5 ± 0.4 (23) | 20.9 ± 0.4 (20) | 20.1 ± 0.5 (22) | 20.3 ± 0.4 (20) | 21.1 ± 0.4 (23)
15–18 | 24.1 ± 0.3* (23) | 24.5 ± 0.4 (20) | 24.1 ± 0.6 (22) | 24.6 ± 0.6 (20) | 26.2 ± 0.6* (23)
18–21 | 26.1 ± 0.4** (23) | 27.1 ± 0.5 (20) | 26.6 ± 0.6 (22) | 27.6 ± 0.5* (20) | 28.2 ± 0.8** (23)

Statistical significance for a dose group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Feed consumption for pregnant animals is given in grams per day. Data are displayed as mean ± standard error (number of dams).

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

### Maternal and Litter Observations

No gross observations at necropsy were related to MPEP administration (Appendix F). No effects of MPEP administration were observed on the numbers of resorptions or live fetuses (Table 6).

Table 6 Summary of Uterine Content Data for Female Rats in the Prenatal Developmental Toxicity Gavage Study of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

| 0 mg/kg/day | 62.5 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day | 500 mg/kg/day
Pregnancy Summary
Mated Females^a^ | 25 | 25 | 25 | 25 | 25
Pregnant Females^a^ | 23 | 20 | 22 | 20 | 23
Pregnant Females Examined on GD 21^a^ | 23 | 20 | 22 | 20 | 22
Corpora Lutea per Female^b,c^ | 17.65 ± 0.70 (23) | 17.30 ± 0.54 (20) | 16.95 ± 0.53 (21)^d^ | 17.65 ± 0.73 (20) | 18.27 ± 0.72 (22)
Implantations per Female^b,c^ | 14.70 ± 0.68 (23) | 14.85 ± 0.53 (20) | 13.59 ± 0.88 (22) | 13.85 ± 0.75 (20) | 14.91 ± 0.57 (22)
Percent Postimplantation Loss^b,c^ | 6.90 ± 1.74 (23) | 3.80 ± 1.09 (20) | 8.58 ± 4.91 (22) | 4.22 ± 1.10 (20) | 3.10 ± 1.11 (22)
Total Resorptions per Litter^b,c^ | 1.04 ± 0.26 (23) | 0.50 ± 0.15 (20) | 0.41 ± 0.13 (22) | 0.60 ± 0.13 (20) | 0.45 ± 0.16 (22)
Early Resorptions per Litter^b,c^ | 1.00 ± 0.25 (23) | 0.45 ± 0.14 (20) | 0.41 ± 0.13 (22) | 0.55 ± 0.14 (20) | 0.36 ± 0.14 (22)
Late Resorptions per Litter^b,c^ | 0.04 ± 0.04 (23) | 0.05 ± 0.05 (20) | 0.00 ± 0.00 (22) | 0.05 ± 0.05 (20) | 0.09 ± 0.06 (22)
Dead Fetuses per Litter^b,c^ | 0.00 ± 0.00 (23) | 0.05 ± 0.05 (20) | 0.00 ± 0.00 (22) | 0.00 ± 0.00 (20) | 0.00 ± 0.00 (22)
Number of Early Resorptions^e^ | 23 | 9 | 9 | 11 | 8
Number of Late Resorptions^e^ | 1 | 1 | 0 | 1 | 2
Number of Dead Fetuses^e^ | 0 | 1 | 0 | 0 | 0
Number of Whole Litter Resorptions^a^ | 0 | 0 | 1 | 0 | 0
Live Fetuses^c^
Number of Live Fetuses | 314 | 286 | 290 | 265 | 318
Live Fetuses per Litter^b^ | 13.65 ± 0.68 (23) | 14.30 ± 0.55 (20) | 13.81 ± 0.74 (21) | 13.25 ± 0.73 (20) | 14.45 ± 0.58 (22)
Live Male Fetuses per Litter^b^ | 7.35 ± 0.44 (23) | 7.25 ± 0.56 (20) | 6.71 ± 0.48 (21) | 6.55 ± 0.54 (20) | 7.45 ± 0.46 (22)
Live Female Fetuses per Litter^b^ | 6.30 ± 0.56 (23) | 7.05 ± 0.48 (20) | 7.45 ± 0.41 (20)^f^ | 6.70 ± 0.60 (20) | 7.00 ± 0.52 (22)
Percent Live Male Fetuses per Litter^b^ | 55.12 ± 2.77 (23) | 49.97 ± 3.41 (20) | 50.80 ± 3.53 (21) | 49.87 ± 3.37 (20) | 52.27 ± 2.70 (22)
Fetal Weight (g)^b,g^
Fetal Weight per Litter | 5.35 ± 0.05* (23) | 5.33 ± 0.05 (20) | 5.43 ± 0.13 (21) | 5.26 ± 0.06 (20) | 5.17 ± 0.06 (22)
Male Weight per Litter | 5.47 ± 0.06* (23) | 5.47 ± 0.05 (20) | 5.58 ± 0.12 (21) | 5.39 ± 0.06 (20) | 5.29 ± 0.06 (22)
Female Weight per Litter | 5.21 ± 0.05* (23) | 5.19 ± 0.06 (20) | 5.17 ± 0.04 (20)^f^ | 5.13 ± 0.06 (20) | 5.02 ± 0.06* (22)
Gravid Uterine Weight (g)^b,g^
Gravid Uterine Weight | 98.91 ± 4.44 (23) | 103.39 ± 3.26 (20) | 99.80 ± 4.97 (21) | 94.33 ± 4.80 (20) | 102.13 ± 3.75 (22)
Terminal Body Weight | 387.8 ± 5.1 (23) | 390.3 ± 4.1 (20) | 383.7 ± 5.6 (21) | 379.8 ± 6.0 (20) | 386.5 ± 5.4 (22)
Adjusted Body Weight^h^ | 288.89 ± 3.42 (23) | 286.94 ± 2.89 (20) | 283.88 ± 3.33 (21) | 285.47 ± 3.14 (20) | 284.38 ± 2.71 (22)

Statistical significance for a dose group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

GD = gestation day.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^b^ Data are reported per litter as mean ± standard error (n) and do not include nonpregnant animals or those that did not survive to study termination.

^c^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^d^ One dam had total litter resorption and was excluded from analysis.

^e^ No statistical analyses performed on number of early resorptions, number of late resorptions, or number of dead fetuses.

^f^ One dam had an all-male litter and was excluded from female-only fetal endpoint calculations.

^g^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^h^ Adjusted body weight = terminal body weight minus gravid uterine weight.

Male and female fetal weights in the 500 mg/kg/day group were slightly lower (<4%) than those of the vehicle control groups (significant trend and pairwise for female weight). This observation was associated with a slightly higher live litter size (approximately one fetus). Gravid uterine weight was not affected by MPEP exposure (Table 6). These apparent minimal responses were not considered adverse and were likely spurious.

### Fetal Findings

#### External

No external malformations or variations were attributed to MPEP exposure at 62.5, 125, 250, or 500 mg/kg/day (Appendix F). External findings in exposed rat fetuses were limited to a singular occurrence of subcutaneous hemorrhage in the 250 mg/kg/day group and singular occurrences of thread-like tail in the 125 and 250 mg/kg/day groups; those occurrences were considered unrelated to MPEP exposure.

#### Visceral

No visceral malformations were attributed to MPEP exposure (Table 7; Appendix F). Singular incidences of misshapen liver lobes, a malformation, were observed in two litters in the 500 mg/kg/day group, one left lateral lobe and one left medial lobe. All groups, including the vehicle control group, displayed a low incidence of the malformation misshapen aortic valve. The malformation hemorrhagic stomach was observed at a singular incidence in two litters in the 250 mg/kg/day exposure group. Other malformations included a singular incidence of retroesophageal aortic arch (250 mg/kg/day), absent left subclavian artery (250 mg/kg/day), absent right subclavian artery (vehicle control group), malpositioned testis (62.5 mg/kg/day), hydronephrosis (62.5 mg/kg/day), and misshapen renal capsule (500 mg/kg/day). Hemorrhagic testes (one in the vehicle control group, two and three—all from different litters—in the 62.5 and 250 mg/kg/day groups, respectively) were also observed.

Table 7 Summary of Select Fetal Visceral Findings in Rats in the Prenatal Developmental Toxicity Gavage Study of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

| 0 mg/kg/day | 62.5 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day | 500 mg/kg/day
Total Number of Fetuses | 314 | 286 | 290 | 265 | 318
Number of Fetuses Examined | 314 | 286 | 290 | 265 | 318
Number of Litters Examined | 23 | 20 | 21 | 20 | 22
Abdominal Viscera^a,b^
Liver lobe, left lateral, misshapen – [M]^c^
Fetuses | 0 (0.00) | 0 (0.00) | 0 (0.00) | 0 (0.00) | 1 (0.31)
Litters | 0 (0.00) | 0 (0.00) | 0 (0.00) | 0 (0.00) | 1 (4.55)
Liver lobe, left medial, misshapen – [M]^c^
Fetuses | 0 (0.00) | 0 (0.00) | 0 (0.00) | 0 (0.00) | 1 (0.31)
Litters | 0 (0.00) | 0 (0.00) | 0 (0.00) | 0 (0.00) | 1 (4.55)
Liver lobe, discolored – [V]^c^
Fetuses | 0 (0.00) | 0 (0.00) | 1 (0.34) | 4 (1.51) | 3 (0.94)
Litters | 0 (0.00) | 0 (0.00) | 1 (4.76) | 3 (15.00) | 2 (9.09)
Liver lobe, left lateral, additional fissure – [V]^c^
Fetuses | 0 (0.00) | 6 (2.10) | 4 (1.38) | 2 (0.75) | 7 (2.20)
Litters | 0 (0.00) | 5 (25.00) | 3 (14.29) | 2 (10.00) | 2 (9.09)
Liver lobe, left medial, additional fissure – [V]^c^
Fetuses | 4 (1.27)) | 1 (0.35) | 1 (0.34) | 0 (0.00) | 1 (0.31)
Litters | 4 (17.39) | 1 (5.00) | 1 (4.76) | 0 (0.00) | 1 (4.55)
Liver lobe, right medial, additional fissure – [V]^d^
Fetuses | 0 (0.00) | 0 (0.00) | 0 (0.00) | 0 (0.00) | 1 (0.31)
Litters | 0 (0.00) | 0 (0.00) | 0 (0.00) | 0 (0.00) | 1 (4.55)
Liver lobe, additional fissure – [V]^d^
Fetuses | 4 (1.27) | 7 (2.45) | 5 (1.72) | 2 (0.75) | 8 (2.52)
Litters | 4 (17.39) | 5 (25.00) | 4 (19.05) | 2 (10.00) | 3 (13.64)

[M] = malformation; [V] = variation.

^a^ Upper row denotes number of affected fetuses (%) and lower row the number of affected litters (%).

^b^ Statistical analysis for fetal data including litter effects performed using a Rao-Scott modification to the Cochran-Armitage test where the litter was the random effect for both trend and pairwise analyses. No statistically significant trends or pairwise comparisons were observed.

^c^ Historical incidence for prenatal developmental toxicity gavage studies: fetuses – 0/1,326 (0%); litters – 0/104 (0%).

^d^ Historical incidence for prenatal developmental toxicity gavage studies: fetuses – 1/1,326 (0%); litters – 1/104 (0%).

An increased incidence of discolored liver lobe, a variation, in fetuses exposed to 125 mg/kg/day or greater (fetal incidence of 0.34% to 1.51%; litter incidence of 4.76% to 15%; Table 7) was observed. This finding was not observed in the vehicle control group or historical control groups and is likely the result of fetal liver metabolism of MPEP. All MPEP-exposed groups displayed an increase in the incidence of an additional fissure in the left lateral lobe of the liver; however, that finding had been observed in vehicle control groups. When all the common liver fissure variants were combined, no dose-response relationship was observed, and the fetal and litter incidences in the MPEP-exposed groups were similar to those in the vehicle control group. Although some litters had fetuses with both fissures and lobe discoloration, the incidence was too low to demonstrate any direct association (Appendix F).

#### Head

No visible head lesions in any of the exposure groups were observed (Appendix F).

#### Skeletal

MPEP exposure was not associated with increased incidences of any skeletal malformations or variations (Appendix F).

### Internal Dose Assessment

On GD 18, dam plasma, amniotic fluid (pooled by litter), and fetuses from the 0, 62.5, and 250 mg/kg/day groups were analyzed for MPEP concentrations. MPEP concentrations in dam plasma increased less than proportionally with increasing dose. MPEP was measured in fetuses and was 18%–26% of that in dam plasma, suggesting low to moderate gestational transfer of MPEP in rats. MPEP was observed in dam plasma (3.5 ng/mL) and fetuses (~50 ng/mL) from vehicle control groups (Table 8). Although the concentration in dam plasma was similar to the background concentrations observed in control rat plasma matrices used in analytical method development, the fetal concentrations were approximately 10-fold higher than the concentrations in the corresponding control fetal homogenate matrix.

Table 8 Summary of Internal Dose Data for Rats in the Prenatal Developmental Toxicity Gavage Study of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

| 0 mg/kg/day | 62.5 mg/kg/day | 250 mg/kg/day
n | 3^a^ | 4 | 3^b^
MPEP Concentration^c,d^
Gestation Day 18
Dam plasma (ng/mL)^e^ | 3.5 ± 2.0 | 4,807.5 ± 835.7* | 5,406.7 ± 3,783.3
Amniotic fluid (mg/mL) | BD^f^ | 123.0 ± 23.9 | 163.1 ± 40.8
Pooled fetal (ng/g)^e,g^ | 50.5 ± 19.5* | 862.8 ± 119.5 | 1,418.3 ± 665.7

Statistical significance for a dose group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

MPEP = 2-((1-(4-phenoxyphenoxy)propan-2-yl)oxy)pyridine; BD = below detection; group did not have over 20% of its values above the limit of detection.

^a^ One dam in the 0 mg/kg/day dose group was excluded from all data due to implausible values.

^b^ One animal was not pregnant. Calculated values do not include nonpregnant animals.

^c^ Data are presented as mean ± standard error.

^d^ If over 20% of the animals in a group were above the limit of detection (LOD), one-half of the LOD value was substituted for values below the LOD.

^e^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^f^ When the vehicle control group did not have over 20% of its values above the LOD, no mean or standard error was calculated, and no statistical analysis was performed.

^g^ n = 43–59 fetuses per exposure group (12–18 individual fetuses from each of the three dams per dose group).

## Dose Range-finding Study in Rabbits

### Maternal Findings

#### Viability and Clinical Observations

Rabbits dosed with 500 mg/kg/day MPEP displayed body weight loss over the GD 7–9 interval, lower feed consumption, and concomitantly less feces, resulting in the dose group being removed from the study on GDs 10 and 11. The 400 mg/kg/day dose group also displayed body weight loss that was associated with generally lower feed consumption and less feces, resulting in four does being removed from the study on GDs 13, 14, 22, and 23. The rest of the 400 mg/kg/day dose group was removed from the study on GDs 24 and 25. Two does in the 300 mg/kg/day dose group displayed similar responses and were removed on GDs 12 and 23 (Table 9).

Table 9 Summary of Maternal Disposition of Rabbits in the Dose Range-finding Gavage Study of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

| 0 mg/kg/day | 300 mg/kg/day | 400 mg/kg/day | 500 mg/kg/day
Time-mated Females | 8 | 8 | 8 | 8
Euthanized Moribund – Pregnant | 0 | 2^a^ | 4^b^ | 1^c^
Group Removal | 0 | 0 | 4^d^ | 7^e^
Pregnant (on GD 29) | 8 | 5 | 0 | 0
Nonpregnant (on GD 29) | 0 | 1 | 0 | 0

No trend or pairwise statistical tests were performed on these data.

GD = gestation day.

^a^ Does were euthanized on GDs 12 and 23.

^b^ Does were euthanized on GDs 13, 14, 22, and 23.

^c^ Doe was euthanized on GD 11.

^d^ Group removal on GDs 24 and 25.

^e^ Group removal on GDs 10 and 11.

#### Body Weights and Feed Consumption

Mean body weight gain and mean feed consumption were slightly lower, relative to the vehicle control group, in the remaining 300 mg/kg/day does over the GD 7–9 and GD 9–12 intervals (Table 10, Table 11; Figure 5). However, those values included one doe that was removed on GD 12. The GD 7–29 body weight gains in the remainder of the 300 mg/kg/day dose group were similar to that of the vehicle control group (Table 10; Figure 5).

Table 10 Summary of Maternal Mean Body Weight Gains of Rabbits in the Dose Range-finding Gavage Study of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

Gestation Day Interval^a,b^ | 0 mg/kg/day | 300 mg/kg/day | 400 mg/kg/day | 500 mg/kg/day
7–29 | 381.2 ± 34.8 (8) | 373.7 ± 30.0 (5) | – | –
3–7 | 47.5 ± 13.1 (8) | 57.3 ± 20.5 (7) | 57.1 ± 14.9 (8) | 65.3 ± 15.4 (8)
7–9 | 30.1 ± 14.2* (8) | 1.7 ± 19.9 (7) | −33.6 ± 31.8 (8) | −76.5 ± 35.4* (8)
9–12 | 70.3 ± 15.4 (8) | −10.3 ± 53.2 (7) | 18.1 ± 28.3 (8) | –
12–15 | 116.5 ± 19.3* (8) | 79.7 ± 14.0 (6) | 49.2 ± 33.1 (6) | –
15–18 | 5.5 ± 24.4 (8) | 8.0 ± 41.5 (6) | −61.6 ± 48.1 (6) | –
18–21 | 21.6 ± 14.5 (8) | 4.3 ± 31.6 (6) | −19.5 ± 28.2 (6) | –
21–24 | 41.6 ± 11.7 (8) | 78.1 ± 7.1 (5) | 48.7 ± 35.3 (4) | –
24–27 | 34.1 ± 12.8 (8) | 17.4 ± 17.0 (5) | – | –
27–29 | 61.5 ± 9.4 (8) | 56.1 ± 20.4 (5) | – | –

Statistical significance for a dose group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

^a^ Body weight gains for pregnant animals are given in grams. Data are displayed as mean ± standard error (number of does).

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

Table 11 Summary of Maternal Feed Consumption of Rabbits in the Dose Range-finding Gavage Study of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

Gestation Day Interval^a,b^ | 0 mg/kg/day | 300 mg/kg/day | 400 mg/kg/day | 500 mg/kg/day
7–29 | 116.4 ± 8.4 (8) | 124.1 ± 4.7 (5) | – | –
7–9 | 139.4 ± 10.2** (8) | 122.6 ± 12.1 (7) | 98.9 ± 17.6* (8) | 73.0 ± 18.2** (8)
9–12 | 133.1 ± 10.8 (8) | 102.2 ± 22.4 (7) | 101.1 ± 22.4 (8) | –
12–15 | 112.0 ± 16.1 (8) | 97.0 ± 8.5 (6) | 99.9 ± 17.2 (6) | –
15–18 | 119.2 ± 12.4 (8) | 107.9 ± 18.4 (6) | 76.0 ± 25.8 (6) | –
18–21 | 120.5 ± 13.5 (8) | 120.9 ± 24.2 (6) | 94.0 ± 29.2 (6) | –
21–24 | 112.0 ± 9.0 (8) | 130.7 ± 8.3 (5) | 123.5 ± 12.5 (4) | –
24–27 | 88.4 ± 13.3 (8) | 104.6 ± 19.1 (5) | – | –
27–29 | 113.5 ± 11.5 (8) | 137.8 ± 4.3 (5) | – | –

Statistical significance for a dose group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Feed consumption for pregnant animals is given in grams per day. Data are displayed as mean ± standard error (number of does).

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

Figure 5

Maternal Growth Curves for Pregnant Rabbits Administered 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine by Gavage in the Dose Range-finding Study

Information for statistical significance in maternal weights is provided in Table 10 and Appendix F.

### Maternal and Litter Observations

There were no MPEP-related gross observations in the 300 mg/kg/day group at necropsy.

No effects of 300 mg/kg/day MPEP on postimplantation loss or litter size were observed. Male and female fetal weights in the 300 mg/kg/day dose group were lower (12% and 9%, respectively) than those of the vehicle control group. These lower fetal weights were associated with a reduction in gravid uterine weight (8%) (Table 12).

Table 12 Summary of Uterine Content Data for Female Rabbits in the Dose Range-finding Gavage Study of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

| 0 mg/kg/day | 300 mg/kg/day | 400 mg/kg/day | 500 mg/kg/day
Pregnancy Summary
Mated Females^a^ | 8 | 8 | 8 | 8
Pregnant Females^b^ | 8 | 7 | 8 | 8
Pregnant Females Examined on GD 29^a^ | 8 | 5 | 0 | 0
Corpora Lutea per Female^c,d^ | 8.75 ± 0.25 (8) | 8.80 ± 0.37 (5) | – | –
Implantations per Female^c,d^ | 8.25 ± 0.16 (8) | 8.60 ± 0.51 (5) | – | –
Percent Postimplantation Loss^c,d^ | 1.39 ± 1.39 (8) | 2.22 ± 2.22 (5) | – | –
Total Resorptions per Litter^c,d^ | 0.13 ± 0.13 (8) | 0.20 ± 0.20 (5) | – | –
Early Resorptions per Litter^c,d^ | 0.13 ± 0.13 (8) | 0.20 ± 0.20 (5) | – | –
Late Resorptions per Litter^c,d^ | 0.00 ± 0.00 (8) | 0.00 ± 0.00 (5) | – | –
Dead Fetuses per Litter^c,d^ | 0.00 ± 0.00 (8) | 0.00 ± 0.00 (5) | – | –
Number of Early Resorptions^a^ | 1 | 1 | – | –
Number of Late Resorptions^a^ | 0 | 0 | – | –
Number of Dead Fetuses^a^ | 0 | 0 | – | –
Number of Whole Litter Resorptions^b^ | 0 | 0 | – | –
Live Fetuses^d^
Number of Live Fetuses | 65 | 42 | – | –
Live Fetuses per Litter^c^ | 8.13 ± 0.13 (8) | 8.40 ± 0.51 (5) | – | –
Live Male Fetuses per Litter^c^ | 3.63 ± 0.50 (8) | 3.00 ± 0.32 (5) | – | –
Live Female Fetuses per Litter^c^ | 4.50 ± 0.50 (8) | 5.40 ± 0.68 (5) | – | –
Percent Live Male Fetuses per Litter^c^ | 44.62 ± 6.19 (8) | 36.52 ± 4.85 (5) | – | –
Fetal Weight (g)^c,e^
Fetal Weight per Litter | 41.39 ± 1.29* (8) | 36.87 ± 1.78 (5) | – | –
Male Weight per Litter | 42.81 ± 1.75 (8) | 37.57 ± 2.45 (5) | – | –
Female Weight per Litter | 40.29 ± 1.14 (8) | 36.62 ± 1.33 (5) | – | –
Gravid Uterine Weight (g)^c,e^
Gravid Uterine Weight | 490.56 ± 15.02 (8) | 452.24 ± 29.40 (5) | – | –
Terminal Body Weight | 3,502.8 ± 46.4 (8) | 3,450.3 ± 66.3 (5) | – | –
Adjusted Body Weight^f^ | 3,012.19 ± 39.90 (8) | 2,998.10 ± 42.69 (5) | – | –

Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

GD = gestation day.

^a^ No statistical analyses performed on mated females, pregnant females examined on GD 29, number of early resorptions, number of late resorptions, or number of dead fetuses.

^b^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^c^ Values are reported per litter as mean ± standard error (n) and do not include nonpregnant animals or those that did not survive to end of study.

^d^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^e^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^f^ Adjusted body weight = terminal body weight minus gravid uterine weight.

### Fetal Findings

There were no exposure-related external findings.

### Dose Selection Rationale for the Prenatal Developmental Toxicity Study in Rabbits

In the rabbit dose range-finding study, maternal toxicity was clearly observed at doses ≥400 mg/kg/day, and similar findings, but at a lower incidence, were observed in the 300 mg/kg/day dose group. Therefore, 250 mg/kg was selected as the high dose for the prenatal developmental toxicity study, and half dose spacing was used to provide adequate spacing for evaluation of potential dose-response relationships and ideally to capture a no-observed-effect level. The doses selected for the prenatal developmental toxicity study were 62.5, 125, and 250 mg/kg/day.

## Prenatal Developmental Toxicity Study in Rabbits

### Maternal Findings

#### Viability and Clinical Observations

Three does in the 250 mg/kg/day dose group were removed from the study on GD 21 due to poor feed consumption with a concomitant decrease in feces and body weight. One doe in the 125 mg/kg/day dose group was removed from the study on GD 23 after displaying a similar response. Three does, one in the 125 mg/kg/day dose group and two in the 250 mg/kg/day dose group, delivered prior to necropsy; one doe in each of these groups began delivery just prior to scheduled necropsy. The other doe in the 250 mg/kg/day group gave birth on GD 28; this 1-day advancement was a single incidence and potentially the result of mistiming of insemination by the rabbit supplier rather than an MPEP-related effect. Three does, one in the 62.5 mg/kg/day dose group and two in the 250 mg/kg/day dose group, were not pregnant (Table 13).

Table 13 Summary of Maternal Disposition of Rabbits in the Prenatal Developmental Toxicity Gavage Study of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

| 0 mg/kg/day | 62.5 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day
Time-mated Females^a^ | 24 | 24 | 24 | 23
Euthanized Moribund – Pregnant | 0 | 0 | 1^b^ | 3^c^
Euthanized – Early Delivery | 0 | 0 | 0 | 1^d^
Removed – Delivery before Necropsy | 0 | 0 | 1^e^ | 1^e^
Pregnant (on GD 29) | 24 | 23 | 22 | 16
Nonpregnant (on GD 29) | 0 | 1 | 0 | 2

No trend or pairwise statistical tests were performed on these data.

GD = gestation day.

^a^ Three additional does per dose group were added for determination of plasma 2-((1-(4-phenoxyphenoxy)propan-2-yl)oxy)pyridine concentrations.

^b^ Doe was euthanized on GD 23.

^c^ Does were euthanized on GD 21.

^d^ Doe was euthanized on GD 28.

^e^ Doe was removed from the study on GD 29.

#### Body Weights and Feed Consumption

Maternal body weight gains during gestation were generally lower in the 250 mg/kg/day dose group; however, mean body weight of this group remained within 3% of the vehicle control group (Table 14; Appendix F). Further, the 250 mg/kg/day groupexhibited a downward shift in the body weight curve (Figure 6). This apparent response was still present when the does that were euthanized prior to GD 29 were omitted. Body weight gain from GD 7 through GD 29 in the 250 mg/kg/day dose group was 20% lower than that of the vehicle control group, but the difference was not statistically significant (Table 14). The GD 29 body weights of the 250 mg/kg/day group were similar to those of the vehicle control group (Appendix F), as were the adjusted terminal body weights (Appendix F). In general, feed consumption (g/animal/day) by the 250 mg/kg/day dose group was decreased during the first week of dosing (Table 15). There were no biologically significant differences in mean body weight or feed consumption by the 62.5 and 125 mg/kg/day dose groups compared to the vehicle control group. Daily mean body weights of does in each dose group are available in Appendix F.

Table 14 Summary of Maternal Mean Body Weight Gains of Rabbits in the Prenatal Developmental Toxicity Gavage Study of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

Gestation Day Interval^a,b^ | 0 mg/kg/day | 62.5 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day
7–29 | 351.3 ± 27.8 (24) | 431.5 ± 20.9 (23) | 339.6 ± 28.8 (23) | 282.0 ± 51.9 (17)
3–7 | 81.4 ± 7.7* (24) | 50.7 ± 10.5* (23) | 64.9 ± 7.4 (24) | 47.0 ± 9.1* (21)
7–9 | 46.7 ± 7.1* (24) | 48.6 ± 10.4 (23) | 25.7 ± 5.0 (24) | 23.4 ± 8.2 (21)
9–12 | 56.7 ± 9.1 (24) | 66.8 ± 7.0 (23) | 50.5 ± 8.7 (24) | 50.3 ± 7.7 (21)
12–15 | 107.0 ± 8.1 (24) | 126.5 ± 8.5 (23) | 125.7 ± 12.1 (24) | 77.2 ± 23.1 (21)
15–18 | −11.6 ± 18.0* (24) | 18.1 ± 7.2 (23) | −26.6 ± 14.3 (24) | −29.0 ± 17.6 (21)
18–21 | 34.1 ± 13.6 (24) | 28.1 ± 9.8 (23) | 35.8 ± 9.5 (24) | 2.7 ± 19.4 (21)
21–24 | 50.3 ± 6.9 (24) | 58.0 ± 9.2 (23) | 70.2 ± 12.2 (23) | 47.8 ± 15.8 (18)
24–27 | 33.8 ± 10.0 (24) | 42.8 ± 11.3 (23) | 17.8 ± 11.5 (23) | 9.4 ± 17.6 (18)
27–29 | 34.4 ± 8.2 (24) | 42.6 ± 7.1 (23) | 22.6 ± 23.1 (23) | 9.5 ± 31.4 (17)

Statistical significance for a dose group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

^a^ Body weight gains for pregnant animals are given in grams. Data are displayed as mean ± standard error (number of does).

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

Figure 6

Maternal Growth Curves for Pregnant Rabbits Administered 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine by Gavage in the Prenatal Developmental Toxicity Study

Information for statistical significance in maternal weights is provided in Table 14 and Appendix F.

Table 15 Summary of Maternal Feed Consumption of Rabbits in the Prenatal Developmental Toxicity Gavage Study of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

Gestation Day Interval^a,b^ | 0 mg/kg/day | 62.5 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day
7–29 | 117.0 ± 3.7 (24) | 133.1 ± 3.5** (23) | 119.6 ± 3.4 (23) | 116.6 ± 5.2 (17)
7–9 | 148.2 ± 1.3** (24) | 145.2 ± 3.9 (23) | 142.0 ± 2.8 (24) | 135.5 ± 5.5* (21)
9–12 | 145.5 ± 2.4** (24) | 143.3 ± 3.6 (23) | 137.5 ± 4.6 (24) | 137.6 ± 5.4** (21)
12–15 | 124.7 ± 7.1** (24) | 133.9 ± 6.0 (23) | 123.1 ± 5.7 (24) | 103.2 ± 9.0* (21)
15–18 | 117.4 ± 6.9 (24) | 133.4 ± 5.5 (23) | 110.2 ± 8.7 (24) | 96.5 ± 12.0 (21)
18–21 | 116.0 ± 6.1 (24) | 143.6 ± 2.8** (23) | 120.7 ± 9.1 (24) | 102.1 ± 13.8 (21)
21–24 | 99.1 ± 6.5 (24) | 129.9 ± 6.1** (23) | 118.8 ± 5.0 (23) | 107.6 ± 10.3 (18)
24–27 | 90.1 ± 6.4 (24) | 114.9 ± 7.3* (23) | 97.7 ± 7.1 (23) | 92.4 ± 10.9 (18)
27–29 | 99.6 ± 6.5 (24) | 120.7 ± 5.2 (23) | 98.5 ± 9.6 (23) | 102.5 ± 11.4 (17)

Statistical significance for a dose group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Feed consumption for pregnant animals is given in grams per day. Data are displayed as mean ± standard error (number of does).

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

### Maternal and Litter Observations

There were no notable maternal necropsy findings. The number of pregnant does available for examination was lower in the 250 mg/kg/day dose group due to early removals (16 versus 24 in the vehicle control group). The mean numbers of corpora lutea, implantation sites, and early and late resorptions were similar across groups (Table 16).

Table 16 Summary of Uterine Content Data for Female Rabbits in the Prenatal Developmental Toxicity Gavage Study of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

| 0 mg/kg/day | 62.5 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day
Pregnancy Summary
Mated Females^a^ | 24 | 24 | 24 | 23
Pregnant Females^b^ | 24 | 23 | 24 | 21
Pregnant Females Examined on GD 29^a^ | 24 | 23 | 22 | 16
Corpora Lutea per Female^c,d^ | 9.63 ± 0.28 (24) | 9.04 ± 0.32 (23) | 9.32 ± 0.36 (22) | 9.31 ± 0.31 (16)
Implantations per Female^c,d^ | 9.21 ± 0.35 (24) | 8.43 ± 0.39 (23) | 9.00 ± 0.35 (22) | 8.69 ± 0.43 (16)
Percent Postimplantation Loss^c,d^ | 3.81 ± 1.36 (24) | 4.83 ± 1.70 (23) | 2.89 ± 1.17 (22) | 2.23 ± 1.26 (16)
Total Resorptions per Litter^c,d^ | 0.25 ± 0.09 (24) | 0.39 ± 0.14 (23) | 0.23 ± 0.09 (22) | 0.19 ± 0.10 (16)
Early Resorptions per Litter^c,d^ | 0.17 ± 0.08 (24) | 0.26 ± 0.11 (23) | 0.18 ± 0.08 (22) | 0.06 ± 0.06 (16)
Late Resorptions per Litter^c,d^ | 0.08 ± 0.06 (24) | 0.13 ± 0.07 (23) | 0.05 ± 0.05 (22) | 0.13 ± 0.09 (16)
Dead Fetuses per Litter^c,d^ | 0.04 ± 0.04 (24) | 0.00 ± 0.00 (23) | 0.00 ± 0.00 (22) | 0.00 ± 0.00 (16)
Number of Early Resorptions^a^ | 4 | 6 | 4 | 1
Number of Late Resorptions^a^ | 2 | 3 | 1 | 2
Number of Dead Fetuses^a^ | 1 | 0 | 0 | 0
Number of Whole Litter Resorptions^b^ | 0 | 0 | 0 | 0
Live Fetuses^d^
Number of Live Fetuses | 214 | 185 | 193 | 136
Live Fetuses per Litter^c^ | 8.92 ± 0.39 (24) | 8.04 ± 0.41 (23) | 8.77 ± 0.39 (22) | 8.50 ± 0.43 (16)
Live Male Fetuses per Litter^c^ | 4.50 ± 0.38 (24) | 3.83 ± 0.31 (23) | 3.95 ± 0.40 (22) | 4.53 ± 0.51 (15)
Live Female Fetuses per Litter^c^ | 4.42 ± 0.40 (24) | 4.22 ± 0.37 (23) | 5.05 ± 0.36 (21) | 3.69 ± 0.44 (16)
Percent Live Male Fetuses per Litter^c^ | 50.37 ± 3.79 (24) | 47.92 ± 3.45 (23) | 44.81 ± 4.24 (22) | 49.83 ± 5.52 (16)
Fetal Weight (g) ^c,e^
Fetal Weight per Litter | 37.98 ± 1.25 (24) | 39.84 ± 0.97 (23) | 37.07 ± 0.92 (22) | 36.70 ± 1.37 (16)
Male Weight per Litter | 39.03 ± 1.47 (24) | 40.52 ± 1.22 (23) | 36.96 ± 1.00 (22) | 37.41 ± 1.43 (15)
Female Weight per Litter | 36.65 ± 1.26 (24) | 39.05 ± 0.96 (23) | 37.25 ± 0.92 (21) | 35.64 ± 1.57 (16)
Gravid Uterine Weight (g) ^c,e^
Gravid Uterine Weight | 491.97 ± 15.51 (24) | 471.69 ± 19.67 (23) | 473.39 ± 17.01 (22) | 461.36 ± 22.03 (16)
Terminal Body Weight | 3,383.4 ± 45.3 (24) | 3,461.5 ± 42.3 (23) | 3,430.8 ± 39.0 (22) | 3,336.6 ± 56.2 (16)
Adjusted Body Weight^f^ | 2,891.44 ± 42.95 (24) | 2,989.77 ± 37.86 (23) | 2,957.41 ± 32.40 (22) | 2,875.21 ± 41.83 (16)

GD = gestation day.

^a^ No statistical analyses performed on mated females, pregnant females examined on GD 29, number of early resorptions, number of late resorptions, or number of dead fetuses.

^b^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^c^ Values are reported per litter as mean ± standard error (n) and do not include nonpregnant animals or those that did not survive to end of study.

^d^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^e^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^f^ Adjusted body weight = terminal body weight minus gravid uterine weight.

MPEP exposure did not affect the mean number of viable fetuses per litter, sex ratio, or significantly affect male or female fetal weight (Table 16).

### Fetal Findings

#### External

MPEP exposure was not associated with increased incidences of any external malformations or variations. A singular occurrence of umbilical hernia was observed in the 62.5 mg/kg/day group (Appendix F).

#### Visceral

MPEP exposure was not associated with increased incidences of any visceral malformations or variations. Unilateral absent testes were observed in three fetuses from different litters in the 125 mg/kg/day group, but this finding was not observed in the 250 mg/kg/day group and has been observed once in recent historical control groups. Other findings occurred at a low incidence in all exposure groups (including the vehicle control group; e.g., testis, malpositioned; supernumerary thymus) or were found as a singular incidence (e.g., epididymis, left absent; hydronephrosis, right kidney), none of which suggest an exposure-response trend (Appendix F).

#### Head

The only head malformation observed in an MPEP-exposed group was a single incidence of hydrocephaly in one fetus in the 125 mg/kg/day group (Appendix F). This finding was incidental and not considered to be related to MPEP exposure.

#### Skeletal

Fetuses from the 125 and 250 mg/kg/day groups displayed an increase in the incidences of the malformations unilateral or bilateral costal cartilage seventh not fused to sternum (three fetuses from two litters and three fetuses from one litter, respectively) (Table 17). These findings (i.e., the absence of the underlying cartilaginous structures connecting the seventh rib to the sternum) were not observed in litters that were inadvertently over-macerated during skeletal processing. The incidence of 13th rib, unilateral or bilateral detached, was observed in all exposed groups and the vehicle control group. The 125 mg/kg/day group had the highest incidence (17 fetuses from 10 litters). Similarly, the malformation lumbar vertebra fused to ilium was observed at similar incidences in all exposure groups, including the vehicle control group (Appendix F).

Table 17 Summary of Select Fetal Skeletal Findings in Rabbits in the Prenatal Developmental Toxicity Gavage Study of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

| 0 mg/kg/day | 62.5 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day
Total Number of Fetuses | 214 | 185 | 193 | 136
Number of Fetuses Examined | 214 | 185 | 193 | 136
Number of Litters Examined | 24 | 23 | 22 | 16
Ribs^a,b^
Costal cartilage, 7th unilateral or bilateral, not fused to sternum – [M]^c^
Fetuses | 0 (0.00) | 0 (0.00) | 3 (1.58) | 3 (2.21)
Litters | 0 (0.00) | 0 (0.00) | 2 (9.09) | 1 (6.25)

[M] = malformation.

^a^ Upper row denotes number of affected fetuses (%) and lower row the number of affected litters (%).

^b^ Statistical analysis for fetal data including litter effects performed using a Rao-Scott modification to the Cochran-Armitage test where the litter was the random effect for both trend and pairwise analyses. No statistically significant trends or pairwise comparisons were observed.

^c^ Historical control data are not available for rabbits.

### Internal Dose Assessment

Maternal plasma on GDs 27 and 28 and fetal plasma on GD 28 were analyzed for MPEP concentrations (Table 18). Samples were collected at three timepoints that bracketed the time of anticipated maximum concentration to allow for the detection of MPEP in both maternal and fetal compartments. In general, MPEP concentrations in maternal plasma increased proportionally with the dose on both GD27 and GD 28. On GD 27, predose plasma had measurable concentrations of MPEP, demonstrating that MPEP was not completely cleared after 24 hours. The MPEP concentration was highest at 8 hours postdosing in all dosed groups suggesting the time to reach maximum concentration is ≥8 hours. On GD 28, MPEP concentrations in fetal plasma were similar to that of maternal plasma, demonstrating significant gestational transfer of MPEP. MPEP was observed in plasma from does (11–29 ng/mL) and fetuses (~10 ng/mL) from vehicle control groups; those concentrations were approximately two- to sixfold higher than the background concentrations observed in the respective control matrices used in analytical method development.

Table 18 Summary of Internal Dose Data for Rabbits in the Prenatal Developmental Toxicity Gavage Study of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

| 0 mg/kg/day | 62.5 mg/kg/day | 125 mg/kg/day | 250 mg/kg/day
n | 3 | 3 | 3 | 3
MPEP Concentration (ng/mL plasma)^a,b^
Maternal (GD 27)
Predose | 13.1 ± 1.7 | 20.5 ± 2.4 | 53.7 ± 8.8 | 95.2 ± 22.9
4 hours postdose | 11.9 ± 1.6 | 70.5 ± 20.3 | 213.0 ± 38.0 | 311.0 ± 81.0
8 hours postdose | 13.2 ± 0.7 | 116.2 ± 50.4 | 342.3 ± 126.7 | 376.7 ± 107.4
24 hours postdose | 29.2 ± 9.6 | 98.6 ± 37.7 | 240.1 ± 143.5 | 121.2 ± 26.4
Maternal (GD 28)
2 hours postdose | 10.9 ± 0.5 | 52.6 ± 14.1 | 223.2 ± 74.5 | 206.0 ± 46.0
Fetal (GD 28)^c^
2 hours postdose | 9.7 ± 0.6 | 66.1 ± 6.1 | 158.0 ± 21.5 | 255.0 ± 57.6

MPEP = 2-((1-(4-phenoxyphenoxy)propan-2-yl)oxy)pyridine; GD = gestation day.

^a^ Data are presented as mean ± standard error.

^b^ No statistical analysis was performed on these data.

^c^ n = 10–18 fetuses per exposure group (2–6 individual fetuses from each of the three does per dose group).

## Zebrafish Assay Data

MPEP was included in an NTP high-throughput embryonic zebrafish assay to screen chemicals for their potential to cause developmental toxicity.^56^ This assay is particularly useful for evaluating adverse effects to the head or craniofacial region, which is a proposed target of MPEP-induced developmental toxicity in the literature. Following a 4-day exposure to MPEP (5–20 μM), microcephaly, heart edema, microphthalmia, yolk sac edema, trunk alterations (curved/curled), and yolk opacity were quantified in larvae (Appendix E). Mortality was observed in all embryos at concentrations ≥50 μM. The calculated median effective concentration (EC_50_) for MPEP was 5.4 μM (1.7 μg/mL). These results align with findings in other zebrafish embryo studies by Padilla et al.^57^ and Troung et al.^58^ The concentrations at which MPEP was associated with adverse morphological effects, including craniofacial deficits, was similar across studies despite different experimental approaches: median activity concentration (AC_50_) of 26 μM by Padilla and colleagues versus EC_50_ of 5.2 μM by Troung and colleagues.^57,58^ However, adverse fetal findings were not observed in NTP rat and rabbit studies at similar internal dose concentrations (e.g., rat fetus = plasma concentration of 1,418 ng/mL in the 250 mg/kg/day MPEP group; rabbit fetus = plasma concentration of 255 ng/mL in the 250 mg/kg/day MPEP group). Comparing the results among zebrafish, rats, and rabbits suggests potential species differences between lower vertebrate models, such as teleost fish species, and more established vertebrate models used to assess human-relevant outcomes. In addition, many of the morphological alterations, such as microcephaly, were observed in fish exposed to a variety of other environmental chemicals and pharmaceuticals tested by NTP (e.g., 47 of 88 chemicals evaluated caused at least one morphological alteration).^59^ These results could suggest that microcephaly may be a common chemical-mediated response in embryonic zebrafish screening assays and not entirely MPEP specific.