# Materials and Methods

## Overview of Prenatal Developmental Toxicity Study Designs

Prenatal developmental toxicity studies are conducted to ascertain if in utero exposure to a test agent results in embryo-fetal death, structural malformations/variations, growth retardation, or functional deficits that are not secondary to overt maternal toxicity. Overt maternal toxicity has been shown to affect normal embryo-fetal growth and development (e.g., excessively lower maternal body weight gains and lower fetal weights, increased maternal stress in mice, and cleft palate).^28-30^ The presence of maternal toxicity, however, should not negate a priori an apparent fetal response. Rather, given the maternal/embryo-fetal interrelationship, fetal findings should be interpreted considering the maternal responses. Pregnant animals should be administered dose levels of test agent to the extent feasible (or limit dose) to obtain maximal dam and fetal exposure, thereby sufficiently challenging the test system to identify potential developmental hazards.^31^

The conduct of a dose range-finding study aids in the determination of dose selection when the potential for test agent-induced maternal toxicity is unknown and can provide preliminary information on embryo-fetal outcomes (e.g., postimplantation loss, changes in fetal weight, external defects), and informs the prenatal developmental toxicity study design. In the prenatal developmental toxicity study, fetal examination is expanded to include examination of the fetal viscera, head (soft tissue and skeletal components), and the skeleton for osseous and cartilaginous defects. Abnormalities are separated into malformations that are permanent structural changes that might adversely affect survival, development, or function or variations that are a divergence beyond the usual range of structural constitution that might not adversely affect survival or health,^29^ consistent with that described by Makris et al.^32^ The study design for the prenatal developmental toxicity study in rats is presented in Figure 2, and the study design for the dose range-finding and prenatal developmental toxicity studies in rabbits is presented in Figure 3.

Figure 2

Design of a Prenatal Developmental Toxicity Study in Rats

^a^Animals are dosed once daily from gestation day (GD) 6 to GD 20 and necropsied on GD 21.

^b^All fetuses are examined externally (including inspection of the oral cavity) and are examined for visceral and skeletal effects, with ~50% of the heads examined for soft tissue alterations.

Figure 3

Design of a Dose Range-finding and Prenatal Developmental Toxicity Study in Rabbits

^a^Animals are dosed once daily from gestation day (GD) 7 to GD 28 and necropsied on GD 29.

^b^All fetuses are examined externally (including inspection of the oral cavity).

^c^Fetuses in the prenatal developmental toxicity study also are examined for visceral and skeletal effects with heads examined for soft tissue alterations.

## Procurement and Characterization

### 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine (MPEP) was obtained from AK Scientific, Inc. (Union City, CA) in a single lot (JL44164). Identity, purity, and stability analyses were conducted by the analytical chemistry lab at RTI International (Research Triangle Park, NC) (Appendix A). Reports on analyses performed in support of the MPEP studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

MPEP was received as a white powder. The melting point was consistent with the literature values. Elemental analysis of lot JL44164 was consistent with the composition of MPEP. The identity of lot JL44164 was confirmed using infrared spectroscopy, ^1^H nuclear magnetic resonance (NMR) spectroscopy, ^13^C NMR spectroscopy, and three types of 2-dimensional NMR spectroscopy. The spectra were consistent with the reference and predicted spectra and with the structure of MPEP. Gas chromatography (GC) with mass spectrometry detection (MS) also confirmed the structure of MPEP.

Karl Fisher titration determined the water content of lot JL44164 to be 0.03%. The purity estimated by GC with flame ionization detection (FID) and by ultra-performance liquid chromatography (UPLC) with a photodiode array detector (PDA) was 99.6% and 97.7%, respectively. The UPLC/PDA analysis identified two impurity peaks with >0.1% and 15 additional peaks with <0.1% of the total response. The overall purity of lot JL44164 was estimated to be >97.7%.

Accelerated stability studies confirmed that lot JL44164 was stable for at least 2 weeks when stored in amber glass bottles sealed with Teflon-lined caps at 25, 5, and −20°C. Lot JL44164 was homogenized by stirring, distributed into 80-ounce bottles with Teflon-lined caps, and stored at room temperature.

### Corn Oil

Corn oil was obtained from Welch, Holme & Clark Co. Inc (Newark, NJ) in a single lot (0120-0576) and used as a vehicle in the dose range-finding and prenatal developmental toxicity studies. A solubility and suspendability study of MPEP in corn oil determined that the test article was suspendable at up to 250 mg/mL and soluble at up to 136 mg/mL. Lot 0120-0576 contained peroxide levels that were less than the rejection level of 3 milliequivalents (meQ)/kg corn oil.

## Preparation and Analysis of Dose Formulations

Dose formulations of MPEP were prepared in corn oil following the protocols outlined in Table A-2. The rat and rabbit prenatal developmental toxicity studies used dose formulations of 31.25, 62.5, 125, and 250 mg/mL (rat only). Dose formulations of 150, 200, and 250 mg/mL were used in the rabbit dose range-finding study. A homogeneity study at 250 mg/mL and a stability study at 1 mg/mL dose formulations were conducted using GC/FID. Homogeneity and stability were confirmed for 42 days at room temperature (~25°C).

Analysis of preadministration and postadministration dose formulations was conducted using GC/FID (Table A-3, Table A-4, Table A-5). All formulations were within 10% of the target concentrations except the 250 mg/mL postadministration sample in the rabbit dose range-finding study which was 21.3% above the target concentration.

## Animal Source

Female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats for use in the prenatal developmental toxicity study were obtained from Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN). Sexually mature (11 to 13 weeks old) females were time-mated overnight at the vendor and were received on gestation day (GD) 1 or GD 2. GD 0 was defined as the day positive evidence of mating was observed.

Female New Zealand White (Hra:NZW SPF) rabbits for use in the dose range-finding and prenatal developmental toxicity studies were obtained from Covance Research Products (Denver, PA). Sexually mature females (6 months old) were time-mated at the vendor and were received on GD 1 or GD 2.

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the Southern Research Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health (NIH) and National Toxicology Program (NTP) animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Animal Health Surveillance

### Prenatal Developmental Toxicity Study in Rats

Ten nonmated female rats were received for use as sentinels. Within 5–10 days of arrival and at study termination, blood was collected from the retroorbital plexus of sentinel animals for disease screening. After blood collection, animals were euthanized, necropsied, and examined for internal and external parasites. Necropsy included macroscopic examination of the external surface of the body; all orifices; cranial, thoracic, and abdominal cavities and their contents; and organs and tissues. All lesions were retained, and a histopathological examination was performed.

Serum was prepared from collected blood samples, diluted in saline, and stored frozen until shipped to the NTP-designated disease screening contract laboratory (IDEXX BioResearch, Columbia, MO) for analysis. Sera were analyzed for the presence of pathogens according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative (Table C-1).

### Dose Range-finding Study in Rabbits

Disease screening was performed on nine randomly selected time-mated does across dose groups. Blood samples were collected from all animals at study termination using Opti Spot, allowed to dry, and stored at ambient temperature until shipped to IDEXX BioResearch (Columbia, MO). Opti Spot samples were also collected from four additional does that were euthanized moribund prior to GD 29. Fecal, fur, and oral swab samples were collected from the nine randomly selected does at study termination, stored at ambient temperature, and shipped to IDEXX BioResearch (Columbia, MO). After sample collection, animals were given a gross necropsy and evaluated for external and internal parasites including ectoparasite and endoparasite screening.

Details on the serology tests performed are presented in Appendix C. Antibodies to rotavirus were detected in all samples; all other test results were negative (Table C-2).

### Prenatal Developmental Toxicity Study in Rabbits

Disease screening was performed in 10 time-mated does randomly selected from vehicle control group animals. Blood samples were collected from one animal at the start of the study and all animals at study termination using Opti Spot, allowed to dry, and stored at ambient temperature until shipped to IDEXX BioResearch (Columbia, MO). Fecal samples and fur swabs were collected from the same does at study termination, stored at ambient temperature, and shipped to IDEXX BioResearch (Columbia, MO). After sample collection, animals were euthanized, necropsied, and examined for internal parasites. Gross lesions were retained for potential histopathological evaluation.

Serum samples were analyzed for the presence of pathogens according to the protocols of the NTP Sentinel Animal Program (Appendix C). Antibodies to rotavirus were detected in all samples that were tested; all other test results were negative (Table C-2).

## Experimental Design

In the rat prenatal developmental toxicity study, time-mated animals were housed individually, provided NIH-07 feed and water ad libitum, and observed at least twice daily for viability (morning and afternoon, with at least 6 hours between observations). Clinical observations were recorded on arrival, on GD 3, and daily during dosing (GD 6–20) until removal for necropsy (1–3 hours after dosing). Dams were weighed on arrival, on GD 3, and daily from GD 6 through GD 21. Feed consumption was recorded at 3-day intervals: GD 3–6, GD 6–9, GD 9–12, GD 12–15, GD 15–18, and GD 18–21. Details of the study design, including animal source and identification, diet, water, husbandry, environmental conditions, euthanasia, necropsy, and fetal evaluations, are summarized in Table 1. Information on feed composition and contaminants is provided in Appendix B.

Table 1 Experimental Design and Materials and Methods in the Prenatal Developmental Toxicity Gavage Study of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine in Rats

Prenatal Developmental Toxicity Study
Study Laboratory
Southern Research (Birmingham, AL)
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats
Animal Source
Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN)
Day of Arrival
GD 1 or GD 2 (October 19, 21, or 24, 2016)
Average Age on Arrival
11 to 13 weeks
Weight Range at Randomization
205.4 to 251.7 g on GD 3
Calendar Day of First Dose (GD 6) and Last Dose (GD 20)
GD 6 (October 23, 24, 25, 26, or 30, 2016) and GD 20 (November 6, 7, 8, 9, or 13, 2016); staggered start
Duration of Dosing
GD 6–20, once daily
Size of Study Groups
25 time-mated female rats
Method of Randomization and Identification
Time-mated animals were uniquely identified on day of receipt by ink tail marking and assigned to dose groups by body weight stratified randomization of GD 3 body weights using Instem™ Provantis^®^ (version 8) electronic data collection system. Each animal was assigned a unique animal number in Provantis^®^. This number was linked to the respective marking and all data collected during the study was associated with the Provantis^®^ animal number.
Animals per Cage
1
Diet
Irradiated NIH-07 pelleted diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed at least weekly
Water
Tap water (Birmingham, AL, municipal supply) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum
Cages
Solid-bottom polycarbonate (Lab Products, Inc., Seaford, DE), changed weekly
Bedding
Certified irradiated Sani-Chips® hardwood cage bedding (P.J. Murphy Forest Products Corporation, Montville, NJ), changed weekly
Environmental Enrichment
Crink-l’ Nest (The Andersons; Maumee, OH), changed weekly
Cage Filters
Reemay^®^ spunbonded polyester (Andico, Birmingham, AL), changed every 2 weeks
Racks
Stainless steel (Lab Products, Inc.), changed every 2 weeks
Animal Room Environment
Temperature: 68°F to 81°F Relative humidity: 26% to 59% Room fluorescent light: 12 hours/day Room air changes: at least 16/hour
Doses
0, 62.5, 125, 250, or 500 mg/kg/day in corn oil (dosing volume 2 mL/kg)
Type and Frequency of Observation of Dams
Observed for viability (cageside) twice daily from GD 3 through GD 20. Clinical observations (out of cage) were recorded on arrival, on GD 3, daily beginning on GD 6 at 1–3 hours postdose, and at study termination. Animals were weighed on arrival, on GD 3, and daily from GD 6 through GD 21. Feed consumption was recorded at 3-day intervals from GD 3 through GD 21.
Primary Method of Euthanasia
100% carbon dioxide (dams) or intraperitoneal injection of a solution containing sodium pentobarbital followed by bilateral pneumothorax and/or decapitation (fetuses GD ≥ 19)
Necropsy and Postmortem Evaluation of Dams
On GD 21, terminal body weights and gravid uterine weights were recorded, and the uterine contents examined. The number of corpora lutea on each ovary was recorded. The number and location of all fetuses (live and dead) and resorptions (early or late) and the total number of implantation sites were recorded; if no macroscopic evidence of pregnancy, the uterus was stained with a 10% aqueous solution of ammonium sulfide to visualize potential evidence of implantation sites. Rats removed prior to GD 21 underwent gross necropsy, which included an examination of the thoracic and abdominal viscera. The uterus of each dam was examined to determine pregnancy status or, if no evidence of pregnancy, stained with a 10% aqueous solution of ammonium sulfide to visualize possible early implantation sites.
Fetal Evaluation
Live fetuses were counted, sexed, weighed, and examined for external morphological abnormalities that included inspection of the oral cavity for cleft palate. Placental morphology was also evaluated. Live fetuses were euthanized and then examined for visceral morphological abnormalities by fresh dissection. The sex of each fetus was confirmed by internal examination. The heads from approximately one-half of the fetuses in each litter were fixed, sectioned, and examined. All fetuses were eviscerated, fixed, stained, and examined for skeletal developmental variations, malformations, or other morphological findings.
Internal Dose Assessment
On GD 18, ~2 hours after the last dose administration, MPEP concentrations were determined in plasma from dams (n = 3 or 4 per dose group) and their fetuses (pooled by litter), and in amniotic fluid (pooled by litter) from only the 0, 62.5, and 250 mg/kg/day groups.

GD = gestation day; MPEP = pyridine2-((1-(4-phenoxyphenoxy)propan-2-yl)oxy)pyridine.

In the rabbit dose range-finding and prenatal developmental toxicity studies, time-mated animals were housed individually, provided Purina 5L3M feed and water ad libitum, and observed at least twice daily for viability (morning and afternoon). Clinical observations were recorded on arrival and daily during dosing (GD 7–28) until removal (1–3 hours after dosing). Does were weighed on arrival and daily from GD 3 through GD 29. Feed consumption was recorded daily from GD 3 through GD 29. Details of the rabbit study design, including animal source and identification, diet, water, husbandry, environmental conditions, euthanasia, necropsy, and fetal evaluations, are summarized in Table 2. Information on feed composition and contaminants is provided in Appendix B.

Table 2 Experimental Design and Materials and Methods in the Dose Range-finding and Prenatal Developmental Toxicity Gavage Studies of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine in Rabbits

Dose Range-finding Study | Prenatal Developmental Toxicity Study
Study Laboratory
Southern Research (Birmingham, AL) | Same as dose range-finding study
Strain and Species
New Zealand White (Hra:NZW SPF) rabbits | Same as dose range-finding study
Animal Source
Covance Research Products (Denver, PA) | Same as dose range-finding study
Day of Arrival
GD 1 or GD 2 (November 22, 2017) | GD 1 or GD 2 (January 24 or 26, 2018)
Average Age on Arrival
6 months | Same as dose range-finding study
Weight Range at Randomization
2,952 to 3,264 g on GD 6 | 2,743 to 3,368 g on GD 6
Calendar Day of First Dose (GD 7) and Last Dose (GD 28)
GD 7 (November 27 or 28, 2017) and GD 28 (December 18 or 19, 2017); staggered start | GD 7 (January 29, 30, 31, or February 1, 2018) and GD 28 (February 19, 20, 21, or 22, 2018); staggered start
Duration of Dosing
GD 7–28, once daily | Same as dose range-finding study
Size of Study Groups
8 time-mated female rabbits | 24 (0, 62.5, and 125 mg/kg/day) or 23 (250 mg/kg/day) time-mated female rabbits
Method of Randomization and Identification
Time-mated animals were individually identified on day of receipt by ink ear marking and assigned to dose groups by body weight stratified randomization of GD 6 body weights using Instem Provantis^®^ (version 9) electronic data collection system. Each animal was assigned a unique animal number in Provantis. This number was linked to the respective marking and all data collected during the study was associated with the Provantis animal number. | Same as dose range-finding study
Animals per Cage
1 | Same as dose range-finding study
Diet
Irradiated Purina 5L3M (Purina, Richmond, IN) available ad libitum, changed at least weekly | Irradiated and certified Purina 5L3M (Purina, Richmond, IN): a half ration (75 g) was provided on the day of arrival, and a whole ration (150 g) was provided daily for the rest of the study.
Water
Tap water (Birmingham, AL, municipal supply) via automatic watering system, available ad libitum | Same as dose range-finding study
Cages
Perforated-bottom stainless-steel cages (Allentown Caging Equipment Co., Allentown, PA), changed every 2 weeks | Same as dose range-finding study
Bedding
Paper cage liners, changed three times per week | Same as dose range-finding study
Environmental Enrichment
Consumable – Timothy hay (BioServ; Flemington, NJ), given daily Device – Hanging jingle toy or ball | Same as dose range-finding study
Racks
Stainless-steel racks (Allentown Caging Equipment Co., Allentown, PA; Lab Products, Inc., Seaford, DE), changed every 2 weeks | Same as dose range-finding study
Animal Room Environment
Temperature: 63°F to 73°F Relative humidity: 41% to 73% Room fluorescent light: 12 hours/day Room air changes: at least 16/hour | Temperature: 61°F to 84°F Relative humidity: 45% to 85% Room fluorescent light: 12 hours/day Room air changes: at least 13/hour
Doses
0, 300, 400, or 500 mg/kg/day in corn oil (dosing volume 2 mL/kg) | 0, 62.5, 125, or 250 mg/kg/day in corn oil (dosing volume 2 mL/kg)
Type and Frequency of Observation of Does
Observed for viability twice daily (cageside) from GD 3 through GD 29. Clinical observations (out of cage) were recorded on arrival, daily beginning on GD 7 at 1–3 hours postdose, through study termination. Animals were weighed on arrival and daily from GD 3 through GD 29. Feed consumption was recorded daily beginning on GD 3. | Observed for viability twice daily (cageside) from GD 3 through GD 29. Clinical observations (out of cage) were recorded at least once daily from arrival through study termination at 1–3 hours postdose (where applicable). Animals were weighed on arrival and daily from GD 3 through GD 29. Feed consumption was recorded daily from GD 3 through GD 29.
Primary Method of Euthanasia
Intravenous injection (does) or intraperitoneal injection (fetuses; ≥GD 26) of a solution containing sodium pentobarbital. | Same as dose range-finding study
Necropsy and Postmortem Evaluation of Does
On GD 29, terminal body weights and gravid uterine weights were recorded, and the uterine contents were examined. The number of corpora lutea on each ovary was recorded. The number and location of all fetuses (live or dead) and resorptions (early or late) and the total number of implantation sites were recorded; if no macroscopic evidence of pregnancy, the uterus was stained with a 10% aqueous solution of ammonium sulfide to visualize potential evidence of implantation sites. For all does (including early removals), a gross necropsy including an examination of the thoracic and abdominal viscera (including the stomach for trichobezoars) was performed. The uterus of each dam was examined to determine pregnancy status, or, if no evidence of pregnancy, stained with a 10% aqueous solution of ammonium sulfide to visualize possible early implantation sites. | Same as dose range-finding study
Fetal Evaluation
Live fetuses were counted, sexed, weighed, and examined for external morphological abnormalities that included inspection of the oral cavity for cleft palate. Placental morphology was also evaluated. | Live fetuses were counted, sexed, weighed, and examined for external morphological abnormalities that included inspection of the oral cavity for cleft palate. Placental morphology was also evaluated. Live fetuses were euthanized and then examined for visceral morphological abnormalities by fresh dissection. The sex of each fetus was confirmed by internal examination. All fetuses received a soft tissue examination of the head. All fetuses were eviscerated, fixed, stained, and examined for skeletal developmental variations, malformations, or other morphological findings.
Internal Dose Assessment
None | On GD 27, MPEP concentrations were determined in plasma from dams (3 per dose group) at four time points (before dosing and at 4, 8, and 24 hours postdose). On GD 28, MPEP concentrations were determined in plasma from the same dams and their fetuses 2 hours after the last dose.

GD = gestation day; MPEP = 2-((1-(4-phenoxyphenoxy)propan-2-yl)oxy)pyridine.

On GD 21, dams in the rat prenatal developmental toxicity study were weighed, euthanized with carbon dioxide, and examined for gross lesions of the thoracic and abdominal cavities. On GD 29, does in both the rabbit dose range-finding and prenatal developmental toxicity studies were weighed, euthanized with intravenous injection of sodium pentobarbital-containing solution, and examined for gross lesions of the thoracic and abdominal cavities, including the stomach for trichobezoars. The gravid uterus and ovaries were excised and weighed, and any placental findings were recorded. The numbers of uterine implantation sites and corpora lutea visible on the surface of each ovary were recorded. Uterine contents were examined for pregnancy status, and the numbers and locations of all live and dead fetuses (a live fetus is defined as one that responds to stimuli; a dead fetus is defined as a term fetus that does not respond to stimuli and is not markedly autolyzed) and resorptions were recorded.

Resorptions were classified as early or late. Early resorptions included a conceptus characterized by a grossly necrotic mass that had no recognizable fetal form and presence of nidation sites (“pregnant by stain”). Late resorptions were characterized by grossly necrotic but recognizable fetal form with placental remnants visible.^33,34^ Postimplantation loss was calculated as the number of dead and resorbed conceptuses divided by the total number of implantations (multiplied by 100). For each uterus with no macroscopic evidence of implantation, the uterus was stained with 10% (v/v) ammonium sulfide to visualize any possible implantation sites.^35^

Adult female rats that were euthanized moribund, delivered early, or found dead received a gross necropsy that included an examination of the thoracic and abdominal viscera for evidence of dosing trauma or toxicity. The uterus of each female was examined and stained, if necessary, to determine pregnancy status. Dams were not retained for further examination.

All female rabbits that aborted (defined as delivering before GD 29), were euthanized moribund, or found dead received a gross necropsy that included examination of the thoracic and abdominal viscera for evidence of dosing trauma, toxicity, and gross lesions. The uterus of each female was examined and stained, as necessary, to determine pregnancy status. Does were not retained for further examination.

### Dose Selection Rationale for the Prenatal Developmental Toxicity Study in Rats

Dose selection was made on the basis of the sponsoring manufacturer’s study in rats in which 300 mg MPEP/kg body weight/day (mg/kg/day) was associated with a 15% decrease in body weight gain during pregnancy and dam mortality was observed at 1,000 mg/kg/day. A high dose of 500 mg/kg/day was selected because it was half the dose associated with dam mortality in the sponsoring manufacturer’s study, and likely high enough to ensure that the dams were challenged. The 125 and 250 mg/kg/day dose levels were similar to the 100 and 300 mg/kg/day dose levels in the sponsoring manufacturer’s study. Because of the availability of these summary data and the desire to generate timely information on potential hazard given human exposure, a dose range-finding study was not considered warranted. Owing to possible differences in rat sensitivity (strain or genetic drift) and to aid in identifying a no-observed-effect level for fetuses, one lower dose (62.5 mg/kg/day) was added. Oral gavage was selected as the route of administration given the short duration of dosing and that oral exposure is of most concern for humans. The route and corn oil vehicle would also allow comparison of the study findings with the sponsoring manufacturer’s summary data.

### Prenatal Developmental Toxicity Study in Rats

On receipt (GD 1 or GD 2), time-mated rats were individually identified by tail marking and were randomized by GD 6 body weight stratification into five dose groups using the Instem™ Provantis^®^ (version 8) electronic data collection system.

Groups of 25 time-mated female rats were administered 0 (vehicle control), 62.5, 125, 250, or 500 mg/kg/day (based on the most recent body weight), in corn oil by gavage from GD 6 to GD 20. Vehicle control animals received corn oil vehicle alone; the dosing volume was 2 mL/kg.

On GD 21, fetuses were removed from the uterus and live fetuses individually weighed. The uteri of animals that did not appear pregnant were examined for nidations (implantation sites) by staining with 10% ammonium sulfide.^35,36^ All fetuses were examined externally for alterations, including inspection of the oral cavity for cleft palate. Live fetuses were subsequently euthanized by intraperitoneal injection of sodium pentobarbital. Fetal sex was confirmed by inspection of gonads in situ. All fetuses were examined for soft tissue alterations under a stereomicroscope.^37,38^ The heads were removed from approximately half of the fetuses in each litter and fixed in Bouin’s solution and subsequently examined by free-hand sectioning.^39^ This technique precludes skeletal evaluations of the skull; therefore, remaining heads and all fetuses were eviscerated, fixed in ethanol, macerated in potassium hydroxide, stained with Alcian blue and Alizarin red, and examined for subsequent cartilage and osseous alterations.^36,40^ External, visceral, and skeletal fetal alterations were recorded as developmental variations or malformations.

On GD 18, blood was collected from dams in the 0, 62.5, and 250 mg/kg/day groups designated for biological sampling (n = 3 or 4 per dose group) approximately 2 hours postdose. Blood was collected via cardiac puncture into tubes containing tripotassium ethylenediaminetetraacetic acid (K_3_ EDTA). Following maternal blood collection, amniotic fluid was collected and pooled by litter. Fetuses were removed from amniotic sacs, euthanized by decapitation, collected, frozen, and pooled by litter. All blood samples from dams were collected within 2 hours of each other and kept on ice until processing. Blood samples were centrifuged (refrigerated), and the plasma was isolated and frozen at approximately −70°C. Plasma samples, amniotic fluid, and fetuses were shipped on dry ice to the analytical laboratory at RTI International (Research Triangle Park, NC). All samples were analyzed for MPEP concentration as described in Appendix D.

### Dose Selection Rationale for the Dose Range-finding Study in Rabbits

Dose selection for the range-finding study was made on the basis of the sponsoring manufacturer’s study that used melted and cooled MPEP administered to rabbits by gavage at doses of 100, 300, and 1,000 mg/kg/day from GD 6 to GD 18.^41^ Moribundity and mortality were observed at 1,000 mg/kg/day. Other findings at this dose included soft stools, decreased feed consumption, decreased activity and bradypnea, and premature delivery/abortions. Similar findings, at lower incidences, were also observed in the 300 mg/kg/day dose group. Therefore, doses of 300, 400, and 500 mg/kg/day were selected to identify the highest tolerated dose rather than exploring an “optimal” dose-response relationship. The high dose of 500 mg/kg/day was one-half of the dose associated with unacceptable maternal toxicity; the two lower doses were selected to encompass possible rabbit stock differences.

### Dose Range-finding Study in Rabbits

On receipt (GD 1 or GD 2), time-mated rabbits were individually identified by ear marking and were randomized by GD 6 body weight stratification into four dose groups using the Instem™ Provantis^®^ (version 9) electronic data collection system.

Groups of eight time-mated female rabbits were administered 0 (vehicle control), 300, 400, or 500 mg/kg/day MPEP (based on the most recent body weight) in corn oil by gavage from GD 7 to GD 28. Vehicle control animals received corn oil vehicle alone; the dosing volume was 2 mL/kg.

On GD 29, fetuses were removed from the uterus, individually weighed (live fetuses only), and examined externally for alterations, including inspection of the oral cavity for cleft palate. Live fetuses were euthanized by intraperitoneal injection of a commercially available solution containing sodium pentobarbital. Fetuses were not retained after completion of the external examination.

### Prenatal Developmental Toxicity Study in Rabbits

On receipt (GD 1 or GD 2), time-mated rabbits were individually identified by ear marking and were randomized by GD 6 body weight stratification into five dose groups using the Instem™ Provantis^®^ (version 9) electronic data collection system.

Groups of 23 or 24 time-mated female rabbits were administered 0 (vehicle control), 62.5, 125, or 250 mg/kg/day MPEP (based on the most recent body weight) in corn oil by gavage from GD 7 to GD 28. Vehicle control animals received corn oil vehicle alone; the dosing volume was 2 mL/kg.

On GD 29, fetuses were removed from the uterus, and live fetuses were individually weighed. The uteri of animals that did not appear pregnant were examined for nidations (implantation sites) by staining with 10% ammonium sulfide.^35,36^ All fetuses were examined externally for alterations, including inspection of the oral cavity for cleft palate. Live fetuses were subsequently euthanized by intraperitoneal injection of sodium pentobarbital. Fetal sex was confirmed by inspection of gonads in situ. All fetuses were examined for soft tissue alterations under a stereomicroscope, including a soft tissue examination of the head.^37,38^ All fetuses were eviscerated, fixed in ethanol, macerated in potassium hydroxide, stained with Alcian blue and Alizarin red, and examined for subsequent cartilage and osseous alterations.^36,40^ External, visceral, and skeletal fetal alterations were recorded as developmental variations or malformations. Over-maceration during skeletal processing occurred in all groups: (1) vehicle control group (47 fetuses [F] from 5 litters [L]), limited to phalanges (22F, 3L), with fore/hind limbs (22F, 3L), and included portions of the axial skeleton (7F, 2L); (2) 62.5 mg/kg/day dose group (2F, 2L), limited to phalanges (1F), and included the fore/hind limbs (1F); (3) 125 mg/kg/day dose group (51F, 4L), limited to phalanges (13F, 2L), included fore/hind limbs (21F, 4L), and portions of the axial skeleton (3F, 1L); (4) 250 mg/kg/day dose group (10F, 1L), limited to phalanges (1F), and included the fore/hind limbs (9F, 1L). These structures were removed from the respective incidence calculations, and their removal was not considered to affect the study results.

On GD 27, blood was collected from does designated for biological sampling (n = 3 per dose group) at four time points (before dosing and at 4, 8, and 24 hours postdose). Collection at 24 hours occurred before dosing on GD 28. On GD 28, approximately 2 hours after dosing, blood was collected from the same does and their fetuses. For does, blood was collected from the central ear artery or lateral ear vein into tubes containing K_3_ EDTA. After their blood collection, does were euthanized and trunk blood was collected from each fetus. All samples were collected approximately 2 hours after the last dose and within 2 hours of each other and kept on ice until processing. Blood samples were centrifuged (refrigerated), and the plasma was isolated and frozen at approximately −70°C. Samples were shipped on dry ice to the analytical laboratory at RTI International (Research Triangle Park, NC). All samples were analyzed for MPEP concentration as described in Appendix D.

## Statistical Methods

In the prenatal developmental toxicity study in rats and the dose range-finding and prenatal developmental toxicity studies in rabbits, statistical analyses were performed on data from pregnant females that survived until study termination and were examined on GD 21 (rats) or GD 29 (rabbits) and from live fetuses. Statistical analyses were performed using SAS 9.4 (SAS Institute, Cary, NC).

### Descriptive Statistics

Maternal Parameters: Maternal body weights are reported as means. Terminal maternal body weights at GD 21 (for rats) or GD 29 (for rabbits) were adjusted for gravid uterine weight by subtracting the gravid uterine weight from the dam’s (or doe’s) body weight. Body weight gains were calculated over each 3-day interval and from GD 6 through GD 21 (or GD 7 through GD 29). Daily feed consumption was averaged over each 3-day interval and from GD 6 through GD 21 (or GD 7 through GD 29). These continuous variables, in addition to gravid uterine weights and other organ weights, are summarized with means and standard errors.

Placental and Fetal Parameters: Data on uterine contents are reported as means and standard errors of counts per dam per litter or doe per litter (corpora lutea, implants, resorptions, dead fetuses) and as total numbers of occurrences (resorptions, dead fetuses). Data from females that were not pregnant or that did not survive to study termination were not included. Postimplantation loss is calculated as a percentage of the number of implants per dam or per doe. Fetal findings are reported as means and standard errors of counts per litter (numbers of live fetuses, male fetuses, female fetuses), means and standard errors of litter means (fetal weight, male fetal weight, female fetal weight) and total numbers of occurrences (total number of live fetuses). In addition, several calculated variables are reported, including the percentage of live male and female fetuses per litter.

Incidences of morphological findings from the gross, external, visceral, skeletal, and head examinations of pathology of placentae and fetuses (where applicable) are presented as number and percentage of affected fetuses per exposure group and as number and percentage of affected litters per exposure group.

### Analysis of Maternal Parameters and Uterine Contents

Maternal organ and body weight and fetal body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett and Williams.^42^ Nonnormally distributed variables, such as feed consumption and uterine content endpoints, were analyzed using the nonparametric multiple comparison methods of Shirley^43^ (as modified by Williams^44^) and Dunn.^45^ For all the continuous endpoints, the Jonckheere test^46^ was used to assess the significance of dose-related trends at p < 0.01 to determine whether a trend-sensitive test (Williams or Shirley test) was more appropriate than a test that does not assume a monotonic dose-related trend (the Dunnett or Dunn test). Before statistical analysis, extreme values identified by the outlier test of Dixon and Massey^47^ for small samples (n < 20) and Tukey’s outer fences method^48^ for large samples (n ≥ 20) were examined by NTP personnel, and implausible values were eliminated from the analysis.

Incidences of gross findings in the dams or does (binary endpoints) were analyzed using the Cochran-Armitage trend test^49^ and Fisher’s exact test.^50^

### Analysis of Fetal Findings

The tendency of littermates to respond more similarly than animals in different litters has been referred to as the “litter effect”^51^ and reflects littermates’ similarities in genetics and early life environment. Failure to account for correlation within litters leads to underestimates of variance in statistical tests, resulting in higher probabilities of Type I errors (“false positives”). To accommodate litter effects in the fetal findings data, the Cochran-Armitage test was modified using the Rao-Scott approach.^52^ The Rao-Scott approach accounts for litter effects by estimating the ratio of the variance in the presence of litter effects to the variance in the absence of litter effects. This ratio is then used to adjust the sample size downward to yield the estimated variance in the presence of litter effects. The Rao-Scott approach was implemented in the Cochran-Armitage test as recommended by Fung et al.,^53^ formula ₸_RS2_.

### Historical Control Data

The concurrent control group is the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP developmental and reproductive toxicity studies. However, historical control data are often helpful in interpreting potential exposure-related effects, particularly for uncommon fetal findings that occur at a very low incidence. For meaningful comparisons, the conditions for studies in the historical control database must be generally similar. Factors that might affect the background incidences of fetal findings at a variety of sites are diet, strain/stock, route of exposure, study type, and/or laboratory that conducted the study. The NTP historical control database for teratology studies contains all fetal evaluations (e.g., teratology studies or modified one-generation studies) for each laboratory. In general, the historical control database for a given study includes studies using the same route of administration and study design. However, historical control data for rats in this NTP Developmental and Reproductive Toxicity Technical Report contain data from gavage studies conducted at Southern Research. The concurrent controls are included in the historical control data set. There are no NTP historical control data available for rabbits. NTP historical controls are available online at https://ntp.niehs.nih.gov/data/controls/index.html.

## Quality Assurance Methods

The prenatal developmental toxicity study in rats and the dose range-finding and prenatal developmental toxicity studies in rabbits were conducted in compliance with U.S. Food and Drug Administration Good Laboratory Practice Regulations (21 CFR Part 58).^54^ Records from these studies were submitted to the NTP Archives. The prenatal developmental toxicity study in rats and the dose range-finding and prenatal developmental toxicity studies in rabbits were audited retrospectively by an independent quality assessment contractor. Separate audits covered completeness and accuracy of the final study data tables for the dose range-finding and prenatal developmental toxicity studies and a draft of this NTP Developmental and Reproductive Toxicity Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this report.