# Introduction

## Chemical and Physical Properties

2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine (MPEP)^1^ is a solid with a molecular mass of 321.4 g/mol (Figure 1). Its appearance at technical grade has been reported as colorless crystalline, white to off-white and powdery, or pale yellow and waxy. It has a melting point of 47°C, a vapor pressure of <9.8 × 10^−8^ mm Hg at 23°C, and a log K_OW_ of 5.37. MPEP has an estimated water solubility of 0.681 mg/L at 25°C and is readily soluble in hexane, methanol, and xylene.^1^

Figure 1

2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine (CASRN 95737-68-1; Chemical Formula: C_20_H_19_NO_3_; Molecular Weight: 321.4)

Synonyms: MPEP; MPPE; pyridine, 2-[1-methyl-2-(4-phenoxyphenoxy)ethoxy]-; 2-[1-methyl-2-(4-phenoxyphenoxy)ethoxy]pyridine; 2-((1-(4-phenoxyphenoxy)propan-2-yl)oxy)pyridine; pyriproxyfen.

Trade names: Nylar.

## Production, Use, and Human Exposure

MPEP is an insecticide that acts as a juvenile insect hormone analog and growth regulator. Insect exposure to MPEP prevents larvae from developing into adulthood, thus rendering them unable to reproduce. MPEP can be formulated into granules, aerosols, baits, carpet powders, foggers, pet shampoos, and collars, as well as into a general surface spray for food and nonfood areas. MPEP is used in agriculture and applied to pasture grass and rangeland to control a variety of insect populations.^2,3^

MPEP is also added to potable water^4^ to control mosquito populations, including the species that carry Zika virus. The Zika virus, a member of the Flaviviridae family (which also includes yellow fever, dengue, West Nile, and Chikungunya viruses), is carried by Aedes mosquitoes (A. aegypti and A. albopictus) and can also be transmitted from human to human via body fluids.^5^ Initial infection in humans is often characterized by fever, rash, joint pain, and conjunctivitis, and pregnant women who are infected with Zika virus have an increased risk of giving birth to a baby with microcephaly and other abnormalities.^6^ An increase in microcephaly was not reported in previous Zika virus outbreaks, but an outbreak in Brazil in 2015 was associated with almost 4,000 microcephaly cases by 2016.^5^ The Zika virus has been reported to be present in fetal brain tissue, which is common with other viruses. An increased incidence of Guillain-Barré syndrome (inflammatory peripheral neuropathy) has also been observed in the adult population exposed to the Zika virus.^5^ Although several risk assessments^4,7^ of MPEP have indicated that likely exposure levels are safe, the Brazilian Association for Collective Health requested that all growth inhibitor insecticides not be used in potable water. This position was highlighted by a report from physicians in the crop-sprayed villages, as well as by others,^8-10^ suggesting an association between the increase in microcephaly and MPEP exposure.

## Regulatory Status

The U.S. Environmental Protection Agency (EPA) has established tolerance levels ranging from 0.1 to 10 ppm for MPEP on specific fresh and processed vegetables and fruits, milk, and eggs with levels ≤20 ppm in citrus oil and 100 ppm in dried herbs.^2^ MPEP is also labeled for insect control on cotton, pasture grass, and rangeland.^3^ Adding MPEP granules to potable water in cisterns/barrels was approved by the World Health Organization in 2008 to control mosquito populations.^11^

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

Following a single oral administration of 2 or 1,000 mg/kg [^14^C]-labeled MPEP in male and female Sprague Dawley rats, the administered radioactivity was recovered in the feces (89%–92%) and urine (~8%) within 7 days of administration, although most of the radioactivity was excreted within 2 days.^12^ Radioactivity was distributed to tissues with peak concentrations in blood, kidney, and liver occurring 4–8 hours after, and in fat occurring 12–14 hours after, a single administration. On day 7 after a single oral dose, the residual radioactivity in tissues was <0.3% with fat containing the highest concentration. Following administration of a 2 mg/kg dose of [^14^C]-labeled MPEP, approximately 34% of the radioactivity was recovered in bile, suggesting part of the dose excreted in feces was likely from the absorbed dose. [^14^C]-labeled metabolites identified in feces, urine, and bile were products of hydroxylation at 2- or 4-positions of the terminal phenyl ring, products of hydroxylation at the 5-position of the pyridyl ring, and products from cleavage of the ether linkages and sulfation of the resulting phenols. The parent compound was detected only in feces, accounting for 25%–37% of the administered radioactivity.^12^

In liver microsomes, in the presence of nicotinamide adenine dinucleotide phosphate, most of the major metabolites of MPEP observed in vivo in rodents were also observed.^13^ Although no sex-related differences were observed in mouse microsomes, there were significant sex-related differences in rats for some of the metabolic pathways.

### Humans

The literature contains no studies on the absorption, distribution, metabolism, or excretion of MPEP in humans.

## Developmental and Reproductive Toxicity

### Experimental Animals

Publicly available data on the developmental and reproductive toxicity of MPEP are limited and include two summaries of studies in rats (Slc:SD and CRL:SD) conducted by the manufacturer to support registration. The first study showed that in a combined pre- and postnatal study design, female Slc:SD rats administered 0, 100, 300, or 1,000 mg MPEP/kg body weight/day (mg/kg/day) in corn oil from gestation day (GD) 7 to GD 17 exhibited excessive toxicity (mortality) at 1,000 mg/kg/day, whereas a 15% decrease in body weight gain was observed at 300 mg/kg/day. Increased incidences of cervical vertebrae variations were observed in fetuses in the 300 and 1,000 mg/kg/day groups. Postnatal findings on postnatal day (PND) 21 and/or PND 56 in both exposed groups included dilation of the renal pelvis. No MPEP-related effects were noted on motor coordination, learning, or physical and emotional development. No MPEP-related effects on reproductive performance of the dams were observed.^14^

In the second multigenerational study, CRL:SD rats were exposed to 0, 200, 1,000, or 5,000 ppm MPEP in the diet; estimated chemical intake was 87 and 453 mg/kg/day for the 1,000 and 5,000 ppm groups, respectively. Decreases in body weight, body weight gain, and feed consumption were observed in both sexes and generations. An increase in liver weights was observed in both sexes and was associated with liver and kidney histopathological findings in F_1_ males.^15^

In a rabbit developmental toxicity study,^16^ melted and cooled MPEP was administered via gavage (~1 mL/kg) at doses of 0, 100, 300, or 1,000 mg/kg/day from GD 6 to GD 18. Mortality and moribundity were noted in rabbits in the 1,000 mg/kg/day dose group. Other findings at this dose included soft stools, decreased feed consumption, decreased activity and bradypnea, and premature delivery/abortions. Similar findings, at lower incidences, were also observed in the 300 mg/kg/day dose group. Fetuses could be assessed in only 4 of the 13 available pregnant rabbits in the 1,000 mg/kg/day dose group. The other dose groups had 13/14 (0 mg/kg/day), 12/12 (100 mg/kg/day), and 11/14 (300 mg/kg/day) litters examined from their respective pregnant rabbits. No exposure-related findings were observed in the four litters examined in the 1,000 mg/kg/day dose group.

### Humans

The literature contains no studies on the developmental or reproductive toxicity of MPEP in humans.

## General Toxicity

### Experimental Animals

The rat oral median lethal dose (LD_50_) of technical grade MPEP is >5,000 mg/kg, and the rat dermal LD_50_ of MPEP is >2,000 mg/kg. The rat inhalation median lethal concentration (LC_50_) is >1.3 mg/L (highest concentration attainable). MPEP was not a dermal irritant or sensitizer in guinea pigs.^17-22^

Subchronic exposure of rats to MPEP via the diet at approximately 118–141 mg/kg/day was associated with higher mean total cholesterol and phospholipids, lower red blood cell, hematocrit, and hemoglobin counts, and higher relative liver weights compared to the control group (the no-observed-adverse-effect level was ~23.5–27.7 mg/kg/day). Subchronic exposure of dogs to MPEP via the diet at approximately 300 mg/kg/day and higher was associated with higher absolute and relative liver weights in males and higher incidences of hepatocellular hypertrophy in females compared to the control groups. These findings potentially represented adaptive changes. MPEP was not found to increase the incidences of neoplasms in either Sprague Dawley rats or CD-1 mice at a dietary exposure concentration of 3,000 ppm. Topical application of MPEP to rats at the limit dose of 1 g/kg was not associated with any adverse findings.^23-27^

### Humans

The literature contains no studies on the general toxicity of MPEP in humans.

## Study Rationale

Due to the concern that MPEP exposure may lead to increased incidences of birth defects in Zika virus-infected humans in regions where the insecticide is applied and because publicly available information is limited, NTP conducted studies to assess the potential for MPEP to induce fetal toxicity in well-characterized rat and rabbit prenatal developmental toxicity model systems. An assessment of blood and fetal concentrations was also included. In addition, MPEP was screened in a developmental zebrafish model.