# Appendix F Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NTP-DATA-DART-07.

## F.1 Prenatal Developmental Toxicity Study – Rats

I01 – Animal Removal Summary

I02 – Animal Removals

I03 – Growth Curve

I04 – Mean Body Weight Summary

I04G – Mean Body Weight Gain

I05 – Clinical Observations Summary

I06 – Mean Feed Consumption

PA46 – Summary of Gross Pathology

PA48 – Summary of Tissue Concentration

R09 – Uterine Content Summary

R10 – Fetal Defects

R11 – Fetal Defect Summary

R12 – Placental Findings

R13 – Fetal Defect Cross Reference Summary

## F.2 Prenatal Developmental Toxicity Individual Animal Data – Rats

Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Consumption Data

Individual Animal Gross Pathology Data

Individual Animal Removal Reasons Data

Individual Animal Teratology Dam Data

Individual Animal Teratology Fetal Weight Data

Individual Animal Teratology Implant Findings Data

Tissue Concentration (K16011)

## F.3 Prenatal Developmental Toxicity Dose Range-finding Study – Rabbits

I01 – Animal Removal Summary

I02 – Animal Removals

I03 – Growth Curve

I03C – Growth Curve

I04 – Mean Body Weight Summary

I04G – Mean Body Weight Gain

I05 – Clinical Observations Summary

I06 – Mean Feed Consumption

PA46 – Summary of Gross Pathology

R09 – Uterine Content Data

R10 – Fetal Defects

R11 – Fetal Defect Summary

R12 – Placental Findings

R13 – Fetal Defect Cross Reference Summary

## F.4 Prenatal Developmental Toxicity Dose Range-finding Individual Animal Data – Rabbits

Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Consumption Data

Individual Animal Gross Pathology Data

Individual Animal Removal Reasons Data

Individual Animal Teratology Dam Data

Individual Animal Teratology Fetal Weight Data

Individual Animal Teratology Implant Findings Data

## F.5 Prenatal Developmental Toxicity Study – Rabbits

I01 – Animal Removal Summary

I02 – Animal Removals

I03 – Growth Curve

I03C – Growth Curve

I04 – Mean Body Weight Summary

I04G – Mean Body Weight Gain

I05 – Clinical Observations Summary

I06 – Mean Feed Consumption

PA46 – Summary of Gross Pathology

PA48 – Summary of Tissue Concentration

R09 – Uterine Content Summary

R10 – Fetal Defects

R11 – Fetal Defect Summary

R12 – Placental Findings

R13 – Fetal Defect Cross Reference Summary

## F.6 Prenatal Developmental Toxicity Individual Animal Data – Rabbits

Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Consumption Data

Individual Animal Gross Pathology Data

Individual Animal Removal Reasons Data

Individual Animal Teratology Dam Data

Individual Animal Teratology Fetal Weight Data

Individual Animal Teratology Implant Findings Data

Individual Animal Tissue Concentration Data

## F.7 Zebrafish Data

Zebrafish MPEP CASRN 95737-68-1