# Appendix E Exploratory Developmental Toxicity of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine in Zebrafish Embryos

## Study Rationale

The embryonic zebrafish model is considered a useful alternative organism for high-throughput developmental toxicity testing^66,67^ or to complement results of rodent prenatal developmental toxicity studies. 2-((1-(4-phenoxyphenoxy)propan-2-yl)oxy)pyridine (MPEP) exposures during susceptible windows of development (i.e., in utero) have been hypothesized to cause or enhance the incidence of microcephaly in humans. Due to the transparency and rapid development of zebrafish embryos, adverse effects to the head or craniofacial region, such as microcephaly, can be monitored quickly and relatively easily. In previously published work, MPEP exposure to zebrafish embryos did not result in abnormal brain size.^68^ However, a broader screening assessment in zebrafish embryos revealed that MPEP can cause morphological alterations, including craniofacial deficits, at exposure concentrations of 5–30 μM.^57,58^ Inconsistent results across laboratories could be explained by different experimental designs and analysis. Due to varying results in the literature, the National Toxicology Program (NTP) elected to evaluate MPEP developmental toxicity in the zebrafish model for a comparison to prenatal toxicity data obtained in rats and rabbits.

## E.1 Materials and Methods

All experiments were conducted at Biobide (Donostia-San Sebastián, Spain). MPEP (lot number: 2-SEH-64-1, Toronto Research Chemicals, purity 99%) was supplied by the National Toxicology Program (NTP) (Research Triangle Park, NC) and studies were completed in conjunction with several other test chemicals described in Quevedo et al.^69^

In brief, the adult zebrafish line Tg(Cmlc2: copGFP) was used to evaluate embryo toxicity following chemical exposure. Fertilized embryos, at 4 hours postfertilization, were placed in 24-well plates with 0.5% dimethylsulfoxide (DMSO, vehicle control) or the corresponding MPEP concentration (0.5, 1, 2, 5, 10, 20, 50, or 100 μM; n = 15 embryos per concentration). The plates were covered and wrapped with aluminum foil to avoid degradation of light-sensitive compounds. Fifteen embryos were analyzed per condition after 2 or 4 days of incubation (i.e., 2 or 4 days postfertilization [dpf]) at 28.5°C. Detailed examination of embryo morphology (including malformations in the head, heart, and tail, deformed body shape, and the presence of edemas) and mortality was performed at 2 or 4 dpf. Embryo morphology was visualized under a stereo microscope (Olympus SXZ10, Waltham, MA) by experienced technicians. Morphologies found on study were recorded as present (1) or absent (0). The presence of morphological alterations was totaled for all fish to evaluate whether there was a concentration-related effect of MPEP exposure at 4 dpf. Statistical analysis was not conducted. Incidences of morphological alterations were compared to results in Quevedo et al.^69^ to provide context regarding the abundance of phenotypes in zebrafish.

## E.2 Results

Individual fish results are available in the NTP Chemical Effects in Biological Systems (CEBS) database.^55^ At 4 dpf, MPEP was overtly toxic in embryos exposed to 50 or 100 μM. In these concentration groups, 100% of fish did not survive and therefore a morphological assessment was not completed. Survival was not decreased in any other concentration group except at 20 μM MPEP, in which survival was 20% lower than for the vehicle control group. At MPEP exposure concentrations of 5–20 μM, occurrences of morphological alterations such as microcephaly, yolk sac edema, yolk opacity, heart edema, microphthalmia, and curved body were increased compared to DMSO vehicle control fish. Figure E-1 provides representative images of zebrafish larvae exposed to 5, 10, and 20 μM MPEP. Table E-1 tabulates the number of larvae that died and lists the occurrences of each type of morphological alteration up to 20 μM MPEP.

Figure E-1

Representative Images Corresponding to 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine Exposure in Zebrafish Four Days Postfertilization

DMSO = dimethylsulfoxide; dpf = days postfertilization. Observed effects include microcephaly (b), heart edema (c), microphthalmia (e), yolk sac edema (g), curved body shape (h), and yolk opacity (i).

Table E-1 Summary of Morphological Alterations in Zebrafish Following 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine Exposure

| MPEP Concentration (μM)
| DMSO | 0.5 | 1 | 2 | 5 | 10 | 20 | 50 | 100
n | 15 | 15 | 15 | 15 | 15 | 15 | 15 | 15 | 15
Morphology Endpoint
Mortality | 0 | 1 | 0 | 0 | 0 | 0 | 3 | 15 | 15
Jaw morphology | 0 | 0 | 0 | 0 | 0 | 0 | 0 | NA | NA
Microcephaly or abnormal head shape | 0 | 0 | 1 | 1 | 6 | 14 | 12 | NA | NA
Microphthalmia/cyclopia | 0 | 0 | 1 | 0 | 0 | 2 | 2 | NA | NA
Head edema | 0 | 0 | 0 | 0 | 0 | 0 | 0 | NA | NA
Malformation of the sacculi/otoliths | 0 | 0 | 0 | 0 | 0 | 0 | 0 | NA | NA
Heart edema/irregular shape | 0 | 0 | 1 | 2 | 2 | 6 | 10 | NA | NA
Abnormal heartbeat | 0 | 0 | 0 | 0 | 0 | 0 | 0 | NA | NA
Length alteration | 0 | 0 | 1 | 0 | 0 | 0 | 0 | NA | NA
Curved/curled | 0 | 0 | 0 | 0 | 0 | 2 | 10 | NA | NA
Notochord morphology | 0 | 0 | 0 | 0 | 0 | 0 | 0 | NA | NA
Tail malformations (including tail fins) | 0 | 0 | 0 | 0 | 0 | 0 | 0 | NA | NA
Yolk sac edema | 0 | 0 | 1 | 0 | 3 | 8 | 10 | NA | NA
Yolk opacity | 0 | 0 | 0 | 0 | 0 | 11 | 12 | NA | NA
Somite morphology | 0 | 0 | 0 | 0 | 0 | 0 | 0 | NA | NA
Other effects | 0 | 0 | 0 | 0 | 0 | 0 | 0 | NA | NA
Hatching | 0 | 0 | 0 | 0 | 0 | 0 | 0 | NA | NA
Necrotic tissues | 0 | 0 | 0 | 0 | 0 | 0 | 0 | NA | NA

Data represent the total number of zebrafish larva displaying each morphology after 4 days of MPEP exposure.

MPEP = 2-((1-(4-phenoxyphenoxy)propan-2-yl)oxy)pyridine; DMSO = dimethylsulfoxide; NA = not applicable.

## E.3 Data Interpretation

MPEP induced a number of morphological anomalies in the zebrafish head, heart, yolk sac, and body shape in a concentration-dependent manner. With the hypothesized concern for MPEP to cause craniofacial abnormalities, it was shown that MPEP does result in microcephaly with a calculated median effective concentration (EC_50_) of 5.4 μM. These results support findings in Padilla et al.^57^ and Troung et al.^58^ but differ from NTP studies in traditional mammalian models of developmental toxicity.