# Appendix D 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine Internal Dose Assessment

## D.1 Sample Collection

### D.1.1 Prenatal Developmental Toxicity Study in Rats

On gestation day (GD) 18, blood was collected from dams designated for biological sampling from the 0 (vehicle control), 62.5, and 125 mg MPEP/kg body weight/day (mg/kg/day) groups (n = 3 or 4 per dose group). Blood was collected via cardiac puncture into tubes containing tripotassium ethylenediaminetetraacetic acid (K_3_ EDTA) and kept on ice until processing. Blood samples were centrifuged (refrigerated), and plasma was isolated. Following maternal blood collection, amniotic fluid was collected and pooled by litter. Fetuses were removed from amniotic sacs, euthanized by decapitation, collected, frozen, and pooled by litter. All samples were collected approximately 2 hours after the last dose and within 2 hours of each other. All samples were frozen at approximately −70°C and shipped on dry ice to the analytical laboratory at RTI International (Research Triangle Park, NC).

### D.1.2 Prenatal Developmental Toxicity Study in Rabbits

On GD 27, blood (enough to yield 1–1.5 mL plasma) was collected from does designated for biological sampling (n = 3 per dose group) at four time points (before dosing and at 4, 8, and 24 hours postdose). Collection at 24 hours occurred before dosing on GD 28. On GD 28, approximately 2 hours after the last dose, blood was collected from the same does and their fetuses. For does, blood was collected from the central ear artery or lateral ear vein into tubes containing K_3_ EDTA. All samples were collected approximately 2 hours after the last dose and within 2 hours of each other and kept on ice until processing.

Following maternal blood collection on GD 28, does were euthanized and fetuses were collected, individually weighed, and euthanized. Trunk blood was collected (as much as possible) from each fetus. All samples were collected approximately 2 hours after the last dose and within 2 hours of each other and kept on ice until processing.

Plasma was isolated as described above and flash frozen at approximately −70°C. Frozen samples were shipped on dry ice to the analytical laboratory at RTI International (Research Triangle Park, NC).

## D.2 Sample Analysis

### D.2.1 Method Qualification and Results

All samples were analyzed using a qualified method. The method was evaluated using commercially procured adult male Sprague Dawley rat plasma by analyzing calibration standards and quality control (QC) samples in replicates to demonstrate linearity, sensitivity, precision, and accuracy over the concentration range 10–1,000 ng/mL. Accuracy was evaluated as percent relative error (% RE) and precision as relative standard deviation (RSD). The limit of quantitation (LOQ) was evaluated by preparing six replicates at the lowest calibration standard. The limit of detection (LOD) was defined as three times the standard deviation of the LOQ response expressed as concentration. Precision and accuracy were evaluated at two concentrations (20 and 500 ng/mL) using three independent standards prepared on the same day. Selectivity was assessed by analyzing triplicate matrix blanks (adult male commercial Sprague Dawley rat plasma, GD 18 study Sprague Dawley rat dam plasma, amniotic fluid, and fetus homogenate) for background interferences and comparing to the response relative to the LOQ (10 ng/mL, Table D-2). Fetal homogenates were prepared by homogenizing fetuses in chilled water (1:1, w/v). Storage stabilities of MPEP in the study matrices were assessed at 200 ng/mL when stored at approximately −70°C; data were compared against freshly prepared samples at the same concentration.

Two standard stock solutions of MPEP were prepared at 250 and 500 ug/mL in methanol. Spiking solutions of MPEP (25–5,000 ng/mL) were prepared in methanol using alternate stock solutions and were used to prepare the matrix calibration standards and QC samples. A working solution of the internal standard d4-2-((1-(4-phenoxyphenoxy)propan-2-yl)oxy)pyridine (d4-MPEP, C/D/N Isotopes, Pointe-Claire, Quebec, Canada) was prepared at 500 ng/mL in methanol. Standard solutions were stored refrigerated (~5°C) when not in use.

Plasma calibration standards were prepared by fortifying 50 μL of blank commercial male Sprague Dawley rat plasma with 10 μL of the appropriate spiking standard to obtain plasma MPEP concentrations of 10, 20, 100, 250, 500, and 1,000 ng/mL. QC samples were prepared similarly at 20 and 500 ng/mL. For matrix blanks, 10 μL of methanol were substituted for the spiking solution. A 10 μL aliquot of the internal standard solution was added to each sample, followed by 150 μL acetonitrile. Samples were vortexed for 1 minute and centrifuged at 12,000 rpm for 10 minutes at 4°C, and the supernatants were collected. Amniotic fluid and fetal homogenate samples were prepared similarly using 50 μL aliquots.

Supernatants were analyzed by ultra-performance liquid chromatography (UPLC) with tandem mass spectrometry (MS/MS) using the system in Table D-1.

Calibration curves were generated by plotting the peak area ratios of MPEP to d4-MPEP as a function of analyte concentration. The regression model for MPEP was a linear weighted least squares algorithm with a weighting factor of 1/concentration-squared (1/x^2^). The concentration of MPEP was calculated using response ratio and the regression equation. Plasma and amniotic fluid data are expressed as ng/mL, whereas fetus data are expressed as ng/g fetus.

The method qualification data are given in Table D-2, and stability data are given in Table D-3. Background concentrations of MPEP were detected in all matrices and were lower than the LOQ set for the matrix concentration range (44%–50% of LOQ). These data suggest that the analytical method developed for commercial Sprague Dawley rat plasma was suitable for quantitation of MPEP in rat and rabbit study matrices. In addition, MPEP was stable in rat study matrices (GD 18 dam plasma, amniotic fluid, and fetus homogenate) under the study sample storage conditions and duration.

### D.2.2 Study Sample Analysis

Study biological samples were thawed prior to aliquoting. Study samples were prepared and analyzed similar to matrix standards above except the addition of MPEP. Fetuses were thawed, and two were randomly selected and weight recorded. Each fetus was combined with 2.3-mm stainless-steel beads equal to two times the weight of fetus and homogenized at 1,750 rpm for 2 minutes. A 1:1 volume of fetal homogenate to chilled water (1:1, w/v) was added and the fetuses were homogenized again at 1,750 rpm for 2 minutes. The two fetuses were combined and homogenized together at 1,750 rpm for 1 minute, then placed on ice until analysis. The combined fetus homogenate was then prepared using the same procedure as for plasma samples.

Study samples that were above the upper limit of the calibration curve (1,000 ng/mL) were reanalyzed by diluting 1:10 with the corresponding matrix and were processed similar to above.

Table D-1 Ultra-performance Liquid Chromatography with Tandem Mass Spectrometry System and Parameters

| Instrument Parameter
System | Waters Acquity UPLC/Applied Biosystems 4000 QTRAP (Water Corp., Milford MA/Applied Biosystems, Framingham, MA)
Column | Waters Acquity UPLC BEH C18 (2.1 × 50 mm ID, 1.7 μm film thickness)
Mobile Phase | A: 0.1% formic acid in 80:20 water:acetonitrile B: 0.1% formic acid in acetonitrile
Binary Gradient | Hold at 80:20 for 2 minutes, ramp to 5:95 in 10 minutes, hold at 5:95 for 2 minutes, reverse to 80:20 in 0.5 minutes, hold at 80:20 for 1.5 minutes; total run time = 16 minutes
Flow Rate | 0.3 mL/minute
Injection Volume | 5 μL
Ionization Mode | ESI, positive ion mode
Curtain Gas | Nitrogen, 35 psi
CAD Gas | 12 psi
IonSpray Voltage | 4,000 V
Source Temperature | 350°C
Ion Source Gas 1 | Nitrogen, 15 psi
Ion Source Gas 2 | Nitrogen, 50 psi
Interface Heater | On
MRM Transitions | 321.9/95.9 (MPEP); 326.1/100.1 (IS)
Declustering Potential | 35 V (MPEP); 45 V (IS)
Entrance Potential | 10 V
Collision Energy | 23 V (MPEP); 35 V (IS)
Collision Cell Exit Potential | 8 V (MPEP); 10 V (IS)
Data System | AB Sciex Analyst 1.6.2

UPLC = ultra-performance liquid chromatography; ESI = electrospray ionization; CAD = charged aerosol detector; MRM = multiple reaction monitoring; MPEP = 2-((1-(4-phenoxyphenoxy)propan-2-yl)oxy)pyridine; IS = internal standard.

Table D-2 Analytic Method Qualification for Detection and Quantitation of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine in Biological Matrices

Parameter | Result
Plasma Matrix Concentration Range (ng/mL) | 10–1,000
LOD^a^ (ng/mL) | 3.12
LOQ^b^ (ng/mL) | 10.6
Precision (% RSD) (at LOQ) | 10.2
Accuracy (mean % RE) (at LOQ) | ≤13.7
Correlation Coefficient (r) | ≥0.99
Assay Precision and Accuracy^c^
Commercial male Sprague Dawley rat plasma
Precision (% RSD) | ≤3.6
Accuracy (% RE) | ≤ ± 9.9
Study GD 18 rat dam plasma^d^
Precision (% RSD) | ≤8.1
Accuracy (% RE) | ≤ ± 15.4
Study GD 18 rat fetal homogenate^d^
Precision (% RSD) | ≤ 20.0
Accuracy (% RE) | ≤ ± 10.3
Study GD 18 rat amniotic fluid^d^
Precision (% RSD) | ≤4.1
Accuracy (% RE) | ≤ ± 7.9
Rabbit doe plasma
Precision (% RSD) | 14.3
Accuracy (mean % RE) | 1.8
Rabbit fetal plasma
Precision (% RSD) | 8.03
Accuracy (mean % RE) | 4.9
Method Selectivity (%)^e^
Male Sprague Dawley rat plasma | 46
Study GD 18 rat dam plasma^d^ | 47
Study GD 18 rat fetal homogenate^d^ | 33
Study GD 18 rat amniotic fluid^d^ | 40
Rabbit doe plasma | 50
Rabbit fetal plasma | 48

% RSD = percent relative standard deviation; % RE = percent relative error; GD = gestation day.

^a^ LOD = limit of detection; equivalent to 6.24 ng/g fetus.

^b^ LOQ = limit of quantitation; lowest standard at which RE ≤ ±20% and RSD ≤20% for n = 6. Due to background concentrations observed in biological matrices, LOQ was set at 10 ng/mL.

^c^ Precision and accuracy determined for triplicate quality controls (QCs) prepared at both at 20 and 500 ng/mL except for rabbit matrices where values were determined using QC samples (n = 6) prepared at 9.25 ng/mL.

^d^ Study strain: Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^).

^e^ Selectivity was assessed in blank study matrices by comparing the response relative to LOQ (10 ng/mL). Values give are % response relative to LOQ response.

Table D-3 Stability Data for 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine in Biological Matrices^a^

Matrix (Storage Duration) | Mean % of Day 0 (% RSD)
Study GD 18 Rat Dam Plasma (95 Days) | 135 (12.9)
Study GD 18 Rat Fetal Homogenate (104 Days) | 75.2 (6.6)
Study GD 18 Rat Amniotic Fluid (95 Days) | 74.7 (1.8)

% RSD = percent relative standard deviation; GD = gestation day.

^a^ Determined for triplicate quality controls at 200 ng/mL and stored at −70°C and compared against freshly prepared samples.