# Appendix C Sentinel Animal Program

## C.1 Methods

Animals used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that might affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the animals is monitored via sera or feces from extra (sentinel) or exposed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

For these studies, blood was collected per the following methods:

- Rats: Blood samples were collected, allowed to clot, and the serum was separated. All samples were processed appropriately with serology testing performed by IDEXX BioResearch (formerly Rodent Animal Diagnostic Laboratory [RADIL]), University of Missouri), Columbia, MO for determination of the presence of pathogens. Evaluation for endo- and ectoparasites was performed in-house by the testing laboratory.
- Rabbits: Blood samples were collected via dried blood spot sampling technology. All samples were processed appropriately with serology testing performed by IDEXX BioResearch (formerly Rodent Animal Diagnostic Laboratory (RADIL), University of Missouri), Columbia, MO for determination of the presence of pathogens. Fur swabs were collected for ectoparasite evaluations.

The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Table C-1 Methods and Results for Sentinel Animal Testing in Female Rats

Collection Time Points | Arrival | End of Study
Number Examined (Females)^a^ | 5 | 5
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Kilham rat virus (KRV) | – | –
Mycoplasma pulmonis | – | –
Pneumonia virus of mice (PVM) | – | –
Rat coronavirus/sialodacryoadenitis virus (RCV/SDA) | – | –
Rat minute virus (RMV) | – | –
Rat parvo virus (RPV) | – | –
Rat theilovirus (RTV) | – | –
Sendai | – | –
Theiler’s murine encephalomyelitis virus (TMEV) | – | –
Toolan’s H-1 | – | –
In-house Evaluation
Endoparasites | – | –
Ectoparasites | – | –

– = negative.

^a^ Age-matched nonpregnant females

Table C-2 Methods and Results for Sentinel Animal Testing in Female Rabbits

Collection Time Points | Dose Range-finding Study | | Prenatal Developmental Toxicity Study
Collection Time Points | 1–2 Weeks after Study Start^a^ | End of Study | Study Start | End of Study
Number Examined (Females) | 4 | 9 | 1 | 10
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
CAR bacillus | – | – | – | –
Clostridium piliform | – | – | – | –
Encephalitozoon cuniculi | – | – | – | –
Rotavirus | + | + | + | +
Immunofluorescence Assay (IFA)
Clostridium piliform | NT | NT | NT | –
Rotavirus | + | + | + | NT
Treponema | – | – | – | –
PCR Evaluation
Ectoparasites (fur swab)
Myocoptes | NT | NT | NT | –
Radfordia/myobia | NT | NT | NT | –

– = negative; + = positive; NT = not tested; CAR = cilia-associated respiratory; PCR = polymerase chain reaction.

^a^ Euthanized due to moribundity.

## C.2 Results

Antibodies to rotavirus were detected in all rabbit samples tested. Rotavirus is a common virus in rabbits that was not considered to have affected the study results. All other test results were negative.