# Appendix B Ingredients, Nutrient Composition, and Contaminant Levels in Rat and Rabbit Rations

## B.1 Prenatal Developmental Toxicity Study in Rats

Table B-1 Ingredients of NIH-07 Rat Ration

Ingredients | Percent by Weight
Ground #2 Yellow Shelled Corn | 24.25
Ground Hard Winter Wheat | 23.00
Soybean Meal (47% Protein) | 12.00
Wheat Middlings | 10.00
Fish Meal (62% Protein) | 10.00
Dried Skim Milk | 5.00
Alfalfa Meal (Dehydrated, 17% Protein) | 4.00
Corn Gluten Meal (60% Protein) | 3.00
Soy Oil (without Preservatives) | 2.50
Dried Brewer’s Yeast | 2.00
Dried Molasses | 1.50
Calcium Phosphate, Dibasic (USP) | 1.25
Calcium Carbonate (USP) | 0.50
Salt | 0.5
Premixes (Vitamin)^a^ | 0.25
Premixes (Mineral)^b^ | 0.15
Choline Chloride (70% Choline) | 0.10

USP = United States Pharmacopeia.

^a^ Wheat middling as carrier.

^b^ Calcium carbonate as carrier.

Table B-2 Vitamins and Minerals in NIH-07 Rat Ration^a^

| Amount | Source
Vitamins
A | 6,062 IU | Stabilized vitamin A palmitate or acetate
D | 5,070 IU | D-activated animal sterol
K | 3.09 mg | Menadione (MSBC)
E | 22 IU | α-Tocopheryl acetate
Niacin | 33 mg | –
Folic acid | 2.4 mg | –
d-Pantothenic acid | 19.8 mg | d-Calcium pantothenate
Riboflavin | 3.8 mg | –
Thiamin | 11 mg | Thiamine mononitrate
B_12_ | 50 μg | –
Pyridoxine | 6.5 mg | Pyridozine hydrochloride
Biotin | 0.15 mg | d-Biotin
Minerals
Iron | 132 mg | Iron sulfate
Zinc | 18 mg | Zinc oxide
Manganese | 66 mg | Manganese oxide
Copper | 4.4 mg | Copper sulfate
Iodine | 1.5 mg | Calcium iodate
Cobalt | 0.44 mg | Cobalt carbonate

MSBC = menadione sodium bisulfite complex.

^a^ Per kg of finished product.

Table B-3 Nutrient Composition of NIH-07 Rat Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 23.3 | – | 1
Crude Fat (% by Weight) | 5 | – | 1
Crude Fiber (% by Weight) | 3.49 | – | 1
Ash (% by Weight) | 6.6 | – | 1
Amino Acids (% of Total Diet)
Arginine | 1.376 ± 0.061 | 1.3–1.49 | 9
Cystine | 0.322 ± 0.033 | 0.274–0.372 | 9
Glycine | 1.147 ± 0.073 | 1.06–1.31 | 9
Histidine | 0.514 ± 0.022 | 0.497–0.553 | 9
Isoleucine | 0.981 ± 0.023 | 0.952–1.03 | 9
Leucine | 2.011 ± 0.067 | 1.93–2.13 | 9
Lysine | 1.247 ± 0.053 | 1.13–1.32 | 9
Methionine | 0.486 ± 0.015 | 0.468–0.515 | 9
Phenylalanine | 1.094 ± 0.021 | 1.07–1.12 | 9
Threonine | 0.915 ± 0.032 | 0.883–0.961 | 9
Tryptophan | 0.280 ± 0.021 | 0.265–0.326 | 9
Tyrosine | 0.859 ± 0.039 | 0.785–0.894 | 9
Valine | 1.131 ± 0.024 | 1.11–1.17 | 9
Essential Fatty Acids (% of Total Diet)
Linoleic | 2.34 ± 0.201 | 2.04–2.59 | 9
Linolenic | 0.25 ± 0.028 | 0.217–0.296 | 9
Vitamins
Vitamin A (IU/kg) | 4,860 | – | 1
α–Tocopherol (ppm) | 7,442 ± 22,184 | 40.3–66,600 | 9
Thiamine^a^ (ppm) | 11.1 | – | 1
Riboflavin (ppm) | 14.1 ± 3.37 | 10–19.8 | 9
Niacin (ppm) | 99 ± 8.63 | 87–112 | 9
Pantothenic acid (ppm) | 44.8 ± 3.82 | 38.2–51.1 | 9
Pyridoxine^a^ (ppm) | 13.2 ± 3.23 | 9.63–19.7 | 9
Folic Acid (ppm) | 2.47 ± 0.514 | 1.68–3.09 | 9
Biotin (ppm) | 0.304 ± 0.163 | 0.0–0.64 | 9
Vitamin B_12_ (ppb) | 49.89 ± 7.06 | 41.8–61.6 | 9
Choline (as Chloride) (ppm) | 1,801 ± 198 | 1,570–2,200 | 9
Minerals
Calcium (%) | 0.980 | – | 1
Phosphorus (%) | 0.887 | – | 1
Potassium (%) | 0.833 ± 0.036 | 0.769–0.88 | 9
Chloride (%) | 0.641 ± 0.107 | 0.441–0.8 | 9
Sodium (%) | 0.374 ± 0.047 | 0.318–0.469 | 9
Magnesium (%) | 0.186 ± 0.014 | 0.170–0.218 | 9
Iron (ppm) | 386.6 ± 58.0 | 276–469 | 9
Manganese (ppm) | 91.58 ± 7.60 | 80.7–104 | 9
Zinc (ppm) | 64.41 ± 10.64 | 52.4–89.2 | 9
Copper (ppm) | 14.1 ± 2.73 | 11.9–21.1 | 9
Iodine (ppm) | 1.63 ± 0.862 | 0.54–3.45 | 9
Chromium (ppm) | 3.95 ± 0.030 | 3.91–4.00 | 9
Cobalt (ppm) | 0.51 ± 0.282 | 0.01–0.963 | 9

^a^ As hydrochloride (thiamine and pyridoxine).

Table B-4 Contaminant Levels in NIH-07 Rat Ration^a^

| Mean | Number of Samples
Contaminants
Arsenic (ppm) | 0.576 | 1
Cadmium (ppm) | 0.09 | 1
Lead (ppm) | 0.077 | 1
Mercury (ppm) | 0.018 | 1
Selenium (ppm) | 0.298 | 1
Aflatoxins (ppb)^b^ | <5.00 | 1
Nitrate Nitrogen^b,c^ (ppm) | <10.0 | 1
Nitrite Nitrogen^b,c^ (ppm) | <0.61 | 1
BHA^b,d^ (ppm) | <1.0 | 1
BHT^b,d^ (ppm) | <1.0 | 1
Aerobic Plate Count (CFU/g) | <10 | 1
Coliform (MPN/gm) | <3 | 1
Escherichia coli (MPN/g) | <10 | 1
Salmonella (MPN/g) | Negative | 1
Total Nitrosamines^e^ (ppb) | 4.3 | 1
N–Nitrosodimethylamine^e^ (ppb) | 1.8 | 1
N–Nitrosopyrrolidine^e^ (ppb) | 2.5 | 1
Pesticides (ppm)
α-BHC^b^ | <0.01 | 1
β-BHC^b^ | <0.02 | 1
γ-BHC^b^ | <0.01 | 1
δ-BHC^b^ | <0.01 | 1
Heptachlor^b^ | <0.01 | 1
Aldrin^b^ | <0.01 | 1
Heptachlor Epoxide^b^ | <0.01 | 1
DDE^b^ | <0.01 | 1
DDD^b^ | <0.01 | 1
DDT^b^ | <0.01 | 1
HCB^b^ | <0.01 | 1
Mirex^b^ | <0.01 | 1
Methoxychlor^b^ | <0.05 | 1
Dieldrin^b^ | <0.01 | 1
Endrin^b^ | <0.01 | 1
Telodrin^b^ | <0.01 | 1
Chlordane^b^ | <0.05 | 1
Toxaphene^b^ | <0.10 | 1
Estimated PCBs^b^ | <0.20 | 1
Ronnel^b^ | <0.01 | 1
Ethion^b^ | <0.02 | 1
Trithion^b^ | <0.05 | 1
Diazinon^b^ | <0.10 | 1
Methyl Chlorpyrifos | 0.015 | 1
Methyl Parathion^b^ | <0.02 | 1
Ethyl Parathion^b^ | <0.02 | 1
Malathion | 0.11 | 1
Endosulfan I^b^ | <0.01 | 1
Endosulfan II^b^ | <0.01 | 1
Endosulfane Sulfate^b^ | <0.03 | 1

All samples were irradiated. BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ Concentrations of 2-((1-(4-phenoxyphenoxy)propan-2-yl)oxy)pyridine in feed were confirmed to be below the limit of quantitation of the feed analysis method of 0.01 mg/kg feed.

^b^ All values were below the limit of detection. The detection limit is given as the mean.

^c^ Sources of contamination include alfalfa, grains, and fish meal.

^d^ Sources of contamination include soy oil and fish meal.

^e^ All values were corrected for percent recovery.

## B.2 Dose Range-finding Study in Rabbits

Additional information on ingredients, vitamins, and minerals in the 5L3M rabbit ration diet can be found online.^65^

Table B-5 Nutrient Composition of Purina 5L3M Rabbit Ration

Nutrient | Mean | Number of Samples
Protein (% by Weight) | 14.9 | 1
Crude Fat (% by Weight) | 3.4 | 1
Crude Fiber (% by Weight) | 22.6 | 1
Ash (% by Weight) | 8.66 | 1
Vitamins
Vitamin A (IU/kg) | 16,800 | 1
Thiamine^a^ (ppm) | 4.4 | 1
Minerals
Calcium (%) | 1.36 | 1
Phosphorus (%) | 0.562 | 1

^a^ As hydrochloride (thiamine).

Table B-6 Contaminant Levels in Purina 5L3M Rabbit Ration

| Mean | Number of Samples
Contaminants
Arsenic (ppm) | 0.274 | 1
Cadmium (ppm) | 0.15 | 1
Lead (ppm) | 0.213 | 1
Mercury^a^(ppm) | <0.0050 | 1
Selenium (ppm) | 0.368 | 1
Aflatoxins (ppb) | 5.3 | 1
Nitrate Nitrogen^b^ (ppm) | 40 | 1
Nitrite Nitrogen^b^ (ppm) | 0.122 | 1
BHA^b^ (ppm) | <1.0 | 1
BHT^b^ (ppm) | <1.0 | 1
Aerobic Plate Count (CFU/g) | <10.0 | 1
Coliform (MPN/gm) | <10.0 | 1
Escherichia coli (MPN/g) | <10.0 | 1
Enterobacteriaceae (CFU/g) | <10.0 | 1
Total Nitrosamines^c^ (ppb) | 49.1 | 1
N–Nitrosodimethylamine^c^ (ppb) | 7 | 1
N–Nitrosopyrrolidine^c^ (ppb) | 42.1 | 1
Pesticides (ppm)
β-BHC^a^ | <0.01 | 1
γ-BHC^a^ | <0.01 | 1
δ-BHC^a^ | <0.01 | 1
Heptachlor^a^ | <0.01 | 1
Aldrin^a^ | <0.01 | 1
Heptachlor Epoxide^a^ | <0.01 | 1
DDE^a^ | <0.01 | 1
DDD^a^ | <0.01 | 1
DDT^a^ | <0.01 | 1
Mirex^a^ | <0.01 | 1
Methoxychlor^a^ | <0.01 | 1
Dieldrin^a^ | <0.01 | 1
Endrin^a^ | <0.01 | 1
Chlordane^a^ | <0.01 | 1
Ethion^a^ | <0.01 | 1
Diazinon^a^ | <0.01 | 1
Methyl Chlorpyrifos^a^ | <0.01 | 1
Methyl Parathion^a^ | <0.01 | 1
Ethyl Parathion^a^ | <0.01 | 1
Malathion | 0.018 | 1
Endosulfan I^a^ | <0.02 | 1
Endosulfan II^a^ | <0.02 | 1
Endosulfane Sulfate^a^ | <0.02 | 1

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ For values below the detection limit, the detection limit is given as the mean.

^b^ Sources of contamination include alfalfa and grains.

^c^ All values were corrected for percent recovery.

## B.3 Prenatal Developmental Toxicity Study in Rabbits

Additional information on ingredients, vitamins, and minerals in the 5L3M rabbit ration diet can be found online.^65^

Table B-7 Nutrient Composition of Purina 5L3M Rabbit Ration

Nutrient | Mean | Number of Samples
Protein (% by Weight) | 15.1 | 1
Crude Fat (% by Weight) | 3.5 | 1
Crude Fiber (% by Weight) | 21.6 | 1
Ash (% by Weight) | 8.47 | 1
Vitamins
Vitamin A (IU/kg) | 14,900 | 1
Thiamine^a^ (ppm) | 3.8 | 1
Minerals
Calcium (%) | 1.240 | 1
Phosphorus (%) | 0.522 | 1

^a^ As hydrochloride (thiamine).

Table B-8 Contaminant Levels in Purina 5L3M Rabbit Ration

| Mean | Number of Samples
Contaminants
Arsenic (ppm) | 0.282 | 1
Cadmium (ppm) | 0.151 | 1
Lead (ppm) | 0.229 | 1
Mercury (ppm)^a^ | <0.0050 | 1
Selenium (ppm) | 0.406 | 1
Aflatoxins^a^ (ppb) | <5.00 | 1
Nitrate Nitrogen^b^ (ppm) | 50.1 | 1
Nitrite Nitrogen^b^ (ppm) | 4.3 | 1
BHA^a^ (ppm) | <1.0 | 1
BHT (ppm) | 2.22 | 1
Aerobic Plate Count^c^ (CFU/g) | 15,000 | 1
Coliform^c^ (CFU/gm) | 10.0 | 1
Escherichia coli^c^ (CFU/g) | <10 | 1
Enterobacteriaceae^c^ (CFU/g) | 30 | 1
Total Nitrosamines^d^ (ppb) | 51.9 | 1
N–Nitrosodimethylamine^d^ (ppb) | 4.7 | 1
N–Nitrosopyrrolidine^d^ (ppb) | 47.2 | 1
Pesticides (ppm)
β-BHC^a^ | <0.01 | 1
γ-BHC^a^ | <0.01 | 1
δ-BHC^a^ | <0.01 | 1
Heptachlor^a^ | <0.01 | 1
Aldrin^a^ | <0.01 | 1
Heptachlor Epoxide^a^ | <0.01 | 1
DDE^a^ | <0.01 | 1
DDD^a^ | <0.01 | 1
DDT^a^ | <0.01 | 1
Mirex^a^ | <0.01 | 1
Methoxychlor^a^ | <0.01 | 1
Dieldrin^a^ | <0.01 | 1
Endrin^a^ | <0.01 | 1
Chlordane^a^ | <0.01 | 1
Ethion^a^ | <0.01 | 1
Diazinon^a^ | <0.01 | 1
Methyl Chlorpyrifos^a^ | <0.01 | 1
Methyl Parathion^a^ | <0.01 | 1
Ethyl Parathion^a^ | <0.01 | 1
Malathion | 0.011 | 1
Endosulfan I^a^ | <0.02 | 1
Endosulfan II^a^ | <0.02 | 1
Endosulfane Sulfate^a^ | <0.02 | 1

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane.

^a^ For values below the detection limit, the detection limit is given as the mean.

^b^ Sources of contamination include alfalfa and grains.

^c^ Preirradiation sample.

^d^ All values were corrected for percent recovery.