# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization

### A.1.1 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine (MPEP) was obtained from AK Scientific, Inc. (Union City, CA) in a single lot (JL44164). Identity, purity, and stability analyses were conducted by the analytical chemistry lab at RTI International (Research Triangle Park, NC). Reports on analyses performed in support of the MPEP studies are on file at the National Institute of Environmental Health Sciences.

MPEP was received as a white powder. The melting point of lot JL44164 was 46.6°C–47.9°C, which is consistent with literature values (45°C–47°C). Elemental analysis was consistent with the theoretical values of MPEP. Lot JL44164 was identified using infrared (IR) spectroscopy, ^1^H nuclear magnetic resonance (NMR) spectroscopy, and ^13^C NMR spectroscopy. Additionally, three types of 2-dimensional NMR were used to verify identity: proton-proton correlation spectroscopy (COSY), proton-carbon correlation spectroscopy (HSQC), and long-range proton-carbon correlation spectroscopy (HMBC). Gas chromatography (GC) with mass spectrometry detection (MS) also confirmed the identity of lot JL44164 (Table A-1, System A).

The IR spectrum was consistent with a reference spectrum of MPEP from the National Institute of Advanced Industrial Science and Technology (AIST) Spectral Database (No. 53368) (Figure A-1). Both ^1^H and ^13^C NMR spectra were in good agreement with library references from the AIST Spectral Database (No. HR2014-02914NS and CR2014-02914NS, respectively), as well as predicted spectra from Advanced Chemistry Development (ACD) spectral prediction program (Version 10.02, Toronto, Ontario, Canada) (Figure A-2). The high-resolution NMR techniques (COSY, HSQC, and HMBC) matched the ACD-predicted spectra and indicated impurity of <5%. The GC/MS spectra correlated well to the structure of MPEP.

The moisture content of lot JL44164 was determined by Karl Fisher titration. The purity of lot JL44164 was evaluated using GC with flame ionization detection (FID) and ultra-performance liquid chromatography (UPLC) with a photodiode array detector (PDA, 210 nm) (Table A-1, Systems B and C, respectively). Karl Fisher titration yielded water content of 0.03%. The GC/FID analysis determined the purity to be 99.6%; one impurity peak with 0.1% and seven peaks <0.1% of the total response were identified. The UPLC/PDA analysis determined purity to be 97.7% with two impurity peaks with 1.6% and 0.3% and 15 additional peaks <0.1%. The overall purity of lot JL44164 was estimated to be >97.7%.

Accelerated stability studies were conducted on samples of MPEP stored at 60°C, 22°C, 5°C, and −20°C using the UPLC/PDA described above. Stability was confirmed for at least 2 weeks when stored in sealed amber glass bottles sealed with Teflon-lined caps at 25°C, 5°C, and −20°C. Lot JL44164 was received in a 15 kg drum. Lot JL44164 was homogenized and transferred into 80-ounce bottles with Teflon sealed caps and stored at room temperature. Lot JL44164 was periodically analyzed (Table A-1, System D) to ensure no degradation relative to a frozen reference sample.

### A.1.2 Corn Oil

Corn oil was obtained from Welch, Holme & Clark Co. Inc (Newark, NJ) in a single lot (0120-0576) and used as a vehicle in the dose range-finding and prenatal developmental toxicity studies. A solubility and suspendability study of MPEP in corn oil determined that the test article was suspendable at up to 250 mg/mL and soluble at up to 136 mg/mL. Lot 0120-0576 contained peroxide levels that were less than the rejection level of 3 milliequivalents (meQ)/kg corn oil.

## A.2 Preparation and Analysis of Dose Formulations

Dose formulations of MPEP were prepared in corn oil following the protocols outlined in Table A-2. The rat and rabbit prenatal developmental toxicity studies used dose formulations of 31.25, 62.5, 125, and 250 mg/mL (rat only). Dose formulations of 150, 200, and 250 mg/mL were used in the rabbit dose range-finding study. Prior to study start, a homogeneity study at 250 mg/mL and a stability study at 1 mg/mL dose formulations were conducted using GC/FID (Table A-1, System D). Homogeneity and stability were confirmed for 42 days at room temperature (~25°C) when stored in clear glass bottles with Teflon-lined caps. To simulate conditions in the animal room, the 1 mg/mL formulation was stored in glass bottles at room temperature exposed to air and light for 3 hours. No loss in MPEP was found under these conditions.

Analysis of preadministration and postadministration dose formulations was conducted using GC/FID within 2 days of preparation and at the conclusion of the studies (Table A-3, Table A-4, Table A-5). Postadministration samples were collected from the remainder of the formulations in the day’s bottles. All dose formulation samples in the rat and rabbit prenatal developmental toxicity studies were within 10% of the target concentrations except for the 250 mg/mL postadministration sample in the rabbit dose range-finding study which was 21.3% above the target concentration.

Table A-1 Chromatography Systems Used in the Prenatal Developmental Toxicity Studies of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

Chromatography | Detection System | Column | Mobile Phase
System A
Gas chromatography | Mass spectrometer | J&W DB-5MS (30 m × 0.25 mm ID, 0.25 μm film thickness) | Helium, 1.0 mL/min flow rate
System B
Gas chromatography | Flame ionization detector (275°C) | J&W DB-5MS (30 m × 0.25 mm ID, 0.25 μm film thickness) | Helium, 1.0 mL/min flow rate
System C
Ultra-performance liquid chromatography | Photodiode array detector (210–400 nm) | Waters Acquity UPLC HSS T3, (2.1 × 50 mm, 1.8 μm) | A: Water B: Acetonitrile Gradient program: A:B (70:30 for 0.5 minutes, ramp to 10:90 in 7 minutes, hold at 10:90 for 0.5 minutes, reverse to 70:30 in 1 minute, hold at 70:30 for 2 minutes) 0.50 mL/min flow rate
System D
Gas chromatography | Flame ionization detector (325°C) | J&W DB-5MS (30 m × 0.32 mm ID, 0.5 μm film thickness) | Helium, 2.0 mL/min flow rate

ID = internal diameter; UPLC = ultra-performance liquid chromatography.

Table A-2 Preparation and Storage of Dose Formulations in the Prenatal Developmental Toxicity Studies of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

Preparation
Dose formulations of MPEP in corn oil were created by weighing an appropriate amount of lot JL44164 in a weighing container. The contents were transferred to a precalibrated glass mixing bottle. The weighing container was rinsed with corn oil vehicle (lot 0120-0576, Welch, Holme and Clark Co., Inc) into the mixing bottle to ensure complete transfer. Flasks were brought to volume with corn oil. Formulations were stirred with a spatula for ~15 minutes, mixed using a Polytron for 10–15 minutes, then stirred again for 15–30 minutes until homogenous.
Chemical Lot Number
JL44164 (AK Scientific, Inc.)
Maximum Storage Time
42 days
Storage Conditions
Clear glass bottles with Teflon-lined caps stored at 25°C (room temperature)
Study Laboratory
Southern Research (Birmingham, AL)

MPEP = 2-((1-(4-phenoxyphenoxy)propan-2-yl)oxy)pyridine.

Table A-3 Results of Analyses of Dose Formulations Administered to Female Rats in the Prenatal Developmental Toxicity Study of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^a^ | Difference from Target (%)
Preadministration Samples
October 11, 2016 | October 11–18, 2016 | 0.0 | BLOQ | NA
October 11, 2016 | October 11–18, 2016 | 31.25 | 29.8 ± 1.7 | −4.6
October 11, 2016 | October 11–18, 2016 | 62.5 | 64.0 ± 2.8 | 2.0
October 11, 2016 | October 11–18, 2016 | 125 | 127 ± 3.8 | 2.0
October 11, 2016 | October 11–18, 2016 | 250 | 246 ± 18 | −1.6
Postadministration Samples
October 11, 2016 | November 21–22, 2016 | 0.0 | BLOQ | NA
October 11, 2016 | November 21–22, 2016 | 31.25 | 32.1 ± 2.41 | 3.0
October 11, 2016 | November 21–22, 2016 | 62.5 | 64.1 ± 2.42 | 3.0
October 11, 2016 | November 21–22, 2016 | 125 | 129 ± 1.23 | 3.0
October 11, 2016 | November 21–22, 2016 | 250 | 246 ± 6.97 | −1.6

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Results of triplicate analyses.

Table A-4 Results of Analyses of Dose Formulations Administered to Female Rabbits in the Dose Range-finding Study of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^a^ | Difference from Target (%)
Preadministration Samples
November 13, 2017 | November 13–14, 2017 | 0.0 | BLOQ | NA
November 13, 2017 | November 13–14, 2017 | 150 | 159 ± 2.20 | 6.2
November 13, 2017 | November 13–14, 2017 | 200 | 214 ± 3.21 | 7.1
November 13, 2017 | November 13–14, 2017 | 250 | 274 ± 3.12 | 9.8
Postadministration Samples
November 13, 2017 | December 28–29, 2017 | 0.0 | BLOQ | NA
November 13, 2017 | December 28–29, 2017 | 150 | 150 ± 2.25 | −0.21
November 13, 2017 | December 28–29, 2017 | 200 | 210 ± 0.771 | 5.2
November 13, 2017 | December 28–29, 2017 | 250 | 303 ± 1.44 | 21.3

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Results of triplicate analyses.

Table A-5 Results of Analyses of Dose Formulations Administered to Female Rabbits in the Prenatal Developmental Toxicity Study of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^a^ | Difference from Target (%)
Preadministration Samples
January 11, 2018 | January 15–16, 2018 | 0.0 | BLOQ | NA
January 11, 2018 | January 15–16, 2018 | 31.25 | 31.0 ± 0.188 | −0.8
January 11, 2018 | January 15–16, 2018 | 62.5 | 61.1 ± 0.278 | −2.3
January 11, 2018 | January 15–16, 2018 | 125 | 127 ± 0.634 | 2.0
Postadministration Samples
January 11, 2018 | February 21–22, 2018 | 0.0 | BLOQ | NA
January 11, 2018 | February 21–22, 2018 | 31.25 | 32.2 ± 0.385 | 3.1
January 11, 2018 | February 21–22, 2018 | 62.5 | 63.3 ± 0.471 | 1.3
January 11, 2018 | February 21–22, 2018 | 125 | 132 ± 0.583 | 5.5

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Results of triplicate analyses.

Figure A-1

Reference Infrared Absorption Spectrum of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine

Figure A-2

^1^H Nuclear Magnetic Resonance Spectrum of Reference Sample of 2-((1-(4-Phenoxyphenoxy)propan-2-yl)oxy)pyridine