# Overview

The National Toxicology Program (NTP) has assessed the potential adverse effects of sunscreens using in vitro and in vivo model systems; the data presented herein are part of that larger effort. The scope of 2-ethylhexyl p-methoxycinnamate (EHMC) studies includes the assessment of potential endocrine activity as outlined in the U.S. Environmental Protection Agency Endocrine Disruptor Screening Program Tier 1 studies (estrogen- and androgen-receptor binding and activation, Hershberger and uterotrophic assays, aromatase inhibition, and steroid synthesis inhibition), metabolism and disposition following oral gavage and dermal exposure, and characterization of the potential effects of continuous EHMC exposure over multiple generations using the NTP modified one-generation study design. In this study, exposure to EHMC in feed began on gestation day (GD) 6. At weaning, 1 and 2 pups/sex/litter were allocated to prenatal and reproductive performance cohorts, respectively; one pup/sex from 10 litters was allocated to the subchronic cohort; and an additional one pup/sex/litter was allocated to the biological sampling cohort. In addition to an assessment of reproductive performance, F_2_ fetal outcomes (GD 21 fetal examinations) were assessed in the prenatal cohort, the potential effects on parturition and early growth of the F_2_ generation were assessed in the reproductive performance cohort, and the potential effects on adult F_1_ organ systems were evaluated in the subchronic cohort. Apical indicators sensitive to endocrine modulation were measured.