# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2690-2052

DOI: https://doi.org/10.22427/NTP-DART-06

Report Series: NTP Developmental and Reproductive Toxicity Report Series

Report Series Number: 06

Official citation: National Toxicology Program (NTP). 2022. NTP developmental and reproductive toxicity technical report on the modified one-generation study of 2-ethylhexyl p-methoxycinnamate (CASRN 5466-77-3) administered in feed to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats with prenatal, reproductive performance, and subchronic assessments in F_1_ offspring. Research Triangle Park, NC: National Toxicology Program. DART Report 06.