# Explanation of Levels of Evidence for Developmental and Reproductive Toxicity

The National Toxicology Program (NTP) describes the results of individual studies of chemical agents and other test articles and notes the strength of the evidence for conclusions regarding each study. Generally, each study is confined to a single laboratory animal species, although in some instances, multiple species could be investigated under the purview of a single study report. Negative results, in which the study animals do not exhibit evidence of developmental toxicity, do not necessarily imply a test article is not a developmental toxicant, but only that the test article is not a developmental toxicant under the specific conditions of the study. Positive results demonstrating a test article causes developmental toxicity in laboratory animals under the conditions of the study are assumed relevant to humans, unless data are available that demonstrate otherwise. In addition, such positive effects should be assumed to be primary effects, unless clear evidence shows they are secondary consequences of excessive maternal toxicity. Given that developmental events are intertwined in the reproductive process, effects on developmental toxicity may be detected in reproductive studies. Evaluation of such developmental effects should be based on the NTP Criteria for Levels of Evidence for Developmental Toxicity.

It is critical to recognize that the “levels of evidence” statements described herein describe only developmental hazard. The actual determination of risk to humans requires exposure data that are not considered in these summary statements.

Five categories of evidence of reproductive toxicity are used to summarize the strength of the evidence observed in each experiment: two categories for positive results (clear evidence and some evidence); one category for uncertain findings (equivocal evidence); one category for no observable effects (no evidence); and one category for experiments that cannot be evaluated because of major design or performance flaws (inadequate study). Application of these criteria requires professional judgment by individuals with ample experience with and understanding of the animal models and study designs employed. For each study, conclusion statements are made using one of the following five categories to describe the findings; if warranted, these conclusion statements should be made separately for males and females. These categories refer to the strength of the evidence of the experimental results and not to potency or mechanism.

## Levels of Evidence for Evaluating Reproductive Toxicity

- Clear evidence of reproductive toxicity is demonstrated by a dose-related effect on fertility or fecundity, or by changes in multiple interrelated reproductive parameters of sufficient magnitude that the weight of evidence implies a compromise in reproductive function.
- Some evidence of reproductive toxicity is demonstrated by effects on reproductive parameters, the net impact of which is judged by weight of evidence to have potential to compromise reproductive function. Relative to clear evidence of reproductive toxicity, such effects would be characterized by greater uncertainties or weaker relationships with regard to dose, severity, magnitude, incidence, persistence, or decreased concordance among affected endpoints.
- Equivocal evidence of reproductive toxicity is demonstrated by marginal or discordant effects on reproductive parameters that may or may not be related to the test article.
- No evidence of reproductive toxicity is demonstrated by data from a study with appropriate experimental design and conduct that are interpreted as showing no biologically relevant effects on reproductive parameters that are related to the test article.
- Inadequate study of reproductive toxicity is demonstrated by a study that, because of major design or performance flaws, cannot be used to determine the occurrence of reproductive toxicity.

## Levels of Evidence for Evaluating Developmental System Toxicity

- Clear evidence of developmental toxicity is demonstrated by data that indicate a dose-related effect on one or more of its four elements (embryo-fetal death, structural malformations, growth retardation, or functional deficits) that is not secondary to overt maternal toxicity.
- Some evidence of developmental toxicity is demonstrated by dose-related effects on one or more of its four elements (embryo-fetal death, structural malformations, growth retardation, or functional deficits), but are greater uncertainties or weaker relationships with regard to dose, severity, magnitude, incidence, persistence, or decreased concordance among affected endpoints occur.
- Equivocal evidence of developmental toxicity is demonstrated by marginal or discordant effects on developmental parameters that may or may not be related to the test article.
- No evidence of developmental toxicity is demonstrated by data from a study with appropriate experimental design and conduct that are interpreted as showing no biologically relevant effects on developmental parameters that are related to the test article.
- Inadequate study of developmental toxicity is demonstrated by a study that, because of major design or performance flaws, cannot be used to determine the occurrence of developmental toxicity.

When a conclusion statement for a particular study is selected, consideration must be given to key factors that would support the selection of an individual category of evidence. Such consideration should allow for incorporation of scientific experience and current understanding of developmental and reproductive toxicity studies in laboratory animals, particularly with respect to interrelationships between endpoints or malformation, effect of the change on reproductive function or developmental outcomes, relative sensitivity of endpoints, normal background incidence, and specificity of the effect. For those evaluations that are on the borderline between two adjacent levels, some factors to consider in selecting the level of evidence of reproductive toxicity are given below:

- Increases in severity and/or prevalence (more individuals and/or more affected litters) as a function of dose generally strengthen the level of evidence, keeping in mind that the specific manifestation could be different with increasing dose. For example, histological changes at a lower dose level might reflect reductions in fertility at higher dose levels.
- In general, the more animals affected, the stronger the evidence; however, effects on a small number of animals across multiple related endpoints should not be discounted, even in the absence of statistical significance for the individual endpoint(s). In addition, effects with low background incidence when interpreted in the context of historical controls could be biologically important.
- Effects seen in many litters might provide stronger evidence than effects confined to one or a few litters, even if the incidence within those litters is high.
- Because of the complex relationship between maternal physiology and development, evidence for developmental toxicity might be greater for a selective effect on the embryo-fetus or pup.
- Concordant effects (syndromic) can strengthen the evidence of developmental toxicity. Single endpoint changes by themselves can be weaker indicators of effect than concordant effects on multiple endpoints related by a common process or mechanism.
- In order to be assigned a level of “clear evidence,” the endpoint(s) evaluated should normally show a statistical increase in the deficit, or syndrome, on a litter basis.
- Consistency of effects across generations may strengthen the level of evidence. However, special care should be taken for decrements in reproductive parameters noted in the F_1_ generation that were not seen in the F_0_ generation, which may suggest developmental as well as reproductive toxicity. Alternatively, if effects are observed in the F_1_ generation but not in the F_2_ generation (or the effects occur at a lesser frequency in the F_2_ generation), this may be due to the nature of the effect resulting in selection for resistance to the effect (i.e., if the effect is incompatible with successful reproduction, then the affected individuals will not produce offspring).
- Transient changes (e.g., pup weight decrements) by themselves are weaker indicators of effect than persistent changes.
- Single endpoint changes by themselves are weaker indicators of effect than concordant effects on multiple, interrelated endpoints.
- Marked changes in multiple reproductive tract endpoints without effects on integrated reproductive function (i.e., fertility and fecundity) may be sufficient to reach a conclusion of clear evidence of reproductive toxicity.
- Insights from supportive studies (e.g., toxicokinetics, ADME [absorption, distribution, metabolism, and excretion], computational models, structure-activity relationships) and reproductive findings from other in vivo animal studies (NTP or otherwise) should be drawn upon when interpreting the biological plausibility of an effect.
- New assays or techniques need to be appropriately characterized to build confidence in their utility: Their usefulness as indicators of effect increases if they can be associated with changes in traditional endpoints.

For more information visit: https://ntp.niehs.nih.gov/go/10003.