# Peer Review

The National Toxicology Program (NTP) convened a virtual external ad hoc panel to peer review the draft NTP Developmental and Reproductive Toxicity Technical Report on the Modified One-Generation Study of 2-Ethylhexyl p-Methoxycinnamate (CASRN 5466-77-3) Administered in Feed to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats with Prenatal, Reproductive Performance, and Subchronic Assessments in F_1_ Offspring on October 14, 2021. NTP announced the peer-review meeting in the Federal Register (86 FR. 42869. August 5, 2021). The public could view the proceedings online, and opportunities were provided for submission of written and oral public comments. The selection of panel members and conduct of the peer review were in accordance with federal policies and regulations. The panel was charged to:

1. Review and evaluate the scientific and technical elements of each study and its presentation.
2. Determine whether each study’s experimental design, conduct, and findings support NTP’s conclusions under the conditions of each study.

NTP carefully considered the panel’s recommendations in finalizing the report. The peer-review report is provided in Appendix D. Other meeting materials are available on the NTP website (https://ntp.niehs.nih.gov/go/meeting).

## Peer Reviewers

- Rebecca Fry, Ph.D., Chairperson
  Associate Chair, Department of Environmental Sciences and Engineering
  University of North Carolina at Chapel Hill
  Chapel Hill, North Carolina, USA
- Brian Enright, Ph.D., M.Sc., DABT
  Research Fellow, Toxicology and Pharmacology
  AbbVie, Inc.
  North Chicago, Illinois, USA
- Bethany Hannas, Ph.D., DABT
  Team Leader, Endocrine
  Corteva Agriscience
  Middletown, Delaware, USA
- Linda Roberts, Ph.D., DABT
  Principal
  NapaTox Consulting LLC
  Napa, California, USA
- Mary Alice Smith, Ph.D.
  Professor Emeritus
  University of Georgia Regenerative Bioscience Center
  Athens, Georgia, USA