# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Designed studies, evaluated and interpreted results, and reported findings
  B.S. McIntyre, Ph.D., Study Scientist
  C.R. Blystone, Ph.D.
  M.F. Cesta, D.V.M., Ph.D.
  B.J. Collins, M.S.P.H.
  M.C. Cora, D.V.M.
  H.C. Cunny, Ph.D.
  P.M. Foster, Ph.D. (Retired)
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D. (Retired)
  D.E. Malarkey, D.V.M., Ph.D. (Retired)
  G.K. Roberts, Ph.D.
  K.A. Shipkowski, Ph.D.
  K.R. Shockley, Ph.D.
  M.D. Stout, Ph.D.
  V.L. Sutherland, Ph.D.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
- Provided oversight for data management
  J.M. Fostel, Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  A.E. Brix, D.V.M., Ph.D., Study Pathologist
- Provided pathology review
  J.C. Seely, D.V.M., Principal Investigator
- RTI International, Research Triangle Park, North Carolina, USA
  Conducted studies and evaluated findings
  C.J. Price, Ph.D., Principal Investigator (Dose Range-finding Study)
  R.W. Tyl, Ph.D., Principal Investigator (Modified One-Generation Study)
  K.J. Turner, Ph.D.
- Prepared and analyzed dose formulations
  R.A. Fernando, Ph.D.
  J.C. Blake, B.A.
- MRIGlobal, Kansas City, Missouri, USA
  Conducted prestart chemistry activities
  J.W. Algaier, Ph.D., Principal Investigator
  K.L. Aillon, Ph.D.
  S.P. Kerns, M.S.
  M. Kroenke, B.S.
- Integrated Laboratory Systems, LLC, Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Peer Review on modified one-generation studies (October 10, 2017)
  Y.V. Costecalde, D.V.M.
- Social & Scientific Systems, a DLH Company, Research Triangle Park, North Carolina, USA
  Provided statistical analyses
  S. McBride, Ph.D., Principal Investigator
  L.J. Betz, M.S.
- ASRC Federal, Research Triangle Park, North Carolina, USA
  Prepared data for report
  J. Berke, B.S.
  P. Brown, B.S.
  C. Myers, M.S.
  A. Raghuraman, M.S.
  N. Sayers, B.S.
- ICF, Fairfax, Virginia, USA
  Contributed to technical writing and data integration and ensured report quality
  S.J. Snow, Ph.D.