# References

1 ChemSpider. Structure search. 2021. https://www.chemspider.com/StructureSearch.aspx
2 National Center for Biotechnology Information (NCBI). PubChem Compound Summary for CID 21630, Octyl methoxycinnamate. Bethesda, MD: National Library of Medicine. https://pubchem.ncbi.nlm.nih.gov/compound/21630
3 U.S. Environmental Protection Agency (USEPA). CompTox Database. https://comptox.epa.gov/dashboard/
4 Liem DH, Hilderink LTH. U.V. absorbers in sun cosmetics 1978. Int J Cosmet Sci. 1979; 1(6):341–361. 10.1111/j.1467-2494.1979.tb00228.x 19467089
5 Garcia RDA, Maltarollo VG, Honório KM, Trossini GHG. Benchmark studies of UV–vis spectra simulation for cinnamates with UV filter profile. J Mol Model. 2015; 21(6):150. 10.1007/s00894-015-2689-y 25994457
6 Lee GS, Widjaja A, Ju YH. Enzymatic synthesis of cinnamic acid derivatives. Biotechnol Lett. 2006; 28(8):581–585. 10.1007/s10529-006-0019-2 16614896
7 National Center for Biotechnology Information (NCBI). PubChem Compound Summary for CID 21630, Octyl methoxycinnamate: 9.2.2 Consumer Uses. Bethesda, MD: National Library of Medicine. https://pubchem.ncbi.nlm.nih.gov/compound/Octyl-methoxycinnamate#section=Consumer-Uses
8 Environmental Working Group (EWG). EWG's skin deep: Octinoxate. 2019. https://www.ewg.org/skindeep/ingredients/704203-OCTINOXATE/
9 Huang Y, Law JC-F, Zhao Y, Shi H, Zhang Y, Leung KS-Y. Fate of UV filter ethylhexyl methoxycinnamate in rat model and human urine: Metabolism, exposure and demographic associations. Sci Total Environ. 2019; 686:729–736. 10.1016/j.scitotenv.2019.05.440 31195281
10 U.S. Code. 15(Section 2607).
11 Fennell TR, Mathews JM, Snyder RW, Hong Y, Watson SL, Black SR, McIntyre BS, Waidyanatha S. Metabolism and disposition of 2-ethylhexyl-p-methoxycinnamate following oral gavage and dermal exposure in Harlan Sprague Dawley rats and B6C3F1/N mice and in hepatocytes in vitro. Xenobiotica. 2018; 48(11):1142–1156. 10.1080/00498254.2017.1400129 29111853
12 Janjua NR, Mogensen B, Andersson A-M, Petersen JH, Henriksen M, Skakkebæk NE, Wulf HC. Systemic absorption of the sunscreens benzophenone-3, octyl-methoxycinnamate, and 3-(4-methyl-benzylidene) camphor after whole-body topical application and reproductive hormone levels in humans. J Invest Dermatol. 2004; 123(1):57–61. 10.1111/j.0022-202X.2004.22725.x 15191542
13 Benech-Kieffer F, Wegrich P, Schwarzenbach R, Klecak G, Weber T, Leclaire J, Schaefer H. Percutaneous absorption of sunscreens in vitro: Interspecies comparison, skin models and reproducibility aspects. Skin Pharmacol Appl Skin Physiol. 2000; 13(6):324–335. 10.1159/000029940 11096374
14 Hayden CG, Cross SE, Anderson C, Saunders NA, Roberts MS. Sunscreen penetration of human skin and related keratinocyte toxicity after topical application. Skin Pharmacol Physiol. 2005; 18(4):170–174. 10.1159/000085861 15908756
15 Klimová Z, Hojerová J, Beránková M. Skin absorption and human exposure estimation of three widely discussed UV filters in sunscreens – in vitro study mimicking real-life consumer habits. Food Chem Toxicol. 2015; 83:237–250. 10.1016/j.fct.2015.06.025 26151237
16 Jiménez MM, Pelletier J, Bobin MF, Martini MC. Influence of encapsulation on the in vitro percutaneous absorption of octyl methoxycinnamate. Int J Pharm. 2004; 272(1-2):45–55. 10.1016/j.ijpharm.2003.11.029 15019068
17 Puglia C, Bonina F, Castelli F, Micieli D, Sarpietro MG. Evaluation of percutaneous absorption of the repellent diethyltoluamide and the sunscreen ethylhexyl p-methoxycinnamate-loaded solid lipid nanoparticles: An in-vitro study. J Pharm Pharmacol. 2009; 61(8):1013–1019. 10.1211/jpp.61.08.0004 19703344
18 Schlumpf M, Cotton B, Conscience M, Haller V, Steinmann B, Lichtensteiger W. In vitro and in vivo estrogenicity of UV screens. Environ Health Perspect. 2001; 109(3):239–244. 10.1289/ehp.01109239 11333184
19 Schlumpf M, Schmid P, Durrer S, Conscience M, Maerkel K, Henseler M, Gruetter M, Herzog I, Reolon S, Ceccatelli R, et al. Endocrine activity and developmental toxicity of cosmetic UV filters—An update. Toxicology. 2004; 205(1-2):113–122. 10.1016/j.tox.2004.06.043 15458796
20 Schreurs RHMM, Sonneveld E, Jansen JHJ, Seinen W, van der Burg B. Interaction of polycyclic musks and UV filters with the estrogen receptor (ER), androgen receptor (AR), and progesterone receptor (PR) in reporter gene bioassays. Toxicol Sci. 2005; 83(2):264–272. 10.1093/toxsci/kfi035 15537743
21 Klammer H, Schlecht C, Wuttke W, Jarry H. Multi-organic risk assessment of estrogenic properties of octyl-methoxycinnamate in vivo A 5-day sub-acute pharmacodynamic study with ovariectomized rats. Toxicology. 2005; 215(1-2):90–96. 10.1016/j.tox.2005.06.026 16112788
22 Axelstad M, Boberg J, Hougaard KS, Christiansen S, Jacobsen PR, Mandrup KR, Nellemann C, Lund SP, Hass U. Effects of pre- and postnatal exposure to the UV-filter octyl methoxycinnamate (OMC) on the reproductive, auditory and neurological development of rat offspring. Toxicol Appl Pharmacol. 2011; 250(3):278–290. 10.1016/j.taap.2010.10.031 21059369
23 Schneider S, Deckardt K, Hellwig J, Küttler K, Mellert W, Schulte S, van Ravenzwaay B. Octyl methoxycinnamate: Two generation reproduction toxicity in Wistar rats by dietary administration. Food Chem Toxicol. 2005; 43(7):1083–1092. 10.1016/j.fct.2005.02.013 15833384
24 European Chemicals Agency (ECHA). Registration dossier: 2-Ethylhexyl trans-4-methoxycinnamate: Toxicity to reproduction: 001 Key | Experimental result. 2021. https://echa.europa.eu/registration-dossier/-/registered-dossier/15876/7/9/2
25 European Commission (EC). Reports of the Scientific Committee on Cosmetology (Ninth Series). 1999. https://ec.europa.eu/health/scientific_committees/consumer_safety/docs/scc_o_9.pdf
26 National Toxicology Program (NTP). NTP technical report on the toxicology and carcinogenesis studies of 2-hydroxy-4-methoxybenzophenone administered in feed to Sprague Dawley (Hsd:Sprague Dawley SD) rats and B6C3F1/N mice. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2020. NTP Technical Report No. 597. https://ntp.niehs.nih.gov/publications/reports/tr/500s/tr597/index.html?utm_source=direct&utm_medium=prod&utm_campaign=ntpgolinks&utm_term=tr597abs
27 Rehfeld A, Dissing S, Skakkebæk NE. Chemical UV filters mimic the effect of progesterone on Ca2+ signaling in human sperm cells. Endocrinology. 2016; 157(11):4297–4308. 10.1210/en.2016-1473 27583790
28 Rehfeld A, Egeberg DL, Almstrup K, Petersen JH, Dissing S, Skakkebæk NE. EDC IMPACT: Chemical UV filters can affect human sperm function in a progesterone-like manner. Endocr Connect. 2018; 7(1):16–25. 10.1530/EC-17-0156 28874401
29 European Chemicals Agency (ECHA). Registration dossier: 2-Ethylhexyl trans-4-methoxycinnamate (CASRN: 83834-59-7): Acute toxicity: Oral: 001 key | Experimental result. 2020. https://echa.europa.eu/registration-dossier/-/registered-dossier/15876/7/3/2
30 European Chemicals Agency (ECHA). Registration dossier: 2-Ethylhexyl trans-4-methoxycinnamate (CASRN 83834-59-7): Eye irritation: 001 key | Experimental result. 2020. https://echa.europa.eu/registration-dossier/-/registered-dossier/15876/7/4/3
31 European Chemicals Agency (ECHA). Registration dossier: 2-Ethylhexyl trans-4-methoxycinnamate (CASRN 83834-59-7): Skin sensitisation: 001 key | Experimental result. 2020. https://echa.europa.eu/pt/registration-dossier/-/registered-dossier/15876/7/5/2
32 Rodríguez E, Valbuena MC, Rey M, Porras de Quintana L. Causal agents of photoallergic contact dermatitis diagnosed in the national institute of dermatology of Colombia. Photodermatol Photoimmunol Photomed. 2006; 22(4):189–192. 10.1111/j.1600-0781.2006.00212.x 16869867
33 Ang P, Ng SK, Goh CL. Sunscreen allergy in Singapore. Am J Contact Dermat. 1998; 9(1):42–44. 10.1016/S1046-199X(98)90145-2 9471986
34 Darvay A, White IR, Rycroft RJ, Jones AB, Hawk JL, McFadden JP. Photoallergic contact dermatitis is uncommon. Br J Dermatol. 2001; 145(4):597–601. 10.1046/j.1365-2133.2001.04458.x 11703286
35 National Toxicology Program (NTP). UV filters. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2020. https://ntp.niehs.nih.gov/whatwestudy/topics/uvfilters/index.html#:~:text=NTP%20is%20working%20to%20assess,chemical%20in%20rats%20and%20mice.
36 Blystone CR, Kissling GE, Bishop JB, Chapin RE, Wolfe GW, Foster PM. Determination of the di-(2-ethylhexyl) phthalate NOAEL for reproductive development in the rat: Importance of the retention of extra animals to adulthood. Toxicol Sci. 2010; 116(2):640–646. 10.1093/toxsci/kfq147 20484383
37 U.S. Environmental Protection Agency (USEPA). Guidelines for developmental toxicity risk assessment. Washington, DC: U.S. Environmental Protection Agency, Risk Assessment Forum; 1991. EPA Document No. EPA/600/FR-91/001.
38 Makris SL, Solomon HM, Clark R, Shiota K, Barbellion S, Buschmann J, Ema M, Fujiwara M, Grote K, Hazelden KP. Terminology of developmental abnormalities in common laboratory mammals (version 2). Congenit Anom (Kyoto). 2009; 49(3):123–246. 10.1111/j.1741-4520.2009.00239.x 20002907
39 Cora MC, Kooistra L, Travlos G. Vaginal cytology of the laboratory rat and mouse: Review and criteria for the staging of the estrous cycle using stained vaginal smears. Toxicol Pathol. 2015; 43(6):776–793. 10.1177/0192623315570339 25739587
40 Staples RE. Detection of visceral alterations in mammalian fetuses. Teratology. 1974; 9(3):A37–A38.
41 Stuckhardt JL, Poppe SM. Fresh visceral examination of rat and rabbit fetuses used in teratogenicity testing. Teratog Carcinog Mutagen. 1984; 4(2):181–188. 10.1002/tcm.1770040203 6145223
42 Thompson RF. Chapter 4: Basic neuroanatomy. Foundations of Physiological Psychology. New York, NY: Harper and Row Publishers; 1967. p. 79–82.
43 Marr MC, Price CJ, Myers CB, Morrissey RE. Developmental stages of the CD (Sprague-Dawley) rat skeleton after maternal exposure to ethylene glycol. Teratology. 1992; 46(2):169–181. 10.1002/tera.1420460210 1440420
44 Tyl RW. Commentary on the role of maternal toxicity on developmental toxicity. Birth Defects Res B Dev Reprod Toxicol. 2012; 95(3):262–266. 10.1002/bdrb.21015 22706915
45 Robb GW, Amann RP, Killian GJ. Daily sperm production and epididymal sperm reserves of pubertal and adult rats. J Reprod Fertil. 1978; 54(1):103–107. 10.1530/jrf.0.0540103 712697
46 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
47 Boorman GA, Haseman JK, Waters MD, Hardisty JF, Sills RC. Quality review procedures necessary for rodent pathology databases and toxicogenomic studies: The National Toxicology Program experience. Toxicol Pathol. 2002; 30(1):88–92. 10.1080/01926230252824752 11890481
48 Kupper LL, Portier C, Hogan MD, Yamamoto E. The impact of litter effects on dose-response modeling in teratology. Biometrics. 1986; 42(1):85–98. 10.2307/2531245 3719065
49 Rao JN, Scott AJ. A simple method for the analysis of clustered binary data. Biometrics. 1992; 48(2):577–585. 10.2307/2532311 1637980
50 Fung KY, Krewski D, Rao JN, Scott AJ. Tests for trend in developmental toxicity experiments with correlated binary data. Risk Anal. 1994; 14(4):639–648. 10.1111/j.1539-6924.1994.tb00277.x 7972964
51 Bailer AJ, Portier CJ. Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988; 44(2):417–431. 10.2307/2531856 3390507
52 Piegorsch WW, Bailer AJ. Statistics for environmental biology and toxicology. London, England: Chapman & Hall; 1997.
53 Portier CJ, Bailer AJ. Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989; 12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
54 Bieler GS, Williams RL. Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993; 49(3):793–801. 10.2307/2532200 8241374
55 Nam JM. A simple approximation for calculating sample sizes for detecting linear trend in proportions. Biometrics. 1987; 43(3):701–705. 10.2307/2532006 3663825
56 Dixon W, Massey F. Introduction to Statistical Analysis. New York, NY: McGraw Hill Book Company Inc; 1957.
57 Tukey J. Easy summaries – numerical and graphical. Exploratory Data Analysis. Reading, MA: Addison-Wesley; 1977. p. 43–44.
58 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
59 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
60 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
61 Hsu JC. The factor analytic approach to simultaneous inference in the general linear model. J Comput Graph Stat. 1992; 1(2):151–168. 10.1080/10618600.1992.10477011
62 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
63 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-doe control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
64 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
65 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1-2):133–145. 10.1093/biomet/41.1-2.133
66 Davison AC, Hinkley DV. Bootstrap Methods and Their Application. Cambridge, UK: Cambridge University Press; 1997. 10.1017/CBO9780511802843
67 Datta S, Satten GA. Rank-sum tests for clustered data. J Am Stat Assoc. 2005; 100(471):908–915. 10.1198/016214504000001583
68 Hommel G. A stagewise rejective multiple test procedure based on a modified Bonferroni test. Biometrika. 1988; 75(2):383–386. 10.1093/biomet/75.2.383
69 Hothorn LA. Statistical evaluation of toxicological bioassays – a review. Toxicol Res (Camb). 2014; 3(6):418–432. 10.1039/C4TX00047A
70 Kalbfleisch JD, Lawless JF. The analysis of panel data under a Markov assumption. J Am Stat Assoc. 1985; 80(392):863–871. 10.1080/01621459.1985.10478195
71 Code of Federal Regulations (CFR). 21(Part 58).
72 National Toxicology Program (NTP). DART-06: Growth and clinical finding tables (I), pathology tables (PA), developmental and reproductive tables (R) from NTP modified one generation dose range finding study and modified one generation main study studies. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health, National Toxicology Program; 2019. 10.22427/NTP-DATA-DART-06
73 Engelbregt MJT, Houdijk MECAM, Popp-Snijders C, Delemarre-van de Waal HA. The effects of intra-uterine growth retardation and postnatal undernutrition on onset of puberty in male and female rats. Pediatr Res. 2000; 48(6):803–807. 10.1203/00006450-200012000-00017 11102550
74 Bronson FH. Puberty in female rats: Relative effect of exercise and food restriction. Am J Physiol. 1987; 252(1 Pt 2):R140–R144. 10.1152/ajpregu.1987.252.1.R140 3812725
75 Chapin RE, Gulati DK, Barnes LH, Teague JL. The effects of feed restriction on reproductive function in Sprague-Dawley rats. Fundam Appl Toxicol. 1993; 20(1):23–29. 10.1006/faat.1993.1003 8432425
76 Ritter EJ, Scott Jr WJ, Randall JL, Ritter JM. Teratogenicity of di(2-ethylhexyl) phthalate, 2-ethylhexanol, 2-ethylhexanoic acid, and valproic acid, and potentiation by caffeine. Teratology. 1987; 35(1):41–46. 10.1002/tera.1420350107 3105103
77 Pennanen S, Tuovinen K, Huuskonen H, Komulainen H. The developmental toxicity of 2-ethylhexanoic acid in Wistar rats. Fundam Appl Toxicol. 1992; 19(4):505–511. 10.1016/0272-0590(92)90088-Y 1426708
78 Tyl RW, Fisher LC, Kubena MF, Vrbanic MA, Gingell R, Guest D, Hodgson JR, Murphy SR, Tyler TR, Astill BD. The developmental toxicity of 2-ethylhexanol applied dermally to pregnant Fischer 344 rats. Fundam Appl Toxicol. 1992; 19(2):176–185. 10.1016/0272-0590(92)90149-C 1516773
79 LabDiet. Advanced Protocol® Verified Casein Diet 10 IF. 2017. https://www.labdiet.com/cs/groups/lolweb/@labdiet/documents/web_content/mdrf/mdi4/~edisp/ducm04_028427.pdf